# METHODS

## REGISTRATION AND REVIEW

A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix. We filed a review protocol with the ESP Coordinating Center.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

Key Question 1 | What approaches have been used to integrate mental or behavioral health care into specialty medical care settings?
Key Question 2 | Does integration of mental or behavioral health care into specialty medical care settings improve patient-important outcomes or health service delivery outcomes?

Study eligibility criteria are shown in the table below.

Population | Adult patients in outpatient specialty medical care settings (oncology, neurology, sleep, infectious disease, cardiology, pulmonary, endocrinology, urology, hepatology, nephrology, and geriatric care) with co-occurring mental or behavioral health conditions/symptoms
Intervention | Approaches or models for integration of mental or behavioral health care into specialty care settings. Approaches should include 1 or more of the following components: co-location of behavioral health and medical specialty care services, active referral (“warm hand-off”) between services, case/care management, screening and/or brief interventions for mental and behavioral health concerns within a specialty medical care setting. Approaches consisting only of passive referral (eg, provision of contact information for a behavioral health care provider) will be ineligible.
Comparator | Usual care (ie, specialty care without integrated mental or behavioral health services or with passive referrals only), alternative approaches
Outcomes | Patient-important and health service delivery outcomes (eg, mental health condition severity, health-related quality of life, satisfaction with care, access to behavioral health care, wait times, engagement/retention, successful referrals, staff workload, staff satisfaction)
Study Design | Any

## SEARCHING AND SCREENING

To identify articles relevant to the key questions, a research librarian searched Medline and PsycInfo through 1/29/24 and 2/14/24, respectively, using terms for mental health, behavioral health, and patient care team (see Appendix for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts.

We used the artificial intelligence function in DistillerSR to screen titles and abstracts from the search results. First, the lead author reviewed a sample of 760 titles and abstracts and selected 23 studies meeting all eligibility criteria. The AI function then used this information to estimate a likelihood of being eligible for each of the 3,652 search results. The lowest likelihood of eligibility for any of the 23 studies included by the lead author was 0.4 (on a scale from 0 to 1.0). More than 3,000 references were given a very low likelihood of eligibility (ranging from 0 to 0.1). The lead author manually reviewed a 10% random sample of these and found no eligible studies, which suggested that the screening algorithm was accurately differentiating eligible and ineligible studies. In the last step, the lead author manually reviewed the studies assigned a likelihood of eligibility greater than 0.1 (k = 256) to identify included studies. Aside from the database searches, we manually screened a list of approximately 1,000 potentially relevant titles that had been identified for a related project by the operational partner. Abstracts and full text articles were reviewed for studies meeting the inclusion criteria. Studies from low and middle income countries were excluded due to the likely context sensitivity in the types of interventions proposed and the health care systems they are implemented in.

One change was made to the exclusion criteria after the review began: we did not include studies specifically about palliative care in oncology clinics (which often includes a mental health practitioner). With the operational partner’s agreement, we judged this type of mental health integration to be outside the focus of this review. Lastly, while the specialty clinics named in the eligibility criteria above (oncology, neurology, sleep, etc) were of greatest interest to the operational partner, we did not exclude studies if the specialty clinic was not on the list (such as pain clinics).

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Abstracted data included study characteristics (design, sample size, setting), type of mental health being integrated, what specialty clinic it is being integrated into, level of integration according to the Center for Integrated Health Solutions (CIHS) framework^5^ (see Table 1), results of the study, and elements needed to complete the Cochrane Risk of Bias^6^ and Risk Of Bias In Non-randomised Studies - of Interventions (ROBINS-I) Risk of Bias^7^ tools. We used single reviewer data extraction, performed by the lead author.

Table 1 Six Levels of Collaboration/Integration

Coordinated; Key Element: Communication | | Co-Located; Key Element: Physical Proximity | | Integrated; Key Element: Practice Change
LEVEL 1; Minimal Collaboration | LEVEL 2; Basic Collaboration at a Distance | LEVEL 3; Basic Collaboration Onsite | LEVEL 4; Close Collaboration Onsite with Some System Integration | LEVEL 5; Close Collaboration Approaching an Integrated Practice | LEVEL 6; Full Collaboration in a Transformed/Merged Integrated Practice

Notes. Adapted from the CIHS Standard Framework for Levels of Integrated Healthcare (https://gcc02.safelinks.protection.outlook.com/?url=https%3A%2F%2Fwww.thenationalcouncil.org%2Fwp-content%2Fuploads%2F2020%2F01%2FCIHS_Framework_Final_charts.pdf%3Fdaf%3D375ateTbd56&data=05%7C02%7C%7C8ed2191b4bae45f04b0908dca1bebd55%7Ce95f1b23abaf45ee821db7ab251ab3bf%7C0%7C0%7C638563087813850593%7CUnknown%7CTWFpbGZsb3d8eyJWIjoiMC4wLjAwMDAiLCJQIjoiV2luMzIiLCJBTiI6Ik1haWwiLCJXVCI6Mn0%3D%7C0%7C%7C%7C&sdata=wQBS94HasBuR16Om4FF%2Be6XYrB2SYWAEVsi7qKvN1p0%3D&reserved=0).^5^

## SYNTHESIS

The data synthesis is narrative, with studies grouped into the level of integration, and then within that by study design and type of mental health/specialty clinic. Level of integration was determined by content experts with the operational partner reviewing highlighted descriptions of the intervention.

### Strength of Evidence

The evidence base for integration at levels 4, 5, and 6 (in other words, all studies over level 3, which is basic collaboration onsite) consisted of only 4 studies, only 1 of which was a randomized trial, and all of which were in different clinical settings. Thus, there was insufficient evidence to formally assess the strength of evidence for each outcome across studies, and rather we discuss some general themes from the included studies without a formal strength of evidence assessment as done by GRADE.