# BACKGROUND

The rationale for integrating mental health care with physical health care clinical sites has been persuasively laid out by Lisa Rubenstein, professor emerita of medicine and public health at University of California–Los Angeles (UCLA) and past recipient of the Department of Veterans Affairs (VA) Under Secretary for Health Award.^1^ She notes that a small proportion of Veterans (5%) account for nearly half of VA costs, most of which is hospitalization for medical (not mental health) conditions. But, almost half of such patients have a mental health diagnosis. These mental health conditions, many of which are potentially treatable, are risk markers (and potentially risk factors) for future emergency visits and admissions for ambulatory care-sensitive conditions. Thus, better identification and treatment of mental health conditions not only has the potential to improve patients’ physical and mental health, but may also reduce health care utilization.

Requiring patients to see different providers in different clinics for their mental and physical health conditions is a barrier to the successful treatment of either. Thus, there is an imperative for integrating mental health care and physical health care.

VA embarked on such mental health integration about 20 years ago, with the Primary Care-Mental Health Integration (PCMHI) initiative. This initiative built on 3 successful research projects: Translating Initiatives in Depression into Effective Solutions (TIDES), the Behavioral Health Laboratory model, and the White River Junction co-located mental health care model. The success of the PCMHI initiative now spurs integrating mental health care into certain specialty clinics, particularly in situations where the specialty clinic cares longitudinally for persons with chronic conditions (eg, ongoing care provided by Infectious Disease clinics to persons living with HIV).

Three older systematic reviews have dealt with some aspects of mental health integration into specialty clinics. Two reviews, with search end dates of 2014 and 2021, were specific to HIV clinic care.^2,3^ The third review broadly covered specialty medical clinics and was also more broad in its intervention focus, including “models for treating depression.”^4^ The review had a search end date of 2013. All reviews concluded the evidence was limited, and additional research was needed.

Thus, the VHA Office of Mental Health asked the Evidence Synthesis Program (ESP) for a review of more recent published studies of mental health integration into outpatient specialty clinic care.