# ABBREVIATIONS TABLE

Abbreviation: Definition
Al: Artificial intelligence
CIHS: Center for Integrated Health Solutions
GAD: General anxiety disorder
GRADE: Grading of Recommendation, Assessment, Development and Evaluation
ICD: International Classification of Diseases
PCMHI: Primary care mental health integration
PHQ: Patient health questionnaire
ROBINS-I: Risk Of Bias In Non-randomised Studies - of Interventions
SMI: Serious mental illness
TIDES: Translating Initiatives in Depression into Effective Solutions
VA: Department of Veterans Affairs