# REFERENCES

1 USCS Brief United States Cancer Statistics: Highlights from 2018 Incidence. (Centers for Disease Control and Prevention, US Department of Health and Human Services) (2021).
2 Zullig LL, Sims KJ, McNeil R, . Cancer Incidence Among Patients of the U.S. Veterans Affairs Health Care System: 2010 Update. Military Medicine. 2017;182:e1883.
3 Lievens Y. Hypofractionated Breast Radiotherapy: Financial and Economic Consequences. The breast journal. 2010;19:192–197.
4 Smith BD, Bellon JR, Blitzblau R, . Radiation Therapy for the Whole Breast: Executive Summary of an American Society for Radiation Oncology (ASTRO) Evidence-Based Guideline. Practical Radiation oncology. 2018;8:145–152.29545124
5 Morgan SC, Hoffman K, Loblaw DA, . Hypofractionated Radiation Therapy for Localized Prostate Cancer: An ASTRO, ASCO, and AUA Evidence-Based Guideline. Journal of Clinical Oncology. 2018;36(34).
6 DistillerSR. Accessed Jan-Nov 2022. https://www.evidencepartners.com/
7 Methods C. Risk of Bias 2 (RoB 2) tool. https://methods.cochrane.org/risk-bias-2
8 Inc. MUaEP. GRADEpro GDT: GRADEpro Guideline Development Tool. https://acp.gradepro.org/app/
9 Schunemann H, Brozek J, Guyatt G, . GRADE Handbook. 2019.
10 Ball D, Mai GT, Vinod S, . Stereotactic ablative radiotherapy versus standard radiotherapy in stage 1 non-small-cell lung cancer (TROG 09.02 CHISEL): a phase 3, open-label, randomised controlled trial. The Lancet Oncology. 2019;20(4):494–503.30770291
11 Group ST, Bentzen SM, Agrawal RK, . The UK Standardisation of Breast Radiotherapy (START) Trial A of radiotherapy hypofractionation for treatment of early breast cancer: a randomised trial. The Lancet Oncology. 2008;9(4):331–41.18356109
12 Group ST, Bentzen SM, Agrawal RK, . The UK Standardisation of Breast Radiotherapy (START) Trial B of radiotherapy hypofractionation for treatment of early breast cancer: a randomised trial. Lancet (London, England). 2008;371(9618):1098–107.18355913
13 Owen JR, Ashton A, Bliss JM, . Effect of radiotherapy fraction size on tumour control in patients with early-stage breast cancer after local tumour excision: long-term results of a randomised trial. The Lancet Oncology. 2006;7(6):467–71.16750496
14 Livi L, Meattini I, Simontacchi G, . Accelerated partial breast irradiation using intensity-modulated radiotherapy versus whole breast irradiation: 5-year survival analysis of a phase 3 randomised controlled trial. European Journal of Cancer. 2015;51(4):451–463.25605582
15 Group FT, Agrawal RK, Alhasso A, . First results of the randomised UK FAST Trial of radiotherapy hypofractionation for treatment of early breast cancer (CRUKE/04/015). Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2011;100(1):93–100.21752481
16 Murray Brunt A, Haviland JS, Wheatley DA, . Hypofractionated breast radiotherapy for 1 week versus 3 weeks (FAST-Forward): 5-year efficacy and late normal tissue effects results from a multicentre, non-inferiority, randomised, phase 3 trial. Lancet (London, England). 2020;395(10237):1613–1626.32580883
17 Brunt AM, Wheatley D, Yarnold J, . Acute skin toxicity associated with a 1-week schedule of whole breast radiotherapy compared with a standard 3-week regimen delivered in the UK FAST-Forward Trial. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2016;120(1):114–8.27046390
18 Van Hulle H, Vakaet V, Monten C, . Acute toxicity and health-related quality of life after accelerated whole breast irradiation in 5 fractions with simultaneous integrated boost. Breast (Edinburgh, Scotland). 2021;55:105–111.33401157
19 Schmeel LC, Koch D, Schmeel FC, . Acute radiation-induced skin toxicity in hypofractionated vs. conventional whole-breast irradiation: An objective, randomized multicenter assessment using spectrophotometry. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2020;146:172–179.32171945
20 Spooner D, Stocken DD, Jordan S, . A randomised controlled trial to evaluate both the role and the optimal fractionation of radiotherapy in the conservative management of early breast cancer. Clinical oncology (Royal College of Radiologists (Great Britain)). 2012;24(10):697–706.23036277
21 Versmessen H, Vinh-Hung V, Van Parijs H, . Health-related quality of life in survivors of stage I-II breast cancer: randomized trial of post-operative conventional radiotherapy and hypofractionated tomotherapy. BMC Cancer. 2012;12:495.23098579
22 Van Parijs H, Miedema G, Vinh-Hung V, . Short course radiotherapy with simultaneous integrated boost for stage I-II breast cancer, early toxicities of a randomized clinical trial. Radiation oncology (London, England). 2012;7:80.22656865
23 Shaitelman SF, Schlembach PJ, Arzu I, . Acute and Short-term Toxic Effects of Conventionally Fractionated vs Hypofractionated Whole-Breast Irradiation: A Randomized Clinical Trial. JAMA oncology. 2015;1(7):931–41.26247543
24 Shaitelman SF, Lei X, Thompson A, . Three-year outcomes with hypofractionated versus conventionally fractionated whole-breast irradiation: Results of a randomized, noninferiority clinical trial. Journal of Clinical Oncology. 2018;36(35):3495–3503.
25 Whelan TJ, Pignol J-P, Levine MN, . Long-term results of hypofractionated radiation therapy for breast cancer. The New England journal of medicine. 2010;362(6):513–20.20147717
26 Whelan T, MacKenzie R, Julian J, . Randomized trial of breast irradiation schedules after lumpectomy for women with lymph node-negative breast cancer. Journal of the National Cancer Institute. 2002;94(15):1143–50.12165639
27 Wang S-L, Fang H, Hu C, . Hypofractionated Versus Conventional Fractionated Radiotherapy After Breast-Conserving Surgery in the Modern Treatment Era: A Multicenter, Randomized Controlled Trial From China. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2020;38(31):3604–3614.32780661
28 Wang S-L, Fang H, Song Y-W, . Hypofractionated versus conventional fractionated postmastectomy radiotherapy for patients with high-risk breast cancer: a randomised, non-inferiority, open-label, phase 3 trial. The Lancet Oncology. 2019;20(3):352–360.30711522
29 Offersen BV, Alsner J, Nielsen HM, . Hypofractionated Versus Standard Fractionated Radiotherapy in Patients With Early Breast Cancer or Ductal Carcinoma In Situ in a Randomized Phase III Trial: The DBCG HYPO Trial. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2020;38(31):3615–3625.32910709
30 King MT, Link EK, Whelan TJ, . Quality of life after breast-conserving therapy and adjuvant radiotherapy for non-low-risk ductal carcinoma in situ (BIG 3-07/TROG 07.01): 2-year results of a randomised, controlled, phase 3 trial. The Lancet Oncology. 2020;21(5):685–698.32203696
31 Whelan TJ, Julian JA, Berrang TS, . External beam accelerated partial breast irradiation versus whole breast irradiation after breast conserving surgery in women with ductal carcinoma in situ and node-negative breast cancer (RAPID): a randomised controlled trial. Lancet. 2019;394(10215):2165–2172.31813635
32 Arsenault J, Parpia S, Goldberg M, . Acute Toxicity and Quality of Life of Hypofractionated Radiation Therapy for Breast Cancer. International journal of radiation oncology, biology, physics. 2020;107(5):943–948.32334033
33 Haviland JS, Owen JR, Dewar JA, . The UK Standardisation of Breast Radiotherapy (START) trials of radiotherapy hypofractionation for treatment of early breast cancer: 10-year follow-up results of two randomised controlled trials. The Lancet Oncology. 2013;14(11):1086–1094.24055415
34 Weng JK, Lei X, Schlembach P, . Five-Year Longitudinal Analysis of Patient-Reported Outcomes and Cosmesis in a Randomized Trial of Conventionally Fractionated Versus Hypofractionated Whole-Breast Irradiation. International journal of radiation oncology, biology, physics. 2021;111(2):360–370.33992718
35 Brunt AM, Haviland JS, Sydenham M, . Ten-Year Results of FAST: A Randomized Controlled Trial of 5-Fraction Whole-Breast Radiotherapy for Early Breast Cancer. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2020;38(28):3261–3272.32663119
36 Olivotto IA, Berrang T, Truong PT, . Interim cosmetic and toxicity results from RAPID: A randomized trial of accelerated partial breast irradiation using three-dimensional conformal external beam radiation therapy. Journal of Clinical Oncology. 2013;31(32):4038–4045.23835717
37 Meattini I, Di Brina L, Mangoni M, . Accelerated partial breast irradiation using intensity-modulated radiotherapy technique compared to whole breast irradiation for patients aged 70 years or older: subgroup analysis from a randomized phase 3 trial. Breast Cancer Research and Treatment. 2015;153(3):539–547.26350524
38 Meattini I, Lucidi S, Marrazzo L, . Accelerated partial-breast irradiation compared with whole-breast irradiation for early breast cancer: Long-term results of the randomized phase III APBI-IMRT-florence trial. Journal of Clinical Oncology. 2020;38(35):4175–4183.32840419
39 Widmark A, Gunnlaugsson A, Beckman L, . Ultra-hypofractionated versus conventionally fractionated radiotherapy for prostate cancer: 5-year outcomes of the HYPO-RT-PC randomised, non-inferiority, phase 3 trial. Lancet (London, England). 2019;394(10196):385–395.31227373
40 Dearnaley D, Syndikus I, Mossop H, . Conventional versus hypofractionated high-dose intensity-modulated radiotherapy for prostate cancer: 5-year outcomes of the randomised, non-inferiority, phase 3 CHHiP trial. The Lancet Oncology. 2016;17(8):1047–1060.27339115
41 Lee WR, Dignam JJ, Amin MB, . Randomized Phase III Noninferiority Study Comparing Two Radiotherapy Fractionation Schedules in Patients With Low-Risk Prostate Cancer. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2016;34(20):2325–32.27044935
42 Appelt AL, Vogelius IR, Farr KP, Khalil AA, Bentzen SM. Towards individualized dose constraints: Adjusting the QUANTEC radiation pneumonitis model for clinical risk factors. Acta oncologica (Stockholm, Sweden). 2014;53(5):605–12.23957623
43 Catton CN, Lukka H, Gu C-S, . Randomized Trial of a Hypofractionated Radiation Regimen for the Treatment of Localized Prostate Cancer. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2017;35(17):1884–1890.28296582
44 Fonteyne V, Sarrazyn C, Swimberghe M, . 4 Weeks Versus 5 Weeks of Hypofractionated High-dose Radiation Therapy as Primary Therapy for Prostate Cancer: Interim Safety Analysis of a Randomized Phase 3 Trial. International journal of radiation oncology, biology, physics. 2018;100(4):866–870.29485064
45 Houshyari M, Mofid B, Alavi Tabatabaee M, Taghizadeh-Hesary F, Bakhshandeh M. Acute toxicity of 4-week versus 5-week hypofractionated radiotherapy in localised prostate cancer. Journal of Radiotherapy in Practice. 2021.
46 Lam D, Wong K, Cheung M, . Prospective randomized phase II study of stereotactic body radiotherapy (SBRT) vs. conventional fractionated radiotherapy (CFRT) for Chinese patients with early-stage localized prostate cancer. Current Oncology. 2022;29(1):27–37.
47 Naismith O, Ostler P, van der Voet H, . Intensity-modulated fractionated radiotherapy versus stereotactic body radiotherapy for prostate cancer (PACE-B): acute toxicity findings from an international, randomised, open-label, phase 3, non-inferiority trial. The Lancet Oncology. 2019;20(11):1531–1543.31540791
48 Incrocci L, Wortel RC, Alemayehu WG, . Hypofractionated versus conventionally fractionated radiotherapy for patients with localised prostate cancer (HYPRO): final efficacy results from a randomised, multicentre, open-label, phase 3 trial. The Lancet Oncology. 2016;17(8):1061–1069.27339116
49 Arcangeli G, Saracino B, Gomellini S, . A prospective phase III randomized trial of hypofractionation versus conventional fractionation in patients with high-risk prostate cancer. International journal of radiation oncology, biology, physics. 2010;78(1):11–8.20047800
50 Karklelyte A, Valuckas KP, Griskevicius R, Janulionis E, Aleknavicius E. Acute toxicity and quality of life in high risk prostate cancer patients: Updated results of randomized hypofractionation trial. Reports of Practical Oncology and Radiotherapy. 2018;23(4):284–289.30090028
51 Norkus D, Miller A, Kurtinaitis J, . A randomized trial comparing hypofractionated and conventionally fractionated three-dimensional external-beam radiotherapy for localized prostate adenocarcinoma : a report on acute toxicity. Strahlentherapie und Onkologie : Organ der Deutschen Rontgengesellschaft [et al]. 2009;185(11):715–21.
52 Pollack A, Walker G, Horwitz EM, . Randomized trial of hypofractionated external-beam radiotherapy for prostate cancer. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2013;31(31):3860–8.24101042
53 Hoffman KE, Voong KR, Levy LB, . Randomized Trial of Hypofractionated, Dose-Escalated, Intensity-Modulated Radiation Therapy (IMRT) Versus Conventionally Fractionated IMRT for Localized Prostate Cancer. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2018;36(29):2943–2949.30106637
54 Lukka H, Hayter C, Julian JA, . Randomized trial comparing two fractionation schedules for patients with localized prostate cancer. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2005;23(25):6132–8.16135479
55 Wang MH, Vos LJ, Yee D, . Clinical Outcomes of the CHIRP Trial: A Phase II Prospective Randomized Trial of Conventionally Fractionated Versus Moderately Hypofractionated Prostate and Pelvic Nodal Radiation Therapy in Patients With High-Risk Prostate Cancer. Practical radiation oncology. 2021;11(5):384–393.33705985
56 Zhong Q-Z, Xia X, Gao H, . Hypofractionated versus conventionally fractionated image-guided volumetric-modulated arc radiotherapy for localized prostate cancer: a phase II randomized trial from China. Aging. 2021;13(5):6936–6944.33653964
57 Yeoh EE, Botten RJ, Butters J, Di Matteo AC, Holloway RH, Fowler J. Hypofractionated versus conventionally fractionated radiotherapy for prostate carcinoma: final results of phase III randomized trial. International journal of radiation oncology, biology, physics. 2011;81(5):1271–8.20934277
58 Fransson P, Nilsson P, Gunnlaugsson A, . Ultra-hypofractionated versus conventionally fractionated radiotherapy for prostate cancer (HYPO-RT-PC): patient-reported quality-of-life outcomes of a randomised, controlled, non-inferiority, phase 3 trial. The Lancet Oncology. 2021;22(2):235–245.33444529
59 de Vries KC, Wortel RC, Oomen-de Hoop E, Heemsbergen WD, Pos FJ, Incrocci L. Hyprofractionated Versus Conventionally Fractionated Radiation Therapy for Patients with Intermediate- or High-Risk, Localized, Prostate Cancer: 7-Year Outcomes From the Randomized, Multicenter, Open-Label, Phase 3 HYPRO Trial. International journal of radiation oncology, biology, physics. 2020;106(1):108–115.31593756
60 Arcangeli G, Saracino B, Arcangeli S, . Moderate Hypofractionation in High-Risk, Organ-Confined Prostate Cancer: Final Results of a Phase III Randomized Trial. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2017;35(17):1891–1897.28355113
61 Arcangeli S, Strigari L, Gomellini S, . Updated results and patterns of failure in a randomized hypofractionation trial for high-risk prostate cancer. International journal of radiation oncology, biology, physics. 2012;84(5):1172–8.22537541
62 Yeoh EE, Holloway RH, Fraser RJ, . Hypofractionated versus conventionally fractionated radiation therapy for prostate carcinoma: updated results of a phase III randomized trial. International journal of radiation oncology, biology, physics. 2006;66(4):1072–83.16965866
63 Avkshtol V, Ruth KJ, Ross EA, . Ten-Year Update of a Randomized, Prospective Trial of Conventional Fractionated Versus Moderate Hypofractionated Radiation Therapy for Localized Prostate Cancer. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2020;38(15):1676–1684.32119599
64 Aluwini S, Pos F, Schimmel E, . Hypofractionated versus conventionally fractionated radiotherapy for patients with prostate cancer (HYPRO): late toxicity results from a randomised, non-inferiority, phase 3 trial. The Lancet Oncology. 2016;17(4):464–474.26968359
65 Arcangeli G, Fowler J, Gomellini S, . Acute and late toxicity in a randomized trial of conventional versus hypofractionated three-dimensional conformal radiotherapy for prostate cancer. International journal of radiation oncology, biology, physics. 2011;79(4):1013–21.20447774
66 Hoffman KE, Voong KR, Pugh TJ, . Risk of late toxicity in men receiving dose-escalated hypofractionated intensity modulated prostate radiation therapy: results from a randomized trial. International journal of radiation oncology, biology, physics. 2014;88(5):1074–84.24661661
67 Bruner DW, Pugh SL, Lee WR, . Quality of Life in Patients With Low-Risk Prostate Cancer Treated With Hypofractionated vs Conventional Radiotherapy: A Phase 3 Randomized Clinical Trial. JAMA oncology. 2019;5(5):664–670.30763425
68 Shaikh T, Li T, Handorf EA, . Long-Term Patient-Reported Outcomes From a Phase 3 Randomized Prospective Trial of Conventional Versus Hypofractionated Radiation Therapy for Localized Prostate Cancer. International journal of radiation oncology, biology, physics. 2017;97(4):722–731.28244407
69 Wilkins A, Mossop H, Syndikus I, . Hypofractionated radiotherapy versus conventionally fractionated radiotherapy for patients with intermediate-risk localised prostate cancer: 2-year patient-reported outcomes of the randomised, non-inferiority, phase 3 CHHiP trial. The Lancet Oncology. 2015;16(16):1605–16.26522334
70 Wilson JM, Dearnaley DP, Syndikus I, . The Efficacy and Safety of Conventional and Hypofractionated High-Dose Radiation Therapy for Prostate Cancer in an Elderly Population: A Subgroup Analysis of the CHHiP Trial. International journal of radiation oncology, biology, physics. 2018;100(5):1179–1189.29722660
71 Qiu B, Li Q, Liu J, . Moderately Hypofractionated Once-Daily Compared With Twice-Daily Thoracic Radiation Therapy Concurrently With Etoposide and Cisplatin in Limited-Stage Small Cell Lung Cancer: A Multicenter, Phase II, Randomized Trial. International journal of radiation oncology, biology, physics. 2021;111(2):424–435.33992717
72 Nyman J, Hallqvist A, Lund J-A, . SPACE - A randomized study of SBRT vs conventional fractionated radiotherapy in medically inoperable stage I NSCLC. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2016;121(1):1–8.27600155
73 Roy S, Pathy S, Mohanti BK, . Accelerated hypofractionated radiotherapy with concomitant chemotherapy in locally advanced squamous cell carcinoma of lung: evaluation of response, survival, toxicity and quality of life from a Phase II randomized study. The British journal of radiology. 2016;89(1062):20150966.26986459
74 Iyengar P, Zhang-Velten E, Westover K, . Accelerated Hypofractionated Image-Guided vs Conventional Radiotherapy for Patients with Stage II/III Non-Small Cell Lung Cancer and Poor Performance Status: A Randomized Clinical Trial. JAMA Oncology. 2021.
75 Moon SH, Cho KH, Chung EJ, . A prospective randomized trial comparing hypofractionation with conventional fractionation radiotherapy for T1-2 glottic squamous cell carcinomas: results of a Korean Radiation Oncology Group (KROG-0201) study. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2014;110(1):98–103.24161568
76 Kodaira T, Kagami Y, Shibata T, . Results of a multi-institutional, randomized, non-inferiority, phase III trial of accelerated fractionation versus standard fractionation in radiation therapy for T1-2N0M0 glottic cancer: Japan Clinical Oncology Group Study (JCOG0701). Annals of Oncology. 2018;29(4):992–997.29401241
77 Tian Y-M, Zhao C, Guo Y, . Effect of total dose and fraction size on survival of patients with locally recurrent nasopharyngeal carcinoma treated with intensity-modulated radiotherapy: a phase 2, single-center, randomized controlled trial. Cancer. 2014;120(22):3502–9.25056602
78 Choudhury K, Sharma S, Maiti S, Roy C, Mallick C. A comparison of outcomes with ‘Christie Regimen’ and pure accelerated radiotherapy versus conventional radiation in locally advanced squamous cell carcinoma of head and neck: A randomized controlled study. Clinical Cancer Investigation Journal. 2012;1(3):118–126.
79 Bujko K, Pietrzak L, Kepka L, . Neoadjuvant treatment for unresectable rectal cancer: An interim analysis of a multicentre randomized study. Radiotherapy and Oncology. 2013;107(2):171–177.23590986
80 Bujko K, Wyrwicz L, Rutkowski A, . Long-course oxaliplatin-based preoperative chemoradiation versus 5 × 5 Gy and consolidation chemotherapy for cT4 or fixed cT3 rectal cancer: results of a randomized phase III study. Annals of oncology : official journal of the European Society for Medical Oncology. 2016;27(5):834–42.26884592
81 Erlandsson J, Holm T, Pettersson D, . Optimal fractionation of preoperative radiotherapy and timing to surgery for rectal cancer (Stockholm III): a multicentre, randomised, non-blinded, phase 3, non-inferiority trial. The Lancet Oncology. 2017;18(3):336–346.28190762
82 Zeman EM. The History and Radiobiology of Hypofractionation. In: Kaidar-Person, O., Chen, R. (eds) Hypofractionated and Stereotactic Radiation Therapy. 2018.
83 Nahum AE. The Radiobiology of Hypofractionation. Clinical Oncology. 2015;27:260–269.25797579
84 Andrade TRM, Fonseca MCM, Segreto HRC, Segreto RA, Martella E, Nazario ACP. Meta-analysis of long-term efficacy and safety of hypofractionated radiotherapy in the treatment of early breast cancer. The breast journal. 2019;48:24–31.
85 Hickey B, James M, Lehman M, . Hypofractionated radiation therapy for early breast cancer. Cochrane Database of Systematic Reviews. 2016(7).
86 Liu L, Yang Y, Guo Q, . Comparing hypofractionated to conventional fractionated radiotherapy in postmastectomy breast cancer: a meta-analysis and systematic review. Radiation Oncology. 2020;15.
87 Sayan M, Yehia ZA, Ohri N, Haffty BG. Hypofractionated Postmastectomy Radiation Therapy. Advances in radiation oncology. 2021;6.
88 Valle LF, Agarwal S, Bickel KE, Herchek HA, Nalepinski DC, Kapadia NS. Hypofractionated whole breast radiotherapy in breast conservation for early-stage breast cancer: a systematic review and meta-analysis of randomized trials. Breast Cancer Res Treat. 2017;162:409–417.28160158
89 Arcangeli G, Arcangeli S, Pinzi V, Benassi M, Benassi M, Strigari L. Optimal Scheduling of hypofractionated radiotherapy for localized prostate cancer: systematic review and metanalysis of randomized clinical trials. Cancer treatment reviews. 2018;70:22–29.30053726
90 Botrel TEA, Clark O, Pompeo ACL, . Hypofractionated external-beam radiation thearpy (HEBRT) versus conventional external-beam radiation (CEBRT) in patients with localized prostate cancer: a systematic review and meta-analysis. Core Evidence. 2013;8:1–13.23526383
91 Cao L, Yang Y-J, Li Z-W, . Moderate hypofractionated radiotherapy is more effective and safe for localized prostate cancer patients: a meta-analysis. Oncotarget. 2017;8(2):2647–2658.27926521
92 Carvalho IT, Baccaglini W, Claros OR, . Genitourinary and gastrointestinal toxicity among patients with localized prostate cancer treated with conventaional versus moderately hypofractionated radiation therapy: systematic review and meta-analysis. Acta Oncologica. 2018;57:1003–1010.29882448
93 Datta NR, Stutz E, Rogers S, Bodis S. Conventional Versus Hypofractionated Radiation Therapy for Localized or Locally Advanced Prostate Cancer: A Systematic Review and Meta-analysis along with Therapeutic Implications. International Journal of Radiation Oncology. 2017;99:573–589.
94 Ferella L, Limoncin E, Vittorini F, . Are we ready for a paradigm shift from high-dose conventional to moderate hypofractionated radiotherapy in intermediate-high risk prostate cancer? A systematic review of randmozed controlled trials with tiral sequential analysis. Critical reviews in oncology/hematology. 2019;139:75–82.31112885
95 Guo W, Sun Y-C, Bi J-Q, He X-Y, Xiao L. Hypofractionated radiotherapy versus conventional radiotherapy in patients with intermediate-to high-risk localized prostate cancer: a meta-analysis of randomized controlled trials. BMC Cancer. 2019;19.
96 Hickey B, James M, Daly T, Soh F, Jeffery M. Hypofractionation for clinically localized prostate cancer. Cochrane Database of Systematic Reviews. 2019(9).
97 Koontz BF, Bossi A, Cozzarini C, Wiegel T, D’Amico A. A Systematic Review of Hypofractionation for Primary Management of Prostate Cancer. European Urology 2015;68:683–691.25171903
98 Lehrer EJ, Kishan AU, Yu JB, . Ultrahypofractionated versus hypofractionated and conventionally fractionated radiation therapy for localized prostate cancer: A systematic review and meta-analysis of phase III randomized trials. Radiotherapy and Oncology. 2020;148:235–242.32505965
99 Morgan SC, Hoffman K, Loblaw A, . Hypofractionated Radiation Therapy for Localized Prostate Cancer: An ASTRO, ASCO, and AUA Evidence-Based Guideline. Journal of clinical oncology. 2018;36.
100 Royce TJ, Lee DH, Keum N, . Conventional Versus Hypofractionated Radiation Therapy for Localized Prostate Cancer: A Meta-analysis of Randomized Noninferiority Trials. European urology focus. 2019;5:577–584.29221876
101 Sanchez-Gomez LM, Polo-deSantos M, Rodriguez-Melcon JI, Angulo JC, Luengo-Matos S. Hypofractionated radiation therapy versus conventional radiation therapy in prostate cancer: A systematic review of its safety and efficacy. Actas urologicas espanolas. 2015;39:367–374.25660427
102 Siepe G, Buwenge M, Nguyen NP, . Postoperative Hypofractionated Radiation Therapy in Prostate Carcinoma: A Systematic Review. Anticancer research. 2018;38:1221–1230.29491044
103 Baillet F, Housset M, Maylin C, . The use of a specific hypofractionated radiation therapy regimen versus classical fractionation in the treatment of breast cancer: a randomized study of 230 patients. International journal of radiation oncology, biology, physics. 1990;19(5):1131–3.2254102
104 Das P, Das T, Jana A, Gupta P, Gupta P, Das S. Comparison of result and outcome of conventional and hypofractionated radiotherapy in post-operative breast cancer patients. International Journal of Medical Science and Public Health. 2018;7(6):452–456.
105 Hosseini S, Shahabadi M, Salek R, . Accelerated hypofractionated whole breast radiotherapy for early breast cancer; arandomized phase iii clinical trial. Acta Medica Iranica. 2019;57(11):645–652.
106 Hou H-L, Song Y-C, Li R-Y, . Similar Outcomes of Standard Radiotherapy and Hypofractionated Radiotherapy Following Breast-Conserving Surgery. Medical science monitor : international medical journal of experimental and clinical research. 2015;21:2251–6.26235604
107 Kalita AK, Bhattacharyya M, Jagtap VK, . Radiotherapy in Post Mastectomy High Risk Breast Cancer: Early results of a Prospective Study comparing Conventional versus Hypofractionated Radiotherapy. Journal of Medical Science and Clinical Research. 2018;6(7):743–751.
108 Kumbhaj P, Sharma R, Saini P, Patel P. Study of two different dose fractionation schedules of post mastectomy chest wall irradiation in carcinoma breast patients. International Journal of Medical Science and Public Health. 2013;2(4):1001–1005.
109 Maiti S, Meyur S, Mandal BC, Shenoi LR, Biswas S, Basu S. Comparison of conventional and hypofractionated radiation after mastectomy in locally advanced breast cancer: A prospective randomised study on dosimetric evaluation and treatment outcome. Journal of Radiotherapy in Practice. 2021;20(1):30–38.
110 Purohit R, Sharma N, Kumar R, Jakhar SL. Comparison of Acute Toxicities in Conventional and Hypofractionated Radiotherapy in Post-Mastectomy Breast Cancer. Journal of Medical Science and Clinical Research. 2016;4(6):10721–10724.
111 Rastogi K, Jain S, Bhatnagar AR, Bhaskar S, Gupta S, Sharma N. A Comparative Study of Hypofractionated and Conventional Radiotherapy in Postmastectomy Breast Cancer Patients. Asia-Pacific Journal of Oncology Nursing. 2017;5(1):107–113.
112 Li X, Sanz J, Foro P, . Long-term results of a randomized partial irradiation trial compared to whole breast irradiation in the early stage and low-risk breast cancer patients after conservative surgery. Clinical & translational oncology : official publication of the Federation of Spanish Oncology Societies and of the National Cancer Institute of Mexico. 2021;23(10):2127–2132.33880724
113 Rodriguez N, Sanz X, Dengra J, . Five-year outcomes, cosmesis, and toxicity with 3-dimensional conformal external beam radiation therapy to deliver accelerated partial breast irradiation. International journal of radiation oncology, biology, physics. 2013;87(5):1051–7.24161420
114 Shahid A, Athar MA, Asghar S, Zubairi T, Murad S, Yunas N. Post mastectomy adjuvant radiotherapy in breast cancer: a comparision of three hypofractionated protocols. JPMA The Journal of the Pakistan Medical Association. 2009;59(5):282–7.19438129
115 Swanick CW, Lei X, Shaitelman SF, . Longitudinal analysis of patient-reported outcomes and cosmesis in a randomized trial of conventionally fractionated versus hypofractionated whole-breast irradiation. Cancer. 2016;122(18):2886–94.27305037
116 Taher AN, El-Baradie MM, Essa H, Zaki OE, Ezzat S. Hypofractionation versus Conventional Fractionation Radiotherapy after Conservative Treatment of Breast Cancer: Early Skin Reactions and Cosmetic Results. Journal of the Egyptian National Cancer Institute. 2004;16(3):178–187.15959551
117 Yadav BS, Loganathan S, Sharma SC, Singh R, Dahiya D. Comparison of Toxicity and Cosmetic Outcomes After Accelerated Partial Breast Irradiation or Whole Breast Irradiation Using 3-Dimensional Conformal External Beam Radiation Therapy. Advances in Radiation Oncology. 2020;5(2):171–179.32280816
118 Zhao XB, Ren GS. Analysis of radiotherapy optimization regimens after modified radical mastectomy. European review for medical and pharmacological sciences. 2016;20(22):4705–4709.27906432
119 Zhao S, Huang F, Chen X, Cao X, Yu J, Liu Y. The long-term outcome of adjuvant hypofractionated radiotherapy and conventional fractionated radiotherapy after breastconserving surgery for early breast cancer: A prospective analysis of 107 cases. Journal of Thoracic Disease. 2017;9(10):3840–3850.29268393
120 Akakura K, Suzuki H, Ichikawa T, . A randomized trial comparing radical prostatectomy plus endocrine therapy versus external beam radiotherapy plus endocrine therapy for locally advanced prostate cancer: results at median follow-up of 102 months. Japanese journal of clinical oncology. 2006;36(12):789–93.17082219
121 Phase 1 clinical trial of stereotactic body radiation therapy concomitant with neoadjuvant chemotherapy for breast cancer. International Journal of Radiation Oncology Biology Physics. 2013;85(5):1193–1199.23332384
122 Aissa AB, Espeli V, Squiban D, . Phase i study of sorafenib combined with radiation therapy and temozolomide as first-line treatment of high-grade glioma. British Journal of Cancer. 2014;110(11):2655–2661.24786603
123 Alexidis P, Karatzoglou S, Dragoumis D, . Late results of a randomized trial on the role of mild hypofractionated radiotherapy for the treatment of localized prostate cancer. Journal of Cancer. 2020;11(5):1008–1016.31956347
124 Alexidis P, Tzitzikas I, Hatzimouratidis K, . The role of hypofractionated radiotherapy for the definitive treatment of localized prostate cancer: Early results of a randomized trial. Journal of Cancer. 2019;10(25):6217–6224.31772654
125 Dearnaley D, Syndikus I, Sumo G, . Conventional versus hypofractionated high-dose intensity-modulated radiotherapy for prostate cancer: preliminary safety results from the CHHiP randomised controlled trial. The Lancet Oncology. 2012;13(1):43–54.22169269
126 Wortel RC, Oomen-de Hoop E, Heemsbergen WD, Pos FJ, Incrocci L. Moderate Hypofractionation in Intermediate- and High-Risk, Localized Prostate Cancer: Health-Related Quality of Life From the Randomized, Phase 3 HYPRO Trial. International journal of radiation oncology, biology, physics. 2019;103(4):823–833.30458234
127 Marzi S, Benassi M, Landoni V, . Modeling of alphabeta for late rectal toxicity from a randomized phase II study: Conventional versus hypofractionated scheme for localized prostate cancer. Journal of Experimental and Clinical Cancer Research. 2009;28(1):117.19689825
128 Norkus D, Karklelyte A, Engels B, . A randomized hypofractionation dose escalation trial for high risk prostate cancer patients: interim analysis of acute toxicity and quality of life in 124 patients. Radiation oncology (London, England). 2013;8:206.24007322
129 Yeoh EEK, Fraser RJ, McGowan RE, . Evidence for efficacy without increased toxicity of hypofractionated radiotherapy for prostate carcinoma: early results of a Phase III randomized trial. International journal of radiation oncology, biology, physics. 2003;55(4):943–55.12605972
130 Aluwini S, Pos F, Schimmel E, . Hypofractionated versus conventionally fractionated radiotherapy for patients with prostate cancer (HYPRO): acute toxicity results from a randomised non-inferiority phase 3 trial. The Lancet Oncology. 2015;16(3):274–83.25656287
131 Norkus D, Miller A, Plieskiene A, Janulionis E, Valuckas KP. A randomized trial comparing hypofractionated and conventionally fractionated three-dimensional conformal external-beam radiotherapy for localized prostate adenocarcinoma: a report on the first-year biochemical response. Medicina (Kaunas, Lithuania). 2009;45(6):469–75.19605967
132 Pollack A, Hanlon AL, Horwitz EM, . Dosimetry and preliminary acute toxicity in the first 100 men treated for prostate cancer on a randomized hypofractionation dose escalation trial. International journal of radiation oncology, biology, physics. 2006;64(2):518–26.16242256
133 Gronberg BH, Halvorsen TO, Flotten O, . Randomized phase II trial comparing twice daily hyperfractionated with once daily hypofractionated thoracic radiotherapy in limited disease small cell lung cancer. Acta oncologica (Stockholm, Sweden). 2016;55(5):591–7.26494411
134 Singh AK, Gomez-Suescun JA, Stephans KL, . One Versus Three Fractions of Stereotactic Body Radiation Therapy for Peripheral Stage I to II Non-Small Cell Lung Cancer: A Randomized, Multi-Institution, Phase 2 Trial. International journal of radiation oncology, biology, physics. 2019;105(4):752–759.31445956
135 Slawson RG, Salazar OM, Poussin-Rosillo H, Amin PP, Strohl R, Sewchand W. Once-a-week vs conventional daily radiation treatment for lung cancer: final report. International journal of radiation oncology, biology, physics. 1988;15(1):61–8.2839442
136 Singh AK, Gomez-Suescun JA, Hermann GM, . One Versus Three Fractions of Stereotactic Body Radiation Therapy for Peripheral Stage I to II Non-Small Cell Lung Cancer: A Randomized, Multi-Institution, Phase 2 Trial. International Journal of Radiation Oncology Biology Physics. 2019;105(4):752–759.31445956
137 Bjordal K, Kaasa S, Mastekaasa A. Quality of life in patients treated for head and neck cancer: a follow-up study 7 to 11 years after radiotherapy. International journal of radiation oncology, biology, physics. 1994;28(4):847–56.8138437
138 Kachhwaha A, Jakhar S, Syiem T, Sharma N, Kumar H, Sharma A. Hypofractionated radiotherapy versus conventional radiotherapy in early glottic cancer T1-2N0M0: A randomized study. Journal of Cancer Research and Therapeutics. 2021;17(6):1499–1502.34916384
139 Tolia M, Kelekis N, Kouloulias V, . Radiobiological and quality of life study of conventional and accelerated fractionated radiotherapy in patients with head and neck squamous cell carcinoma: Correlation of efficacy with cell cycle analysis parameters. Head and Neck Oncology. 2013;5(4):36.
140 Yamazaki H, Nishiyama K, Tanaka E, Koizumi M, Chatani M. Radiotherapy for early glottic carcinoma (T1N0M0): results of prospective randomized study of radiation fraction size and overall treatment time. International journal of radiation oncology, biology, physics. 2006;64(1):77–82.16169681
141 Erlandsson J, Ahlberg M, Holm T, . Tumour regression after radiotherapy for rectal cancer - Results from the randomised Stockholm III trial. Radiotherapy and Oncology. 2019;135:178–186.31015165
142 Ansari N, Solomon MJ, Fisher RJ, . Acute Adverse Events and Postoperative Complications in a Randomized Trial of Preoperative Short-course Radiotherapy Versus Long-course Chemoradiotherapy for T3 Adenocarcinoma of the Rectum: Trans-Tasman Radiation Oncology Group Trial (TROG 01.04). Annals of surgery. 2017;265(5):882–888.27631775