# ACKNOWLEDGMENTS

The authors are grateful to the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Lindsay Puckett, MD
  National VA Radiation Oncology Quality Task Force
- Maria Kelly, MD
  Executive Director
  National Radiation Oncology Program
- Eva Katsoulakis, MD
  National VA Radiation Oncology Quality Task Force
- John Park, MD
  National VA Radiation Oncology Quality Task Force
- Abhishek Solanki, MD
  National VA Radiation Oncology Quality Task Force

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Sue Yom, MD, PhD, FASTRO
  Chief of the Radiation Oncology Head & Neck, Cutaneous, and Thoracic Services
  University of California San Francisco
- Howard M. Sandler, MD, MS
  Chair of the Department of Radiation Oncology
  Cedars-Sinai Medical Center
- Jennifer Wo, MD
  Radiation Oncologist
  Massachusetts General Hospital

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix C for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.