# DISCUSSION

Key Findings

- Despite many randomized trials enrolling individuals with different cancers, evidence was limited regarding the comparative effectiveness and harms of hypofractionation versus conventionally fractionated radiotherapy for definitive (non-palliative) therapy.
  ○ Most studies were not designed to evaluate the comparative effectiveness on overall or cancer specific survival. Few studies were sufficiently similar enough to permit pooling or assess consistency, replicability, and/or broader applicability.
- For breast cancer, moderate hypofractionation results in little to no difference in overall survival, disease-free survival, and local-regional recurrence; there were also generally no differences in treatment harms (with variable certainty for different harms).
- For individuals with prostate and rectal cancer, hypofractionation therapy probably results in little to no difference in overall survival, and may result in little to no difference in disease-free or progression-free survival versus conventionally fractionated radiotherapy.
  ○ Hypofractionation may result in little to no difference in treatment harms.
- For individuals with small cell lung cancer, hypofractionation may result in little to no difference in overall and progression-free survival over 15–36 months follow-up.
  ○ Evidence is generally very uncertain regarding comparative treatment harms.
- For non-small cell lung cancer, evidence from 1 small RCT suggests that SBRT may result in little to no difference in overall survival versus conventionally fractionated radiotherapy through 36 months.
  ○ Evidence is generally very uncertain regarding comparative treatment harms.
- For early stage glottic cancer, hypofractionation may result in little to no difference in overall and disease-free survival, and most harms; the evidence is mostly very uncertain for locally advanced or recurrent head and neck cancers.
- For breast cancer, evidence indicated no differences in comparative effects of moderate hypofractionation versus conventional radiotherapy across a variety of patient, tumor, and adjuvant treatment characteristics; few studies addressed these questions for other cancers.
- No RCTs evaluated bladder, pancreatic, melanoma, or non-melanoma skin cancers.
- Decisions to widely implement hypofractionated radiotherapy, especially in patients with cancers where there is little to no evidence, would require extrapolation of findings from this report to, or conduct of RCTs in, populations, tumors, and radiation therapy regimens not currently evaluated in RCTs.
- We found no data on cost, resource use, or access. Radiation treatment cost, duration, and access as well as patient burden are likely relevant factors influencing practice and policy decisions. While mean treatment duration and number of treatment days varied widely across cancers and treatment regimens, they typically ranged 2–3 weeks and 10–15 treatment days less with hypofractionation versus conventional radiation. Based on limited data, ultra-hypofractionation in selected cancers resulted in greater reductions in treatment duration and sessions versus conventional radiotherapy.

Table 15 Summary of Key Findings and Certainty of Evidence

Cancer Type | Follow-up | N (# Trials) | Certainty | Summary Statement
Overall Survival
Breast | 5-10 years | 9436 (7) | ⨁⨁⨁⨁; High | Hypofractionation results in little or no difference in overall survival.
Prostate | 3-10 years | 4988 (8) | ⨁⨁⨁◯; Moderate | Hypofractionation probably results in little or no difference in overall survival.
NSCLC: hypofractionation vs conventional | 1 year | 132 (2) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation in overall survival.
NSCLC: SBRT vs conventional | 3 years | 102 (1) | ⨁⨁◯◯; Low | SBRT may result in little to no difference in overall survival.
NSCLC: SABR vs conventional | 2 years | 101 (1) | ⨁⨁⨁◯; Moderate | SABR probably results in little to no difference in overall survival.
SCLC | 15-24 months | 218 (2) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference in overall survival.
Early stage glottic Cancer | 3 years | 516 (2) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference in overall survival.
Recurrent or locally advanced head & neck cancer | 5 years | 117 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation in overall survival.
Rectal | 3 years | 771 (2) | ⨁⨁⨁◯; Moderate | Hypofractionation probably results in little or no difference in overall survival.
Disease-free or Progression-free Survival
Breast | 5-10 years | 7574 (6) | ⨁⨁⨁⨁; High | Hypofractionation results in little or no difference in disease-free survival.
Prostate | 2-10 years | 1378 (6) | ⨁⨁◯◯; Low | Hypofractionation may result in little or no difference in biochemical recurrence-free survival.
Prostate | 2-10 years | 1521 (7) | ⨁⨁⨁◯; Moderate | Hypofractionation probably results in little or no difference in prostate cancer-specific survival.
NSCLC: hypofractionation vs conventional | 9-15 months | 132 (2) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation in progression-free survival.
NSCLC: SBRT vs conventional | 3 years | 102 (1) | ⨁⨁⨁◯; Moderate | SBRT probably result in little to no difference in progression-free survival.
SCLC | 3 years | 177 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference in progression-free survival.
Early stage glottic Cancer | 3 years | 516 (2) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference in progression-free survival.
Recurrent or locally advanced head & neck cancer | 5 years | 117 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation in progression-free survival.
Rectal | 3 years | 515 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in little or difference in disease-free survival.
Local-regional Recurrence
Breast | 5-10 years | 7948 (6) | ⨁⨁⨁⨁; High | Hypofractionation results in little or no difference in local-regional recurrence.
Any Toxicity
Breast | ≤3 months | 287 (1) | ⨁⨁⨁◯; Moderate | Hypofractionation probably results in less overall acute toxicity.
Breast | 6 months | 271 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference in overall late toxicity.
Skin Toxicity
Breast | 6 months (acute) | 1370 (5) | ⨁⨁◯◯; Low | Hypofractionation may result in little or no difference in acute skin toxicity.
Breast | 5-10 years (late) | 2054 (2) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference in late skin toxicity.
Pneumonitis
Breast | 6 months (acute) | 1549 (2) | ⨁⨁⨁⨁; High | Hypofractionation results in little or no difference in acute pneumonitis.
NSCLC: hypofractionation vs conventional | 1 year (acute and late) | 96 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference on acute and late pneumonitis.
NSCLC: hypofractionation vs conventional | 15-24 months (acute) | 36 (1) | ⨁⨁◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation on acute pneumonitis.
NSCLC: SABR/SBRT vs conventional | 2 years (acute and late) | 101 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of SABR on acute and late pneumonitis.
NSCLC: SABR/SBRT vs conventional | 1 year (acute and late) | 102 (1) | ⨁⨁◯◯; Low | SBRT may result in little to no difference in acute and late pneumonitis.
SCLC | 3 months (acute) | 177 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation on acute pneumonitis.
SCLC | 2 years (late) | 177 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation on late pneumonitis.
Gastrointestinal Toxicity
Prostate | 3-5 months (acute) | 6702 (10) | ⨁⨁⨁◯; Moderate | Hypofractionation probably results in little or no difference in acute GI toxicity.
Prostate | 2-9 years (late) | 4109 (9) | ⨁⨁⨁◯; Moderate | Hypofractionation probably results in little or no difference in late GI toxicity.
Genitourinary Toxicity
Prostate | 3-5 months (acute) | 6703 (10) | ⨁⨁⨁◯; Moderate | Hypofractionation probably results in little or no difference in acute GU toxicity.
Prostate | 2-9 years (late) | 5069 (9) | ⨁⨁⨁◯; Moderate | Hypofractionation probably results in little to no difference in late GU toxicity.
Cough
NSCLC: hypofractionation vs conventional | 1 year (acute and late) | 96 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in little or no difference in acute and late cough.
NSCLC: SABR/SBRT vs conventional | 2 year (acute and late) | 101 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of SABR on acute and late cough.
NSCLC: SABR/SBRT vs conventional | 1 year (acute and late) | 102 (1) | ⨁⨁◯◯; Low | SBRT may result in little to no difference in acute and late cough.
SCLC: hypofractionation vs hyperfractionation | 3 months (acute) | 177 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation on acute cough.
SCLC: hypofractionation vs hyperfractionation | 2 years (late) | 177 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation on late cough.
Esophagitis
NSCLC: hypofractionation vs conventional | 1 year (acute) | 36 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation on acute pharyngitis/esophagitis.
NSCLC: hypofractionation vs conventional | 1 year (acute and late) | 96 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference on acute and late esophagitis.
NSCLC: SABR/SBRT vs conventional | 2 year (acute and late) | 101 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of SABR on acute and late esophagitis.
NSCLC: SABR/SBRT vs conventional | 1 year (acute and late) | 102 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of SBRT on acute and late esophagitis.
SCLC: hypofractionation vs hyperfractionation | 2 years (acute) | 177 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effects of hypofractionation on acute esophagitis.
Acute Mucositis
Early stage glottic cancer (grade 3-4) | 3 months | 516 (2) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference in acute mucositis.
Recurrent or locally advanced head & neck cancer (grade 3) | 3 months | 117 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation in acute mucositis.
Acute Dysphagia
Early stage glottic cancer (grade 1-2) | 3 months | 360 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference in acute dysphagia.
Late Mucositis
Early stage glottic cancer | 5 years | 156 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in little to no difference in late mucositis.
Recurrent or locally advanced head & neck cancer (grade 3) | 11 months | 132 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in an increase in late mucositis.
Late Soft Tissue Necrosis
Early stage glottic cancer | 4.8 years | 360 (1) | ⨁⨁⨁◯; Moderate | Hypofractionation probably results in little to no difference in soft tissue necrosis.
Late Xerostomia
Recurrent or locally advanced head & neck cancer | 11-25 months | 249 (2) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation in late xerostomia.
Temporal Lobe Necrosis
Recurrent or locally advanced head & neck cancer | 25 months | 117 (1) | ⨁◯◯◯; Very Low | The evidence is very uncertain about the effect of hypofractionation on temporal lobe necrosis.
Acute Diarrhea
Rectal | <30 days | 515 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in a reduction in acute diarrhea.
Late Anal Incontinence
Rectal | >30 days | 256 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in little or no difference in late anal incontinence.
Late Bowel Obstruction
Rectal | >30 days | 256 (1) | ⨁⨁◯◯; Low | Hypofractionation may result in a reduction in late bowel obstruction.

Abbreviations. NSCLC=non-small cell lung cancer; SABR/SBRT=stereotactic ablative radiotherapy/stereotactic body radiation therapy; SCLC=small cell lung cancer.

Radiotherapy requires balancing tumor cell destruction with limiting normal tissue damage. Additionally, radiotherapy, as with all treatment options, should consider patient preferences and values, treatment burden, and costs. Hypofractionation regimens have seen a marked increase in use in large part due to advances in treatment technology over the last 20 years.^82^ Technological advancements on controlling dose delivery and planning of radiotherapy have increased the ability to deliver hypofractionation (ie, higher doses per fraction) in a safe manner.^83^

Our findings suggest that hypofractionation may result in little to no difference in efficacy and most harms, while reducing treatment duration and number of sessions when used as definitive therapy for individuals with breast and prostate. The evidence was more sparse and less consistent for adults with small cell and non-small cell lung cancer though generally indicate similar effects on overall and disease-free or progression-free survival and harms. Data are limited for head and neck and rectal cancer and we found no studies in adults with pancreatic, bladder, melanoma or non-melanoma skin cancers.

We found very limited evidence on whether comparative effectiveness and harms varied by patient and tumor characteristics. What evidence was available suggests that for use of the selected hypofractionation regimen may result in similar outcomes versus the comparator conventional radiotherapy approach regardless of stage. For breast and prostate cancer, the comparative effectiveness of a specific treatment regimen did not vary by tumor stage or patient characteristics. No studies directly addressed this for the other cancers; however, there were no clear patterns in differences in comparative effectiveness of hypofractionation when looking at trials focused on higher vs. lower stage cancer. Because many regimens were intentionally different and studies designed to address different regimens based on tumor type, stage or risk a higher level question could be: “does a hypofractionation regimen specifically designed based on tumor characteristic provide similar or superior outcomes to a comparably designed radiation therapy regimen given in a conventional manner?” While data are limited they suggest that studied hypofractionation regimens resulted in little to no difference in outcomes versus the selected conventional radiation therapy comparator regardless of stage or tumor risk.

As noted above, hypofractionation resulted in fewer treatment days and shorter treatment duration than conventional treatments despite fairly similar overall treatment doses. Differences varied by cancers and treatment regimens but ranged from about 10-15 treatment days less for hypofractionation compared to conventional radiation therapy. This reduce patient and care giver burden related to travel and attendance for therapy and increase patient access and health system capacity for radiation therapy appointments. Our results provide important information for clinicians, patients, health system decision makers, and clinical guideline groups. They also provide a basis for future research given the limitations of existing studies, the gaps in evidence, and the need to consider specific cancer and patient characteristics when developing individualized treatment recommendations.

In an effort to focus on evidence of the highest quality and lowest risk of bias, we restricted eligible studies to RCTs of hypofractionation for specific cancers. A number of the included studies were designed to evaluate non-inferiority for survival or recurrence outcomes; thus their goal was to investigate whether hypofractionation was not substantially worse than conventional radiotherapy. If there are no meaningful differences in effectiveness or harms between hypofractionation and conventional radiation therapy, hypofractionation may be preferred because it offers greater convenience for patients, and less resource use for health systems.

However, no eligible trials reported data on treatment costs or access; this information may be particularly useful to policymakers and operations leadership. Hypofractionation regimens were generally shorter and involved fewer number of treatment sessions, compared with conventional radiation therapy. This may indicate greater availability of treatment slots, although preparations and planning sessions may also be more extensive for hypofractionation techniques. Additionally, the ability to provide hypofractionation regimens may require that health systems make substantial upfront investment in new equipment and software, and staff training.

The majority of evidence in breast cancer compared moderate hypofractionation with conventional radiation therapy. This showed no differences in survival and recurrence, but that hypofractionation probably results in less overall acute toxicity. For prostate cancer, hypofractionation vs. conventional radiation therapy also had similar effects on survival and recurrence, as well as toxicity and harms Prior systematic reviews have examined hypofractionation for breast and prostate cancers. For breast cancer, these include Andrade, 2019,^84^ Hickey, 2016,^85^ Liu, 2020,^86^ Sayan, 2021,^87^ and Valle, 2017.^88^ They found similar results to our review in that overall survival outcome was not different between hypofractionation and conventional radiation therapy. Previous reviews on prostate cancer include Arcangelli, 2018,^89^ Botrel, 2013,^90^ Cao, 2017,^91^ Carvalho, 2018,^92^ Datta, 2017,^93^ Ferella, 2019,^94^ Guo, 2019,^95^ Hickey, 2019,^96^ Koontz, 2015,^97^ Lehrer, 2020,^98^ Morgan, 2018,^99^ Royce, 2019,^100^ Sanchez-Gomez, 2019,^101^ and Siepe, 2018.^102^ These previous reviews also found that overall survival and harms were similar for hypofractionation and conventional radiotherapy, once again in agreement with our findings. Several review authors^86,87,94,95,98,101^ also noted the need for longer follow-up periods and more evidence evaluating harms in future trials.

Studies were typically small in sample size and short in treatment duration and often not designed or intended to address survival or progression outcomes. For several cancers, including lung, head and neck, and rectal cancers there were few studies and reported outcomes. There were only 2 RCTs of rectal cancer and these were small in sample size, and participants differed in clinical characteristics that could influence the findings. While there were more RCTs capturing lung and head and neck cancer patient populations, we were unable to pool these results due to substantial differences in patient and disease characteristics, as well as treatment comparisons. For prostate cancer it is not surprising that there were no differences in survival between regimens given the indolent nature of most early stage prostate cancer and excellent outcomes and fewer harms with no definitive treatment (i.e. observation or active monitoring).

While some cancers had many eligible studies few were designed to adequately address outcomes of interest and provide at least moderate or high certainty of evidence regarding comparative effectiveness and harms of a specific radiation therapy regimen. Such evidence certainty is typically required for clinical guideline development, policy recommendations and practice implementation in most clinical situations. Despite this researchers rarely attempted to replicate prior findings. Published studies were infrequently clinically similar enough to permit pooling and often varied in the populations enrolled, interventions evaluated and outcomes reported. Thus, many of our findings and summary of evidence conclusions are necessarily limited based on few studies, small sample size and short follow-up duration for specific treatment regimens and cancer types/stages. For example, in lung cancer, certainty of evidence was either low or very low for all comparisons and all outcomes. Three of the 5 trials ended study enrollment early when they had only accrued ~50% of the anticipated enrollment goal. The small sample sizes and short trial durations lead to smaller event rates and thus, inadequate power to detect meaningful differences. This was a major concern that led to a reduction in the certainty of evidence. Larger trials of longer duration will be needed to better evaluate the comparative effectiveness of these radiation treatments for lung cancer.

Finally, the applicability of our findings beyond populations, cancers, and treatment regimens studied is not known. Such clinical variation makes policy decisions regarding system wide recommendations for broad implementation of hypofractionation radiotherapy as a preferred approach across and even within cancers challenging.

## LIMITATIONS

This review focused on specific cancers with the use of radiation therapy for curative intent with or without surgery and/or chemotherapy. Studies evaluating palliative therapies were excluded, and as such, extension of the report findings should not be made to these populations. The search was limited to publications in English; there may be relevant studies to the research questions that were missed due to this limitation.

Other limitations are mainly due to the existing data. For pancreatic, bladder and melanoma and nonmelanoma skin cancers we found no eligible studies. Except for breast and prostate cancer, most other cancers had few trials and these were generally small and short-term. The use of non-inferiority comparisons as the primary goal in multiple trials indicates a belief that hypofractionation regimens result in similar outcomes as conventional radiation therapy; in this case, the preference for hypofractionation treatment would be due to greater convenience and less resource use. However, smaller, potentially clinically meaningful, effects on survival and disease progression outcomes cannot be confidentally ruled out. Additionally, costs and access were not evaluated by eligible studies We also found little to no evidence to address our second key question whether comparative effectiveness and harms varied by patient and tumor characteristics. These factors increase challenges for clinicians, researchers and policy makers in applying our findings especially to patients, cancers and treatment regimens not directly studied.

## FUTURE RESEARCH

Randomized controlled trials of hypofractionation (moderate and ultrahypofractionation) compared with conventional radiation therapy are needed for most of the cancers addressed in this review, with the possible exception of breast and prostate cancers. However, even in breast and prostate cancer evidence certainty was often low or based on relatively short follow-up. Furthermore, harms outcomes data was sparse and more varied in definition. Consistency and standardization regarding outcomes measurement and reporting will aid in summarizing and assessing the certainty of evidence.

Effectively assessing differences in overall or disease specific survival likely requires large and longer-term studies. These requirements are practically relevant if trying to assess whether treatment effects vary by patient and tumor characteristics. However, such RCTs are expensive and the studied treatments may be outdated due to advances in diagnostic and treatment approaches. Therefore, it may be reasonable to first focus on important intermediate outcomes of effectiveness and treatment- harms. This is particularly so in breast and prostate cancer were survival outcomes are generally excellent with either regimen through 5-10 years; thus harms and patient care burden are likely more important treatment decision factors. For many patients and cancers, radiation treatment cost, duration, sessions, access, and patient burden are likely relevant factors influencing practice and policy decisions. More research focused on these outcomes will be needed.

## CONCLUSIONS

For individuals with breast, prostate, or rectal cancer, hypofractionation therapy probably results in little to no difference in overall survival; and may result in little to no difference in disease-free or progression-free survival versus conventional radiotherapy. Evidence is more limited for harms. Hypofractionation results in fewer treatment days and thus likely reduces patient and caregive burden and improves treatment access. RCTs are needed in all cancers but particularly among patients with pancreatic, melanoma, non-melanoma, head and neck, rectal, bladder, and lung cancer. There is little to no evidence to address whether comparative effectiveness and harms vary by tumor or patient characteristics.