# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 1) summarizes the results of the study selection process (full list of excluded studies available in Appendix B).

Figure 1 Literature Flowchart

## LITERATURE OVERVIEW

A total of 106 publications were included, comprising 71 trials across the 5 cancers of interest. Of the identified 71 trials, 46 were rated low or some concerns for RoB; characteristics for these trials are summarized in Table 3. No eligible trials were identified for bladder, pancreatic cancer, melanoma, or non-melanoma skin cancer.

The majority of trials rated low or some concerns for RoB compared hypofractionation to conventional radiotherapy, except for a small number of trials in breast, prostate, and lung cancer populations where ultra-hypofractionation was evaluated (Table 3). There was substantial variability in the hypofractionation and comparator treatment regimens and cancer characteristics for each cancer type. The majority of these trials evaluated breast or prostate cancer, 5 addressed lung cancer, 4 for head and neck, and only 2 for rectal cancer. A third of trials enrolled ≤ 500 participants or less. All enrolled populations with a median or mean age ≥ 45 years. All but 1 prostate cancer RCT enrolled men age ≥ 65 years. Trials conducted for breast and prostate cancer tended to have longer follow-up times of ≥ 5 years (range 5–10 years, k = 13 [76%] for breast and k = 10 [56%] for prostate). All lung and rectal cancer trials had ≤ 3 years of follow-up. While many studies reported overall or disease-specific survival, few were designed with these as their primary outcomes.

The remaining trials were assessed as high RoB; detailed results were not abstracted from these studies or included in the synthesis of findings. Study characteristics for trials rated high RoB are provided in Appendices D–H (by cancer type).

Table 3 Summary Characteristics of Included Studies Assessed as Low or Some Concerns for Risk of Bias

| Breast Cancer (Total=17) | Prostate Cancer (Total=18) | Lung Cancer (Total=5) | Other Cancers (Total=6)
Intervention vs comparator
Hypofractionation vs. conventional | 12 | 14 | 3 | 6
Ultra-hypofractionation vs. conventional | 2 | 2 | 2^*^ | –
Ultra-hypofractionation vs. hypofractionation | 3 | 2 | 1^*^ | –
Median length of follow-up
<5 years | 4 | 8 | 5 | 4
≥5 years | 13 | 10 | – | 2
Outcomes
Survival | 13 | 12 | 5 | 6
Harms | 11 | 17 | 3 | 5
Acute (≤90 days) | 11 | 15 | 3 | 5
Late (>90 days) | 6 | 12 | 3 | 5
Quality of life | 4 | 5 | 2 | –
Country
US/Canada | 2 | 4 | 1 | –
UK/Europe | 12 | 7 | 1 | 2
China | 2 | 2 | 1 | 1
Other | – | 2 | 2 | 3
Multi | 1 | 3 | – | –
Sample sizes (total N)
<100 | – | 4 | 2 | 1
100-500 | 5 | 7 | 3 | 4
501-1000 | 4 | 3 | – | 1
1,001-2,500 | 7 | 3 | – | –
>2,500 | 1 | 1 | – | –
Age (mean or median, years)
45-64 | 8 | 1 | 2 | 3
>65 | – | 14 | 2 | 2
Age categories only | 8 | – | – | –
NR | 1 | 3 | 1 | 1

Abbreviations. NR=not reported; UK=United Kingdom; US=United States.

Notes.

* One lung cancer trial compared ultra-hypofractionation (stereotactic ablation radiotherapy [SABR]) with either conventional or moderate hypofractionation.^10^

## BREAST CANCER

### Overview

We identified 32 eligible trials (45 publications) that evaluated hypofractionation for breast cancer. For detailed results on efficacy and harms, we focus here on 17 eligible trials (27 publications) with RoB ratings that were low or some concerns. Table 4 summarizes the characteristics of these trials, all of which enrolled middle-aged and older women (eg, mean or median age range 57–63 years) with breast cancer without distant metastases (ie, not stage IV). Most trials were conducted in Europe (k = 10),^11–22^ 1 trial was conducted in the US,^23,24^ 1 in Canada,^25,26^ 2 others in China,^27,28^ and 3 were in multiple countries.^29–31^ Detailed study characteristics, outcomes, and RoB ratings for all included trials are presented in Appendix D.

Most trials (k = 12) compared moderate hypofractionation with standard conventional whole breast radiation. The remaining 5 trials compared a variety of other radiation therapy schedules and techniques, including ultra-hypofractionation versus conventional or moderate hypofractionation and use of accelerated partial breast irradiation (APBI) in some of the hypofractionation arms.

Below, we first describe results for trials comparing moderate hypofractionation with conventional whole breast radiation. We performed quantitative meta-analyses for each prioritized outcome (when there were sufficient number of trials) and qualtitative synthesis otherwise; we also assessed COE. Following these results, we provide a qualitative synthesis of findings for trials involving other radiation treatments; we did not conduct meta-analyses due to the degree of variation in radiation schedules and techniques across these remaining studies.

Table 4 Summary Characteristics of Included Breast Cancer Trials with Low or Some Concerns for Risk of Bias

Study Characteristics | Number of Studies (Total=17^a^)
Radiation strategies compared
Hypofractionation vs conventional | 12
Ultra-hypofractionation vs conventional | 1
Ultra-hypofractionation vs hypofractionation | 2
Accelerated partial breast vs whole breast^b^ | 2
Median length of follow-up
<1 year | 2
1-5 years | 2
>5 years | 13
Cancer stage(s) of participants
I-II | 9^c^
I-III | 6
III | 1
DCIS only | 1^d^
Survival outcomes
Overall survival | 11
Disease-free survival | 6
Local recurrence | 9
Locoregional recurrence | 8
Harms outcomes
Overall toxicity (grade >2) | 3
Acute skin toxicity | 9
Acute pneumonitis | 3
Late skin toxicity | 3
Late pneumonitis | 1
Late lymphedema | 3
Quality of life outcome | 4

Abbreviations. DCIS=ductal carcinoma in situ; RCT=randomized controlled trial.

a 17 eligible trials, reported in 26 publications.

b The main comparison for 2 trials was between accelerated partial breast irradiation (APBII) and whole breast irradiation (WBI). One trial used conventional dosing for the WBI treatment,^14^ while the other used moderate hypofractionation dosing.^31^

c Three trials also included participants with DCIS.^23,24,29,31^

d One trial included participants with DCIS and meeting criteria for “increased risk of recurrence” (see Appendix D for detailed information).^30^

### Moderate Hypofractionation versus Conventional Whole Breast Radiation

Twelve trials evaluated moderate hypofractionation, consisting of 3–5 weeks of 13–16 daily treatments (total dose range 40.0–43.5 Gy, dose per fraction 2.65–2.9 Gy), compared with conventional radiotherapy of 5 weeks of 25 daily treatments (total dose 50.0 Gy, dose per fraction 2.0 Gy). Thus hypofractionation regimens typically resulted in approximately 10 fewer treatment days versus conventional radiotherapy. Other cancer therapies were commonly used in addition to radiation therapy: these included chemotherapy, hormone therapy, and trastuzumab. Most trials included participants with stage I–III (k = 5)^11–13,25–27,32,33^ or stage I–II (k = 5)^19–24,29,34^ breast cancer. Two of the latter trials also included participants with ductal carcinoma in situ (DCIS).^23,24,29,34^ Additionally, 1 trial focused solely on those with DCIS with a range of high-risk factors,^30^ and 1 trial on stage III only.^28^ Total sample sizes ranged from 121 to 2,327, with the largest being Standardisation of Breast Radiotherapy (START) trials A^11,33^ and B^12,33^ (N = 2,327 and 2,236, respectively). Median follow-up times ranged from less than 1 year to 16.9 years, with most having 5–0 years of follow-up (k = 8;^11–13,20,23–27,29,32–34^ START A and B with median of 9.3 and 9.9 years, respectively). Most of these trials had local or local-regional recurrence as the primary outcome (k = 7),^11,12,20,25–28,30,32,33^ while the remaining trials were primarily examining differences in cosmetic (k = 3)^13,23,24,29,34^ or toxicity outcomes (k = 2).^19,21,22^

#### Key Question 1

Table 5 provides the key findings and certainty of evidence for efficacy and harms in comparing moderate hypofractionation and conventional radiation therapy in the treatment of breast cancer. Of note, overall and disease-free survival were 80% or greater and local-regional recurrence less than 5% for both hypofractionation and conventional radiation therapy at 10 years follow-up. Any acute (but not any late) toxicity, grade ≥ 2, were less with hypofractionation.

Table 5 Certainty of Evidence for Moderate Hypofractionation versus Conventional Radiation Therapy for Breast Cancer Outcomes

Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Hypofractionation | Conventional | Difference | Certainty | What Happens
Overall survival (OS); Absolute effect size estimates based on control event rate at 6 and 9.9 years^*^; MCID: 5% difference | 5-9.9 years; N = 9436; (7 RCTs)^11,12,20,25–29,33^ | RR = 1.003; (0.99, 1.02) | 87.8%; (86.5, 89.2) | 87.5% | 6 years:; 0.3% more; (1.1 fewer to 1.7 more) | ⨁⨁⨁⨁; High | Hypofractionation results in little to no difference in overall survival.
Overall survival (OS); Absolute effect size estimates based on control event rate at 6 and 9.9 years^*^; MCID: 5% difference | 5-9.9 years; N = 9436; (7 RCTs)^11,12,20,25–29,33^ | RR = 1.003; (0.99, 1.02) | 82.9%; (81.6, 84.2) | 82.6% | 9.9 years:; 0.2% more; (1 fewer to 1.6 more) | ⨁⨁⨁⨁; High | Hypofractionation results in little to no difference in overall survival.
Disease-free survival (DFS); Absolute effect size estimates based on control event rate at 6 and 9.9 years^*^; MCID: 5% difference | 5-9.9 years; N = 7574; (6 RCTs)^11,12,20,26–28,33^ | RR = 1.007; (0.97, 1.04) | 85.8%; (82.9, 88.7) | 85.2% | 6 years:; 0.6% more; (2.3 fewer to 3.6 more) | ⨁⨁⨁⨁; High | Hypofractionation results in little to no difference in disease-free survival.
Disease-free survival (DFS); Absolute effect size estimates based on control event rate at 6 and 9.9 years^*^; MCID: 5% difference | 5-9.9 years; N = 7574; (6 RCTs)^11,12,20,26–28,33^ | RR = 1.007; (0.97, 1.04) | 80.5%; (77.8, 83.3) | 79.9% | 9.9 years:; 0.6 more; (2.2 fewer to 3.4 more) | ⨁⨁⨁⨁; High | Hypofractionation results in little to no difference in disease-free survival.
Local-regional recurrence (LRR); Absolute effect size estimates based on control event rate at 6 and 9.9 years^*^; MCID: 10% difference | 5-10 years; N = 7948; (6 RCTs)^11,12,20,27–29,33^ | RR = 0.98; (0.81, 1.17) | 3.2%; (2.6, 3.8) | 3.3% | 6 years:; 0.1% fewer; (0.6 fewer to 0.6 more) | ⨁⨁⨁⨁ High | Hypofractionation results in little to no difference in local-regional recurrence.
Local-regional recurrence (LRR); Absolute effect size estimates based on control event rate at 6 and 9.9 years^*^; MCID: 10% difference | 5-10 years; N = 7948; (6 RCTs)^11,12,20,27–29,33^ | RR = 0.98; (0.81, 1.17) | 4.7%; (3.9, 5.6) | 4.8% | 9.9 years:; 0.1% fewer; (0.9 fewer to 0.8 more) | ⨁⨁⨁⨁ High | Hypofractionation results in little to no difference in local-regional recurrence.
Any acute toxicity (grade ≥2); Absolute effect size estimates based on control event rate ≤3 months^†^; MCID: 10% difference | 3 months; N = 287; (1 RCT)^23^ | RR = 0.61; (0.50, 0.74) | 47.1%; (35.0, 59.2) | 78% | 30.8% fewer; (39.2 fewer to 20.6 fewer) | ⨁⨁⨁◯; Moderate^a^ | Hypofractionation probably results in less overall acute toxicity.
Any late toxicity (grade ≥2); Absolute effect size estimates based on control event rate at 6 months^†^; MCID: 10% difference | 6 months; N = 271; (1 RCT)^23^ | RR = 0.96; (0.67, 1.36) | 31.0%; (16.7, 45.3) | 32% | 1.4% fewer; (12.5 fewer to 9.7 more) | ⨁⨁◯◯; Low^a,c^,^b^ | Hypofractionation may result in little to no difference in overall late toxicity.
Acute skin toxicity (grade ≥2); Absolute effect size estimates based on control event rate at 3 months^‡^; MCID: 10% difference | 3 months; N = 1370; (5 RCTs)^19,22,23,27,32^ | RR = 0.56; (0.31, 0.999) | 4.1%; (2.3, 7.4) | 7.4% | 3.3% fewer; (5.1 fewer to 0 fewer) | ⨁⨁◯◯; Low^a,c^ | Hypofractionation may result in little to no difference in acute skin toxicity.
Late skin toxicity (grade ≥2); Risk ratios and absolute effect size estimates based on control event rate at 5 and 10 years^§^; MCID: 10% difference | 5-10 years; N = 2054; (2 RCTs)^25,28^ | RR = 0.94; (0.46, 1.96) | 3.1%; (1.5, 6.5) | 3.3% | 5 years:; 0.2% fewer; (1.8 fewer to 3.2 more) | ⨁⨁◯◯; Low^a,d^ | Hypofractionation may result in little to no difference in late skin toxicity.
Late skin toxicity (grade ≥2); Risk ratios and absolute effect size estimates based on control event rate at 5 and 10 years^§^; MCID: 10% difference | 5-10 years; N = 2054; (2 RCTs)^25,28^ | RR = 1.16; (0.63, 2.13) | 8.9%; (4.8, 16.5) | 7.7% | 10 years:; 1.2% fewer; (2.9 fewer to 8.8 more) | ⨁⨁◯◯; Low^a,d^ | Hypofractionation may result in little to no difference in late skin toxicity.
Acute pneumonitis (grade ≥2); Risk ratio and absolute effect size estimates based on control event rate at 3 months^‡^; MCID: 10% difference | 6 months; N = 1549; (2 RCTs)^27,28^ | RR = 0.63; (0.25, 1.61) | 1.9%; (0.8, 4.9) | 3.0% | 1.1% fewer; (2.3 fewer to 1.9 more) | ⨁⨁⨁⨁; High | Hypofractionation results in little to no difference in acute pneumonitis.

Notes. The risk in the intervention group (and its 95% confidence interval) is based on the assumed risk in the comparison group and the relative effect of the intervention (and its 95% CI).

* Estimated using data from the START B trial^12^

† Estimated using data from the NCT01266642 trial^23,24,34^

‡ Estimated using data from the NCT01413269 trial^27^

§ Estimated using data from the NCT00156052 trial^25,26,32^

GRADE Working Group grades of evidence

High certainty: we are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: we are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: we have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded one level for study limitations (studies with some concerns for risk of bias)

b Downgraded one level for imprecision (CI crossing MCID in one direction)

c Downgraded one level for inconsistency (variance of point estimates across studies)

d Downgraded one level for indirectness (1 of 2 studies did not report only grade 2+)

Abbreviations. CI=confidence interval; DFS=disease-free survival; LRR=local-regional recurrence; MCID=minimal clinically important difference; NR=not reported; OS=overall survival; RCT=randomized controlled trial; RR=risk ratio.

##### Survival & Recurrence Outcomes

Figure 2 Breast Cancer Overall Survival: Moderate Hypofractionation versus Conventional Radiation Therapy

Hypofractionation results in little to no difference in overall survival compared to conventional radiotherapy (high COE; Figure 2). Overall survival was reported by 7 trials (total N = 9,436);^11,12,20,25–29,32,33^ pooled estimate for RR was 1.003 (95% CI [0.99, 1.02]). All but 1 of these trials included breast cancer stages I–II, with 4 trials also including stage III.^11,12,26,27^ One trial focused on stage III cancer only (Spooner et al).^20,29^ The largest trials were START A and B, both including stages I–III cancer and conducted in the United Kingdom (UK).^11,12,33^ A third trial was also conducted in the UK,^20^ 2 trials in China,^27,28^ 1 in Canada,^26^ and 1 in multiple countries.^29^ Using the reported absolute survival rates from the START B trial,^12,33^ we estimated that the ARD comparing hypofractionation versus conventional radiation is 0.3% (95% CI [−1.1, 1.7]) at 6 years and 0.2% at 9.9 years (95% CI [−1, 1.6]). Although none of the trials evaluated overall survival as the primary outcome, there appeared to be sufficient follow-up (5–15 years median follow-up) and for a relatively large number of participants.

Figure 3 Breast Cancer Disease-free Survival: Moderate Hypofractionation versus Conventional Radiation Therapy

Moderate hypofractionation results in little to no difference in disease-free survival compared to conventional radiotherapy (high COE; Figure 3). Six^11,12,20,25–28,32,33^ of the 7 trials reporting overall survival also presented results on disease-free survival; data on 7,574 participants from these trials were pooled, giving an RR of 1.02 (95% CI [0.98, 1.07])). As above, we used the reported disease-free survival rates from START B to estimate the ARD as 2.0 (95% CI [−1.6, 5.8]) at 6 years and 1.9 (95% CI [−1.5, 5.4]) at 9.9 years. The main concern regarding these findings is the lack of precision in the pooled estimate, with the 95% CI crossing the MCID of 5% in 1 direction (although this was in favor of moderate hypofractionation).

Figure 4 Breast Cancer Local-regional Recurrence: Moderate Hypofractionation versus Conventional Radiation Therapy

There was also little to no difference in local-regional survival between conventional and hypofractionation (high COE; Figure 4). Six^11,12,20,27–29,33^ of the 7 trials reporting overall survival also reported rates of loco-regional recurrence. We pooled data from 7,948 women included in these 6 trials, finding an RR of 0.98 (95% CI [0.81, 1.17]). Once again, we used results from START B to estimate the ARD of −0.1% (95% CI [−0.6, 0.6]) at 6 years, and −0.1% (95% CI [−0.9, 0.8]) at 9.9 years.

Five trials (total N = 7,824) also reported results on local recurrence rates over a median follow-up range 5–10 years. All of these included breast cancer stages I–III.^11–13,25–27^ Four^11,12,25–27,33^ of the 7 trials that reported overall survival (described above) had local recurrence as the primary outcome. Once again, the largest of these were START A and B conducted in the UK.^11–13^ The fifth trial was the START Pilot, which was primarily examining cosmetic outcomes but also reported local recurrence.^13^ A sixth trial stated that the primary outcome will be local recurrence but has thus far only reported results on quality of life.^30^ No trial found a difference in local recurrence rates between moderate hypofractionation and conventional radiation therapy; absolute recurrence rates were 1–9% in the moderate hypofractionation arms.

##### Toxicity & Harms

Hypofractionation probably results in less overall acute toxicity, but no difference in late toxicity at 6 months, compared to conventional radiotherapy (moderate and low COE, respectively). Only 1 trial reported on overall acute and late toxicity, assessed with the Common Terminology Criteria for Adverse Events (CTCAE).^23^ This trial was conducted at MD Anderson in Texas and enrolled 287 women with DCIS or stage 1–II invasive breast cancer. The primary goal was to evaluate cosmetic outcomes at 3 years post-radiation. Rates of any acute toxicity grade ≥2 (during radiation or within 42 days post-radiation) were 47% (65/138) in the hypofractionation group and 78% (116/149) in the conventional radiation arm (p < 0.001). Late toxicity grade ≥2 (assessed at 6 months) were 31% (40/129) for the hypofractionation arm and 32% (46/142) for conventional radiation (p = 0.81). The main methodological limitations were unclear allocation concealment (not reported in paper), which was particularly concerning as there were imbalances in number of participants per arm and also in potentially important participant characteristics (eg, 74% vs 83 invasive cancer for conventional vs hypofractionation arms, respectively). These imbalances could have also occurred by chance, which is more likely to occur with the smaller sample size in this study.

Figure 5 Breast Cancer Acute Skin Toxicity: Moderate Hypofractionation versus Conventional Radiation Therapy

Hypofractionation may result in little to no difference in acute skin toxicity (low COE; Figure 5). Five trials (total n=1,370) assessed acute skin toxicity over a median follow-up of 4–8 weeks.^19,22,23,27,32^ Acute skin toxicity was evaluated by CTCAE or the Radiation Therapy Oncology Group (RTOG)/European Organisation for Research and Treatment of Cancer (EORTC) criteria. Three trials included breast cancer stages I–II^19,22,23^ and 2 trials included stages I–III.^27,32^ Two trials were conducted in Europe,^19,22^ 1 was conducted in the US,^23^ 1 was in China,^27^ and 1 was in Canada.^32^ Pooled analyses using data from these 5 trials gave an RR of 0.56 (95% CI [0.31, 0.999]). Using the reported absolute acute toxicity rates from the NCT01413269 trial (Wang et al),^27^ we estimated that the ARD is −3.3% (95% CI [−5.1, 0]) at 3 months, indicating fewer events in the hypofractionation arm. However, the CI crosses 0 and doesn’t exceed the pre-specified MCID of 10%. Additionally, there was inconsistency in estimates across studies and methodological concerns for some of the studies. These included issues with randomization and/or missing data from loss to follow-up.

Hypofractionation may result in little to no difference in late skin toxicity compared to conventional radiotherapy (low COE). Two trials (N = 1,683) evaluated late skin toxicity, both using RTOG/EORTC criteria; median follow-up was 5–10 years.^25,28^ One trial was conducted in Canada and included breast cancer stages I–III,^25^ while the other occurred in China and focused on stage III breast cancer.^28^ The Canadian trial found no differences in rates of grade 2–3 skin toxicity at 5 or 10 years (3% [14/449] and 9% [21/235] in the hypofractionation arm, 3% [14/424] and 8% [17/220] for conventional radiation; p-values not reported).^25^ The Chinese trial also reported no differences in toxicity at a median follow-up of 58 months; rates of grade 1–2 toxicity were 21% (86/401) in the hypofractionation arm and 22% (90/409) for conventional radiation (p = 0.67).^28^ There was also 1 participant with grade 3 toxicity in the hypofractionation arm and none in the conventional radiation group.^28^ Main concerns impacting the COE include missing data in 1 trial due to loss to follow-up (1,234 participants randomized at baseline, but only 873 at 5 years and 455 at 10 years with data on toxicity),^25^ and the difficulty of applying results reported as combined grade 1–2 toxicity in the other trial (when the outcome of interest is grade ≥ 2 toxicity).^28^

Hypofractionation results in little to no difference in acute pneumonitis compared to conventional radiotherapy (high COE). Two trials (total N = 1,549) evaluated acute pneumonitis, both using CTCAE.^27,28^ One trial included breast cancer stages I–III,^27^ while the other included stage III only.^28^ Both trials were conducted in China and reported no differences in acute pneumonitis between treatment arms. Rates of grade 2 acute pneumonitis were low, ranging 2–3% in the moderate hypofractionation arm. No grade 3 events were observed in either trial.

Only 1 trial reported results on late pneumonitis, finding no events of any grade in either arm.^23^

Several other adverse events were reported by trials comparing moderate hypofractionation with conventional radiation therapy. These included skin ulceration, lymphedema, and lung fibrosis. Detailed outcomes on toxicity and harms for these events (along with those described above) are found in Appendix Table 4.

##### Quality of Life

Three trials reported quality of life over follow-up periods of 2–3 years.^21,23,24,30^ One trial assessed quality of life using EORTC Quality of Life Questionnaire (QLQ-C30) and the Functional Assessment of Cancer Therapy General (FACT-G) and for Breast Cancer (FACT-B),^30^ while another trial used only EORTC QLQ-C30,^22^ and the third only FACT-G and FACT-B.^23,24^ None of these trials found differences in overall quality of life or global health status during follow-up. One trial also reported results for domains of functioning (eg, physical and emotional functioning), also finding no differences for domain-level scores.^22^ Detailed results for these trials are provided in Appendix Table 5.

#### Key Question 2

Six trials comparing moderate hypofractionation with conventional radiation performed subgroup analyses to assess moderation in effect by a variety of patient and disease characteristics.^11–13,25,27,29,33^ Most did not find any effect variation by these characteristics, although these trials may not have been sufficiently powered to detect subgroup effects across all these factors. The largest study involved post-hoc subgroup analyses of combined data from the 3 START trials (A, B, and pilot; N = 5,861).^33^ This showed that the treatment effects of moderate hypofractionation versus conventional radiation were similar irrespective of age, type of primary surgery, axillary node status, tumor grade, adjuvant chemotherapy use, or use of tumor bed boost.

Two of the other trials enrolled women with stages I–III cancer, and both determined that treatment effect on local recurrence was similar across variation in use of adjuvant chemotherapy and a variety of patient prognostic factors (age, cancer stage, tumor size, etc).^25,27^ However, 1 of these trials reported that hypofractionation compared to conventional may be less effective for those with high-grade tumors (hazard ratio [HR] = 3.08, 95% CI [1.22, 7.76]), compared to those with low or medium grades (HR = 0.70, 95% CI [0.31, 1.58], and HR = 0.57, 95% CI [0.29, 1.12], respectively; test for interaction p = 0.01).^25^ In the high-grade tumor group, hypofractionation treatment had a substantially higher local recurrence rate at 10 years (ARD 10.9%, 95% CI [−19, −3]).

The sixth trial included women with DCIS or invasive stage I–II breast cancer, and reported analyses examining treatment effects on local-regional recurrence separately for those with DCIS and invasive cancer.^29^ There were no differences in local-regional recurrence by treatment arm for the whole sample (HR = 0.90, 95% CI [0.51, 1.59]; risk difference [RD] = −0.3%, 95% CI [−2.3, 1.7]), or separately for those with invasive cancer (HR = 0.75, 95% CI [0.37, 1.49]; RD = −0.7%, 95% CI [−2.7, 1.3]), or DCIS only (HR = 1.40, 95% CI [0.49, 4.06]; RD = 1.6%, 95% CI [−5.6, 8.8]).

### Other Radiation Therapy Comparisons

Three trials compared ultra-hypofractionation (total doses 26–30 Gy, dose per fraction 5.2–6.0 Gy) with either moderate hypofractionation (total dose 40.0 Gy, dose per fraction 2.67 Gy)^16–18^ or conventional radiation.^15,35^ Two of these were conducted in the UK,^15–17,35^ and the other one was conducted in Belgium.^18^ Two other trials compared accelerated partial breast irradiation (APBI) to whole breast radiation, either moderate hypofractionation or conventional dosing. One of these was conducted in Italy, with the APBI arm receiving twice daily doses of 3.85 Gy per dose over 5–8 days, for a total dose of 38.5 Gy, while the whole breast radiation group received either moderate hypofractionation (daily dose of 2.65 Gy, total 42.5 Gy) or conventional radiation (daily dose 2.0 Gy, total 50 Gy).^31,36^ The other trial occurred in Canada and used intensity-modulated radiotherapy (IMRT) in the APBI arm (6 Gy per fraction non-consecutively over 2 weeks, total dose 30 Gy), compared with conventional whole breast radiation (2.0 Gy per dose, total 50 Gy).^14,37,38^ Four trials^14,15,18,31,35–38^ included women with stage I–II cancer (one of these also included DCIS),^31,36^ and the fifth enrolled stage I–III.^16,17^ The primary outcomes being evaluated were either local recurrence (k = 3)^16,17,31,36–38^ or cosmetic results (k = 2).^15,18,35^ Follow-up ranged from 6–10 years for 4 of these trials,^14–17,31,35–38^ whereas 1 trial reported only acute outcomes at 2–4 weeks post-radiation.^18^

#### Key Question 1

##### Survival & Recurrence Outcomes

Four of these trials reported overall survival and local recurrence rates, all finding no differences between treatment arms.^15,16,31,38^ Sample sizes were 520–4,096, and absolute overall survival rates were high (92–98%). Local recurrence rates were generally low across all studies (1.0–3.5%). Two trials evaluated ultra-hypofractionation versus moderate hypofractionation^16,17^ or conventional whole breast radiation.^15,35^ The other 2 compared APBI with either moderate hypofractionation or conventional whole breast radiation,^14,31,36–38^ as described above. Two of these trials also reported local-regional recurrence, also finding no difference between treatment arms; one compared ultra-fractionation with moderate hypofractionation to the whole breast (2.3% vs 3.2% at 5 years),^16^ and the other compared APBI with conventional whole breast radiation (3.5% vs 2.7% at 10 years).^38^ No trial reported disease-free survival. Detailed results on survival and recurrence outcomes are provided in Appendix Table 3.

##### Toxicity & Harms

All trials reported acute skin toxicity, which varied substantially across the different treatment arms. The trial comparing ultra-hypofractionation with conventional whole breast radiation reported lower rates in the ultra-hypofractionation arm (12% [27/217] versus conventional 46% [51/110]).^15^ The 2 trials comparing ultra-hypofractionation with moderate hypofractionation reported a wide range of results (ultra-hypofractionation 16–41% vs 12–55% moderate hypofractionation).^17,18^ In contrast, both trials examining APBI found lower rates of acute skin toxicity in the APBI arms (2–9%), compared with whole breast radiation (31–38%).^31,38^

The 2 trials evaluating ABPI both assessed acute and late overall toxicity.^14,38,31^ One of these used RTOG/EORTC criteria and defined acute as any event ≤ 6 months (and late after 6 months).^38^ The other trial used CTCAE and reported as acute any event ≤ 3 months.^31^ Both trials reported higher rates of acute toxicity in the whole breast radiation group (38–46%), compared with the ABPI arm (2–28%, p < 0.001, both studies). For late toxicity, 1 trial reported more toxicity in the whole breast radiation group (3% vs 0% in APBI, p = 0.02),^38^ while the other found more toxicity in the ABPI group (13% whole breast vs 33% APBI, p < 0.001).^31^ One of the APBI trials also reported late skin toxicity, finding no differences (0 APBI vs 0.4% whole breast).^38^ The other APBI trial evaluated acute pneumonitis, also finding no differences (0.2% APBI vs 0.8% whole breast).^31^ Detailed results on toxicity and harms are provided in Appendix Table 4.

##### Quality of Life

One trial that compared ultra-hypofractionation with moderate hypofractionation evaluated quality of life.^18^ This trial measured global health status using the EORTC QLQ-C30 and reported results favored hypofractionation (p = 0.005, results otherwise not reported).

#### Key Question 2

Both trials evaluating APBI reported analyses on subgroup effects related to local recurrence at 8–10 years, finding no differences for a variety of patient and disease characteristics.^14,31^ The factors included patient age, adjuvant therapy, invasive cancer versus DCIS, and tumor size and other characteristics. Although 1 of these was a relatively large trial (N = 2,135),^31^ it lacked sufficient power to examine subgroup effects for all of these characteristics.

## PROSTATE CANCER

### Overview

We identified 20 eligible trials (40 publications) that evaluated hypofractionation for prostate cancer. Of these, 18 trials (38 publications) were judged to have RoB ratings that were low or of some concerns and had outcomes data extracted. Table 6 provides an overview of trial characteristics. Sample sizes varied widely (range 40 to 3,216); 4 trials had a sample size > 1000.^39–43^ All trials included older males with histologically confirmed prostate cancer (reported mean and median ages ranged from 63–75). All but one trial enrolled men age ≥ 65 years. The majority of trials described their populations as clinically localized prostate cancer (k = 12). Risk levels of enrolled participants varied, with 6 trials including men with low or intermediate risk prostate cancer, 6 trials including intermediate to high risk prostate cancer, 2 trials only describing their populations as early-stage localized, and 4 only describing their populations as localized, and including low to high risk prostate cancer. The majority of trials (k = 13) compared hypofractionation (total dose range 52.2–72 Gy, dose per fraction 2.4–3.4 Gy, treatment duration: 3.5–6.5 weeks) to conventional fractionation (total dose range 64–80 Gy, dose per fraction 1.8–2.0 Gy, treatment duration: 6.5–8.4 weeks), (approximately 21 versus 38 treatments for hypofractionation versus conventional radiation therapy, respectively) while few compared hypofractionation (total dose 56 Gy, dose per fraction 3.5 Gy, treatment duration: 4 weeks) to hypofractionation (total dose range 67-70.2 Gy, dose per fraction 2.7 Gy, treatment duration: 5 weeks) (k = 2)^44,45^ or ultra-hypofractionation (total dose range 36.25–42.7 Gy, dose per fraction 6.1–7.25 Gy, treatment duration: 2–2.5 weeks) to conventional fractionation (total dose range 76–78 Gy, dose per fraction 2 Gy, treatment duration: 5–8 weeks) (k = 2).^39,46^ One trial compared ultra-hypofractionation (total dose 36.25 Gy, dose per fraction 7.25 Gy, treatment duration: 1–2 weeks) to a combined arm of conventional and hypofractionation (total dose range 62–78, dose per fraction 2–3.1 Gy, treatment duration: 4 weeks).^47^ The countries in which the trials were conducted varied greatly, with most trials having sites in Europe (k = 9)^39,40,43,44,47–51^ and North America (k = 7),^41,43,47,52–55^ and few with sites in China (k = 2),^46,56^ Iran (k = 1),^45^ Australia (k = 2)^43,57^ and New Zealand (k = 1).^40^ Only 4 trials were held in multiple countries.^40,43,47,58^ Ten RCTs reported follow-up of ≥ 5 years.

Detailed study characteristics, outcomes, and RoB ratings for all included trials are presented in Appendix E.

Table 6 Summary Characteristics of Included Prostate Cancer Trials Assessed as Low or Some Concerns Risk of Bias

| Number of Studies (Total=18)
Intervention vs. comparator
Hypofractionation vs conventional | 13
Hypofractionation vs hypofractionation | 1
Ultra-hypofractionation vs conventional | 2
Ultra-hypofractionation vs hypofractionation | 2
Median length of follow-up
<1 year | 4
1-5 years | 4
≥5 years | 10
Survival outcomes
Overall survival | 10
Prostate-specific survival | 8
Metastasis-free survival | 3
Biochemical recurrence-free | 6
Local recurrence | 3
Harms outcomes
Acute gastrointestinal | 14
Acute genitourinary | 15
Late gastrointestinal | 12
Late genitourinary | 12
Quality of life outcome | 5
Population classified as
Early-stage localized | 2
Localized (low to high risk) | 4
Low risk | 1
Low to intermediate risk | 4
Intermediate risk | 4
Intermediate to high risk | 3
High risk | 3

### Key Question 1

Table 7 provides the key findings and certainty of evidence for efficacy and harms in comparing hypofractionation and conventional radiation therapy in the treatment of prostate cancer.

Below, we provide more detailed information about each outcome and results for comparisons of other radiation strategies. Overall and disease-specific survival exceeded 90% at 5 years for both hypofractionation and conventional radiation therapy regimens with little to no differences in GI or GU toxicity.

Table 7 Certainty of Evidence for Moderate Hypofractionation versus Conventional Radiation Therapy for Prostate Cancer Outcomes

Outcome and Minimal Clinically Important Difference (MCID) | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% CI) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome and Minimal Clinically Important Difference (MCID) | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% CI) | Hypofractionation | Conventional | Difference | Certainty | What Happens
Overall survival (OS); Absolute effect size estimates based on control event rate at 5 years^*^; MCID: 5% difference | 3-10 years; N = 4988; (8 RCTs)^40,41,48,53–55,57,59–62^ | RR = 1.01; (0.98, 1.05) | 92.3%; (89.5, 95.9) | 91.4% | 0.9% more; (1.8 fewer to 4.6 more) | ⨁⨁⨁◯; Moderate^a^ | Hypofractionation probably results in little to no difference in overall survival.
Prostate cancer-specific Survival; Absolute effect size estimates based on control event rate at 5 years^†^; MCID: 5% difference | 2-10 years; N = 1521; (7 RCTs)^48,53–55,57,59–63^ | RR = 1.00; (0.99, 1.01) | 96.2%; (95.2, 97.1) | 96.2% | 0.0%; (1 fewer to 1 more) | ⨁⨁⨁◯; Moderate^a^ | Hypofractionation probably results in little to no difference in prostate cancer-specific survival.
Biochemical recurrence-free survival; Absolute effect size estimates based on control event rate at 5 years^†^; MCID: 5% difference | 2-10 years; N = 1378; (6 RCTs)^49,54–57,60,61,63^ | RR = 0.93; (0.85, 1.02) | 53.6%; (49, 58.8) | 57.7% | 4.0% fewer; (8.6 fewer to 1.2 more) | ⨁⨁◯◯; Low^a,b^ | Hypofractionation may result in little to no difference in biochemical recurrence-free survival.
Acute GI toxicity (grade ≥2); MCID: 10% difference | 3-5 months; N = 6702; (10 RCTs)^40,41,43,50,51,54–56,64,65^ | RR = 1.23; (1.03, 1.58) | 16.6%; (13.9, 21.3) | 13.5% | 3.1% more; (0.4 more to 7.8 more) | ⨁⨁⨁◯; Moderate^a^ | Hypofractionation probably results in little to difference in acute GI toxicity.
Acute GU toxicity (grade ≥ 2); MCID: 10% difference | 3-5 months; N = 6703; (10 RCTs)^40,41,43,50,51,54–56,64,65^ | RR = 1.01; (0.77, 1.32) | 28.4%; (21.6, 37.1) | 28.1% | 0.3% more; (6.5 fewer to 9 more) | ⨁⨁⨁◯; Moderate^a^ | Hypofractionation probably results in little to no difference in acute GU toxicity.
Late GI toxicity (grade ≥2); Absolute effect size estimates based on control event rate at 5 years^*^; MCID: 10% difference | 2-9 years; N = 4109; (9 RCTs)^40,41,43,52–56,60,64–66^ | RR = 1.11; (0.45, 2.57) | 4.2%; (1.7, 9.8) | 3.8% | 0.4% more; (2.1 fewer to 6 more) | ⨁⨁⨁◯; Moderate^a^ | Hypofractionation probably results in little to no difference in late GI toxicity.
Late GU toxicity (grade ≥2); Absolute effect size estimates based on control event rate at 5 years^*^; MCID: 10% difference | 2-9 years; N = 5069; (9 RCTs)^40,41,43,52–56,60,64–66^ | RR = 1.12; (0.98, 1.28) | 1.6%; (1.4, 1.8) | 1.4% | 0.2% more; (0 fewer to 0.4 more) | ⨁⨁⨁◯; Moderate^a^ | Hypofractionation probably results in little to no difference in late GU toxicity.

Notes. The risk in the intervention group (and its 95% confidence interval) is based on the assumed risk in the comparison group and the relative effect of the intervention (and its 95% CI).

* The comparison group is estimated based on the 5-year median data from the CHHiP trial.^40^

† The comparison group is estimated based on the 5-year median data from the Lukka trial.^54^

GRADE Working Group grades of evidence

High certainty: we are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: we are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: we have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded one level for study limitations

b Downgraded one level for imprecision (CI crossing MCID in one direction)

c Downgraded two levels for imprecision (CI crossing MCID in both directions)

Abbreviations. CI=confidence interval; GI= gastrointestinal; GU=genitourinary; MCID=minimal clinically important difference; RCT=randomized controlled trial; RR=risk ratio.

#### Overall Survival

There was probably little to no difference in overall survival between hypofractionation or conventional radiotherapy (RR = 1.01, 95% CI [0.98, 1.05]; Figure 6) (ARD = 0.9%, 95% CI [−1.8, 4.6] at a median follow-up of 5 years based on events in the conventional radiotherapy group of the CHHiP trial^40^; moderate COE). Hypofractionation was provided as total dose range of 52.5–72 Gy, dose per fraction 2.4–3.4 Gy, 21 treatment sessions, and conventional radiation therapy as total dose range 64–80 Gy, dose per fraction 1.8–2.0 Gy, 38 treatment sessions. Eight trials included overall survival as an outcome of interest in understanding the comparative effectiveness of hypofractionation versus conventional radiotherapy in the treatment of prostate cancer (Table 7).

Figure 6 Prostate Cancer Overall Survival: Hypofractionation versus Conventional

Two additional trials reported overall survival as an outcome of interest. Both compared ultra-hypofractionation (total dose range 36.25–42.7 Gy, dose per fraction 6.1–7.25 Gy) to conventional fractionation (total dose range 76–78 Gy, dose per fraction 2 Gy) (k = 2).^39,46^ Both trials reported there was no difference in overall survival at 1 year^46^ or at 5 years.^39^

#### Prostate-cancer-specific Survival

There was probably little to no difference in prostate-cancer-specific survival between hypofractionation and conventional radiotherapy (RR = 1.01, 95% CI [0.99, 1.02]; Figure 7; moderate COE). The estimated ARD is 0% (95% CI [−1.0, 1.0]) at a median follow-up of 5 years, using the reported event rates in the conventional radiotherapy group from the Lukka trial.^54^ Hypofractionation was provided at a total dose range of 52.5–72 Gy and dose per fraction of 2.4–3.4 Gy and conventional radiation therapy at a total dose range of 64–80 Gy, dose per fraction of 1.8–2.0 Gy. Seven trials included prostate-cancer-specific survival as an outcome of interest (Table 7).

Figure 7 Prostate-cancer-specific Survival: Hypofractionation versus Conventional

One additional trial reported 5-year prostate-cancer-specific survival as an outcome of interest. This trial compared ultra-hypofractionation (total dose 42.7 Gy, dose per fraction 6.1 Gy) to conventional fractionation (total dose 78 Gy, dose per fraction 2 Gy) and reported no difference.^39^

#### Biochemical Recurrence

There may be little to no difference in freedom from biochemical recurrence between hypofractionation (total dose range 52.5–70.2 Gy, dose per fraction 2.5–3.1 Gy) or conventional (total dose range 64–80 Gy, dose per fraction 2.0 Gy) radiotherapy (RR = 0.927, 95% CI [0.85, 1.02]; Figure 8) (ARD = −4.0%, 95% CI [−8.6, 1.2]; at a median follow-up of 5 years based on events in the conventional radiotherapy group of the Lukka trial^54^; low COE). Six trials included prostate cancer biochemical recurrence as an outcome of interest (Table 7).

Figure 8 Prostate Cancer Biochemical Recurrence: Hypofractionation versus Conventional

#### Acute GI

There was probably little to no difference in grade ≥ 2 acute GI toxicity between hypofractionation (total dose range 52.5–70 Gy, dose per fraction 2.5–3.4 Gy) or conventional (total dose range 66–80 Gy, dose per fraction 1.8–2.0 Gy) radiotherapy (RR = 1.28, 95% CI [1.03, 1.58]; Figure 9) (ARD = 3.1%, 95% CI [0.4, 7.8]; moderate COE). Ten trials captured acute GI outcomes when investigating hypofractionation versus standard of care in prostate cancer treatment (Table 7).

Figure 9 Prostate Cancer Acute GI: Hypofractionation versus Standard of Care

Four additional trials reported on acute GI toxicity as an outcome of interest.

One compared ultra-hypofractionation (total dose 36.25 Gy, dose per fraction 7.25 Gy) to conventional fractionation (total dose 76 Gy, dose per fraction 2 Gy) and found no difference between groups in regard to acute GI toxicities.^46^

Two trials compared hypofractionation (total dose 56 Gy, dose per fraction 3.5 Gy) to hypofractionation (total dose range 67–70.2 Gy, dose per fraction 2.7 Gy).^44,45^ Neither trial found a difference in acute GI toxicity between hypofractionation compared to a different dose of hypofractionation.

One trial compared ultra-hypofractionation (total dose 36.25 Gy, dose per fraction 7.25 Gy) to a combined arm of conventional and hypofractionation (total dose range 62–78, dose per fraction 2–3.1 Gy) and did not report any difference in acute GI toxicities.^47^

#### Acute GU

There was probably little to no difference in grade ≥ 2 acute GU toxicity between hypofractionation (total dose range 52.5–70 Gy, dose per fraction 2.5–3.4 Gy) or conventional (total dose range 66–80 Gy, dose per fraction 1.8–2.0 Gy) radiotherapy (RR = 1.010, 95% CI [0.773, 1.319]; Figure 10) (ARD = 0.3%, 95% CI [−6.5, 7.8]; moderate COE). Ten trials captured acute GU outcomes when investigating hypofractionation versus conventional radiotherapy in prostate cancer treatment (Table 7).

Figure 10 Prostate Cancer Acute GU: Hypofractionation versus Conventional

Five additional trials reported on acute GU toxicity as an outcome of interest.

Two compared ultra-hypofractionation (total dose range 36.25–42.7 Gy, dose per fraction 6.1–7.25 Gy) to conventional fractionation (total dose range 76–78 Gy, dose per fraction 2 Gy).^39,46^ One of these trials reported no difference in GU toxicities in ultra-hypofractionation compared to conventional fractionation,^39^ while one reported a statistically significant difference (3% vs 24%, p = 0.04), suggesting that ultra-hypofractionation may reduce acute GU toxicities^46^; however, this finding was not supported by other publications.

Two trials compared hypofractionation (total dose 56 Gy, dose per fraction 3.5 Gy) to hypofractionation (total dose range 67–70.2 Gy, dose per fraction 2.7 Gy).^44,45^ Neither trial found a difference in acute GU toxicity between hypofractionation compared to a different dose of hypofractionation.

One trial compared ultra-hypofractionation (total dose 36.25 Gy, dose per fraction 7.25 Gy) to a combined arm of conventional and hypofractionation (total dose range 62–78, dose per fraction 2–3.1 Gy) and did not report any difference in acute GU toxicities.^47^

#### Late GI

There was probably little to no difference in grade ≥ 2 late GI toxicity between hypofractionation (total dose range 52.5–70 Gy, dose per fraction 2.4–3.4 Gy) or conventional (total dose range 66–80 Gy, dose per fraction 1.8–2.0 Gy) radiotherapy (RR = 1.11, 95% CI [0.78, 1.58]; Figure 11) (ARD = 0.4%, 95% CI [−2.1, 6.0] at 5 years; moderate COE). Nine trials captured late GI outcomes when investigating hypofractionation versus standard of care in prostate cancer treatment (Table 7).

One additional trial reported late GI toxicity, but was excluded from this analysis (and subsequent certainty of evidence rating) due to authors only reporting cumulative risk as a percent and not providing number of events.^52^

Figure 11 Prostate Cancer Late GI: Hypofractionation versus Conventional

Two additional trials reported late GI toxicity as an outcome of interest. Both compared ultra-hypofractionation (total dose range 36.25–42.7 Gy, dose per fraction 6.1–7.25 Gy) to conventional fractionation (total dose range 76–78 Gy, dose per fraction 2 Gy) (k = 2).^39,46^ Both trials reported no difference in late GI toxicity at 1 year^46^ or at 5 years.^39^

#### Late GU

There was probably little to no difference in grade ≥ 2 late GU toxicity between hypofractionation (total dose range 52.5–70 Gy, dose per fraction 2.4–3.4 Gy) or conventional (total dose range 66–80 Gy, dose per fraction 1.8–2.0 Gy) radiotherapy (RR = 1.12, 95% CI [0.98, 1.28]; Figure 12) (ARD = 0.2, 95% CI [0, 0.4] at 5 years; moderate COE). Nine trials captured late GU outcomes when investigating hypofractionation versus standard of care in prostate cancer treatment (Table 7).

One additional trial reported late GU toxicity, but was excluded from this analysis (and subsequent certainty of evidence rating) due to authors only reporting cumulative risk as a percent and not providing number of events.^52^

Figure 12 Prostate Cancer Late GU: Hypofractionation versus Conventional

Two additional trials reported late GU toxicity as an outcome of interest. Both compared ultra-hypofractionation (total dose range 36.25–42.7 Gy, dose per fraction 6.1–7.25 Gy) to conventional fractionation (total dose range 76–78 Gy, dose per fraction 2 Gy).^39,46^ One trial reported a statistically significant difference between the ultra-hypofractionation group and the conventional group in late GU toxicity at 1 year follow-up (6.1% vs 2.4%, respectively; p = 0.004); however, at 5 years follow-up, no difference was found (4.5% vs 4.8%; p = 1.00).^39^ The second trial reported no difference at 1 year post-treatment.^46^

#### Local Recurrence

Three trials reported on local recurrence as an outcome of interest.^49,54,61,63^ All 3 compared hypofractionation (total dose range 52.5–70.2 Gy, dose per fraction 2.6–3.1 Gy) to conventionally fractionated radiotherapy (total dose range 66–80 Gy, dose per fraction 2 Gy). All 3 trials reported no difference between groups in regard to local recurrence at 3 years,^49^ 5 years,^54^ 5.8 years,^61^ or 10 years post-treatment.^63^

#### Metastases

Three trials reported on metastases as an outcome of interest.^49,54,61,63^ All 3 compared hypofractionation (total dose range 52.5–70.2 Gy, dose per fraction 2.6–3.1 Gy) to conventionally fractionated radiotherapy (total dose range 66–80 Gy, dose per fraction 2 Gy). All 3 trials reported no difference between groups in regard to metastases at 3 years,^49^ 5 years,^54,61,63^ or 10 years post-treatment.^63^

#### Quality of Life

Five trials reported on an overall, or global, quality of life (QoL) measure using a validated instrument.^47,58,67–69^ There was variability in the measures used to assess QoL across trials, and measures used included the European Organization for Research and Treatment of Cancer Quality of Life Questionnaire (EORTC QLQ-30), Extended Prostate Cancer Index (EPIC), International Prostate Symptom Score (IPSS), EuroQoL5, Functional Assessment of Cancer Therapy-Prostate (FACT-P), Short Form Survey (SF)-12, and and SF-36. Three trials were comparisons of hypofractionation (total dose range 60–70 Gy, dose per fraction 2.5–3 Gy) to conventional fractionation (total dose range 73.8–76 Gy, dose per fraction 1.8–2 Gy).^67–69^ One trial compared ultra-hypofractionation (total dose 42.7, dose per fraction 6.1) to conventional radiotherapy (total dose 78 Gy, dose per fraction 2 Gy),^58^ and the remaining trial compared ultra-hypofractionation (total dose 36.25 Gy, dose per fraction 7.25 Gy) to a combined arm of conventional and hypofractionation (total dose range 62–78, dose per fraction 2–3.1 Gy). None of the 5 trials identified any differences in quality-of-life scores between groups on any of the measures used, at any time point during the trial (follow-up ranged from 6 months to 6 years).

### Key Question 2

Of the included trials, 1 provided stratified analyses of harms (acute GI and acute GU) by age subgroups.^40,70^ In a secondary analysis of the data from the Conventional of Hypofractionated High Dose Intensity Modulated Radiotherapy for Prostate Cancer (CHHiP) trial,^40^ authors reported no difference in acute GI or acute GU in patients treated with hypofractionation (total dose 60 Gy, dose per fraction 3 Gy) compared to conventional fractionation (total dose 74 Gy, dose per fraction 2 Gy) when stratified by participants greater or less than 75 years old.^70^

Three trials limited enrollment to men with high-risk disease. Comparative effects and harms appeared similar. Two trials compared ultra-hypofractionation to conventional radiotherapy. Comparative results appeared similar.

## LUNG CANCER

### Overview

Of 8 eligible trials, 5 were assessed as low and some concerns for RoB.^10,71–74^ Table 8 provides summary characteristics of the included lung cancer studies. A more expansive summary characteristics table can be found in Appendix Table 12. Four of these trials^10,72–74^ evaluated non-small cell lung cancer (NSCLC), while the remaining trial^71^ enrolled individuals with small cell lung cancer (SCLC). Trials were conducted in the United States,^74^ Scandinavia,^72^ India,^73^ China,^71^ and Australia and New Zealand.^10^ Variation in lung cancer populations, stage of cancer, and radiotherapy comparisons precluded meta-analyses; we provide a narrative summary.

Of the 4 trials evaluating NSCLC, 2 compared hypofractionation versus conventional radiotherapy.^73,74^ In Roy et al (N = 36; stage IIIA–IIIB), 1 group received conventional radiotherapy to a total dose of 60 Gy in 30 fractions over 6 weeks compared to another group that received 48 Gy in 20 fractions over 4 weeks. In the second trial, Iyengar et al (N = 96, stage II–III) compared an experimental hypofractionated image-guided radiotherapy (IGRT) of 60 Gy in 15 fractions over 3 weeks versus conventionally fractionated radiotherapy (CFRT) of 60 Gy in 30 fractions over 6 weeks. Roy et al had a median follow up period of 15 months, and Iyengar et al had a median follow up of 8.7 months.

The other 2 trials compared SBRT/SABR to moderate hypofractionation or conventional radiotherapy for NSCLC.^10,72^ Ball et al^10^ enrolled adults (N = 101) with T1-T2a disease and compared SABR (48–54 Gy total dose, consisting of either 4 treatments of 12 Gy each or 3 sessions of 18 Gy) with a standard radiotherapy of 66 Gy in 33 daily fractions or 50 Gy in 20 daily fractions, depending on institutional preference. Nyman et al^72^ enrolled adults (N = 102) with stage I disease and compared total dose 66 Gy (22 Gy per fraction, 3 fractions over 1 week) versus conventional radiotherapy with total dose 70 Gy (2.0 Gy per fraction for 5 days a week for 7 weeks). Ball et al had a median follow-up period of 2.6 years for SABR and 2.1 years for the comparator arm, and Nyman et al had a median follow up of 3.1 years.

Trials of radiotherapy for NSCLC had a variety of primary endpoints, though all were small in size and relatively short in follow-up duration. Ball et al and Roy et al both specified local treatment failure or a local-regional response rate as the primary outcomes, while Nyman et al indicated progression-free survival and Iyengar et al specified overall survival (at 1 year).^10,72–74^

The single SCLC trial^71^ compared 2 different chemotherapy and concurrent thoracic radiation therapy regimens (CCTRT): once-daily CCTRT at 65 Gy in 26 daily fractions for 5 days a week over 36 days versus twice daily CCTRT at 45 Gy in 30 twice-daily fractions, with an interfractional interval of at least 6 hours, for 5 days a week over 19 days. The trial analyzed data from 182 patients (170, 93%; stage IIIA-B) with a median follow up of 24.3 months. The primary outcome was progression-free survival.^71^

Detailed study characteristics, outcomes, and RoB ratings for all included trials are presented in Appendix F.

Table 8 Summary Characteristics of Lung Cancer Studies Assessed as Low or Some Concerns Risk of Bias

| Number of Studies (Total=5)
Intervention vs comparator
Hypofractionation vs conventional | 2
SBRT/SABR vs conventional | 2
hypofractionation vs hyperfractionation | 1
Sub-cancer type
Small cell lung cancer (SCLC) | 1
Non-small cell lung cancer (NSCLC) | 4
Median follow-up:
<1 year | 1
1-2 years | 3
≥3 years | 1
Survival outcomes
Overall survival | 5
Lung cancer-specific survival | 1
Progression-free survival | 2
Harms outcomes
Acute cough | 4
Acute esophagitis | 5
Acute pneumonitis | 5
Late cough | 4
Late esophagitis | 3
Late pneumonitis | 4
Quality of life outcome | 2
Cancer stage
I | 2
I-III | 1
II-III | 1
III | 1

### Key Question 1

Tables 10 through 12 provide the key findings and certainty of evidence for efficacy and harms in comparing hypofractionation or SABR/SBRT to conventional radiation therapy or hyperfractionation in the treatment of non-small cell or small cell lung cancer. As there were fewer than 4 trials in each of these groups, we did not pool outcomes using meta-analyses. Additionally, authors reported outcomes at different time points and levels of severity, further limiting the degree to which they could be grouped in the certainty of evidence assessments. We describe these results in greater detail below. In general, given the very low certainty of evidence, we are uncertain about the comparative effectiveness and harms of hypofractionation versus conventional radiation therapy for individuals with non-small cell or small cell lung cancer.

Table 9 Certainty of Evidence for Hypofractionation versus Conventional Radiation Therapy for NSCLC Lung Cancer Outcomes

Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Hypofractionation | Conventional | Difference | Certainty | What Happens
Overall survival (OS); MCID: 5% difference | 1 year; N = 132; (2 RCTs)^73,74^ | Unable to assess^*^ | 75% | 52% | 23% more | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain about the effect of hypofractionation on overall survival.
Overall survival (OS); MCID: 5% difference | 1 year; N = 132; (2 RCTs)^73,74^ | Unable to assess^*^ | 37.7%; (24.2, 51.0%) | 44.6% | 6.9% fewer | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain about the effect of hypofractionation on overall survival.
Overall survival (OS); MCID: 5% difference | Median length of time; N = 132; (2 RCTs)^73,74^ | Unable to assess^*^ | 24.73 months | 12.33 months | 12.4 months more | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain about the effect of hypofractionation on overall survival.
Overall survival (OS); MCID: 5% difference | Median length of time; N = 132; (2 RCTs)^73,74^ | Unable to assess^*^ | 8.2 months; (5.4, 12.4) | 10.6 months | 2.4 months fewer | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain about the effect of hypofractionation on overall survival.
Progression-free survival (PFS); MCID: 5% difference | Median length of time; N = 132; (2 RCTs)^73,74^ | Unable to assess^*^ | 17 months | 5.36 months | 11.64 months more | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain about the effect of hypofractionation on progression-free survival.
Progression-free survival (PFS); MCID: 5% difference | Median length of time; N = 132; (2 RCTs)^73,74^ | Unable to assess^*^ | 6.4 months; (4.1, 7.8) | 7.3 months | 0.9 months fewer | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain about the effect of hypofractionation on progression-free survival.
Acute and Late Cough (grade ≥ 2); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 10% difference | 1 year; N = 96; (1 RCT)^74^ | RR = 0.33; (0.04 to 3.03) | 2.1%; (0.2, 19.8) | 6.5% | 4.4% fewer; (6.3 fewer to 13.3 more) | ⨁⨁◯◯; Low^c,d^ | Hypofractionation may result in little to no difference on acute and late cough.
Acute Pharyngitis/esoph agitis (grade ≥ 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^‡^; MCID: 5% difference | 1 year; N = 36; (1 RCT)^73^ | RR = 0.33; (0.04 to 2.91) | 5.6%; (0.6, 48.5) | 16.7% | 11.1% fewer; (16 fewer to 31.8 more) | ⨁◯◯◯; Very low^b,c^ | The evidence is very uncertain about the effect of hypofractionation on acute pharyngitis/esophagitis.
Acute and late esophagitis (grade ≥ 2); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 10% difference | 1 year; N = 96; (1 RCT)^74^ | RR = 2.21; (0.84, 5.79) | 24.0%; (9.2, 62.9) | 10.9% | 13.1% more; (1.7 fewer to 52 more) | ⨁⨁◯◯; Low^b,c^ | Hypofractionation may result in little to no difference on acute and late esophagitis.
Acute pneumonitis (grade ≥ 3); Risk ratio and absolute effect size months estimates based on control event rate from 1 trial^‡^; MCID: 5% difference | 15-24 month; N = 36; (1 RCT)^73^ | RR = 0.53; (0.02, 14.79) | 2.9%; (0.1, 82.2) | 5.6% | 2.6% fewer; (5.5 fewer to 76.6 more) | ⨁◯◯◯; Very low^b,c^ | The evidence is very uncertain about the effect of hypofractionation on acute pneumonitis.
Acute and Late Pneumonitis (grade ≥ 2); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 10% difference | 1 year; N = 96; (1 RCT)^74^ | RR = 1.23; (0.29, 5.19) | 8.0%; (1.9, 33.8) | 6.5% | 1.5% more; (4.6 fewer to 27.3 more) | ⨁⨁◯◯; Low^b,c^ | Hypofractionation may result in little to no difference on acute and late pneumonitis.

Notes. The risk in the intervention group (and its 95% confidence interval) is based on the assumed risk in the comparison group and the relative effect of the intervention (and its 95% CI).

* Study authors did not provide count level data to allow for calculation of a relative effect.

† Estimated using data from Iyengar et al.^74^

‡ Estimated using data from Roy et al.^73^

GRADE Working Group grades of evidence

High certainty: we are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: we are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: we have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded one level for inconsistency (variance of point estimate across studies)

b Downgraded one level for imprecision (CI crossing MCID in one direction)

c Downgraded one level for indirectness (acute and late harms grouped together or study did not include grade 2 harms)

d Downgraded one level for study limitations (small n, short follow up, or no events)

Abbreviations. CI=confidence interval; PFS=progression-free survival; MCID=minimal clinically important difference; NR=not reported; OS=overall survival; RCT=randomized controlled trial; RR=risk ratio.

Table 10 Certainty of Evidence for SBRT/SABR versus Conventional Radiation Therapy for NSCLC Lung Cancer Outcomes

Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | SBRT/SABR | Conventional | Difference | Certainty | What Happens
Overall survival; (OS); MCID: 5% difference | 2 years; N = 101; (1 RCT)^10^ | Unable to assess^*^ | 77%; (67, 88) | 59% | 18% more * | ⨁⨁⨁◯; Moderate^b^ | SABR probably results in a better overall survival.
Overall survival; (OS); MCID: 5% difference | 3 years; N = 102; (1 RCT)^72^ | Unable to assess^*^ | 54%^*^ | 59%^*^ | 5% fewer^*^ | ⨁⨁◯◯; Low^a,b^ | SBRT may result in little to no difference in overall survival.
Progression-free survival (PFS); MCID: 5% difference | 3 years; N = 102; (1 RCT)^72^ | Unable to assess^*^ | 42%^*^ | 42%^*^ | 0%^*^ | ⨁⨁⨁◯; Moderate^b^ | SBRT probably results in little to no difference in progression-free survival.
Lung cancer-specific survival; MCID: 5% difference | 2.1 years; N = 101; (1 RCT)^10^ | HR = 0.49; (0.21, 1.14) | -^*^ | -^*^ | -^*^ | ⨁⨁◯◯; Low^a,b^ | SABR may result in little to no difference in lung cancer specific survival.
Acute and late cough (grade ≥ 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 5% difference | 2 year; N = 101; (1 RCT)^10^ | RR = 2.12; (0.10, 45.78) | 3.0%; (0, 26.8) | 0.0% | 3% more; (1 fewer to 7 more) | ⨁◯◯◯; Very low^b,c,d^ | The evidence is very uncertain about the effect of SABR on acute and late cough.
Acute and late cough (grade 2 and 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^‡^; MCID: 10% difference | 1 year; N = 102; (1 RCT)^72^ | RR = 2.21; (0.58, 8.35) | 12.5%; (3.3, 47.3) | 5.7% | 6.8% more; (2.4 fewer to 41.6 more) | ⨁⨁◯◯; Low^b,c^ | SBRT may result in little to no difference in acute and late cough.
Acute and late pneumonitis (grade ≥ 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 5% difference | 2 year; N = 101; (1 RCT)^10^ | RR = 0.53; (0.01, 26.16) | 0.0% | 0.0% | 0.0% fewer | ⨁◯◯◯; Very low^b,c,d^ | The evidence is very uncertain about the effect of SABR on acute and late pneumonitis.
Acute and late pneumonitis (grade 2 and 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^‡^; MCID: 10% difference | 1 year; N = 102; (1 RCT)^72^ | RR = 0.44; (0.09, 2.17) | 4.2%; (0.8, 20.5) | 9.4% | 5.3% fewer; (8.6 fewer to 11.1 more) | ⨁⨁◯◯; Low^b,c^ | SBRT may result in little to no difference in acute to late pneumonitis.
Acute and late esophagitis (grade ≥ 3); Risk ratio and 2 years absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 5% difference | 2 year; N = 101; (1 RCT)^10^ | RR = 0.53; (0.01, 26.16) | 0.0% | 0.0% | 0.0% fewer | ⨁◯◯◯; Very low^b,c,d^ | The evidence is very uncertain about the effect of SABR on acute and late esophagitis.
Acute and late esophagitis (grade 2 and 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 10% difference | 1 year; N = 102; (1 RCT)^72^ | RR = 0.55; (0.02, 16.09) | 0.0% | 1.9% | 1.9% fewer | ⨁◯◯◯; Very low^b,c,d^ | The evidence is very uncertain about the effect of SBRT on acute and late esophagitis.

Notes. The risk in the intervention group (and its 95% confidence interval) is based on the assumed risk in the comparison group and the relative effect of the intervention (and its 95% CI).

* Study authors did not report these results or provide count level data to allow for calculation of these measures and/or CI.

† Estimated using data from Nyman et al.^72^

‡ Estimated using data from Ball et al.^10^

GRADE Working Group grades of evidence

High certainty: we are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: we are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: we have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded one level for imprecision (CI crossing MCID in one direction)

b Downgraded one level for study limitations (small n, short follow up, or no events)

c Downgraded one level for indirectness (acute and late harms grouped together)

d Downgraded one level for other considerations (0 events observed in 1 or more arms)

Abbreviations. CI=confidence interval; PFS=progression-free survival; MCID=minimal clinically important difference; NR=not reported; OS=overall survival; RCT=randomized controlled trial; RR=risk ratio.

Table 11 Certainty of Evidence for Hypofractionation versus Hyperfractionation for SCLC Lung Cancer Outcomes

Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Hypofractionation | Hyperfractionation | Difference | Certainty | What Happens
Overall survival (OS); MCID: 5% difference | 3 year; N = 177; (1 RCT)^71^ | Unable to assess^*^ | 56.2%; (43.2, 69.1) | 41.5% | 14.7% more | ⨁⨁◯◯; Low^a,b^ | Hypofractionation may result in little to no difference in overall survival.
Progression-free survival (PFS); MCID: 5% difference | 3 year; N = 177; (1 RCT)^71^ | Unable to assess^*^ | 37.2%; (26.0, 48.3) | 19.9% | 17.3% more | ⨁⨁◯◯; Low^a,b^ | Hypofractionation may result in little to no difference in progression-free survival.
Acute cough (grade ≥ 3); Risk ratio and absolute effect size 3 months estimates based on control event rate from 1 trial^†^; MCID: 5% difference | 3 year; N = 177; (1 RCT)^71^ | RR = 1.08; (0.02, 53.95) | 0.0%; (0, 0) | 0.0% | 0.0% fewer; (0 fewer to 0 fewer) | ⨁◯◯◯; Very low^a,c,d^ | The evidence is very uncertain about the effect of hypofractionation on acute cough.
Late cough (grade ≥ 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 5% difference | 2 year; N = 177; (1 RCT)^71^ | RR = 1.08; (0.02, 53.95) | 0.0%; (0, 0) | 0.0% | 0.0% fewer; (0 fewer to 0 fewer) | ⨁◯◯◯; Very low^a,c,d^ | The evidence is very uncertain about the effect of hypofractionation on late cough.
Acute pneumonitis (grade ≥ 3); Risk ratio and 3 months absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 5% difference | 3 month; N = 177; (1 RCT)^71^ | RR = 0.72; (0.12, 4.21) | 2.4%; (0.4, 13.7) | 3.3% | 0.9% fewer; (2.9 fewer to 10.5 more) | ⨁◯◯◯; Very low^a,b,c^ | The evidence is very uncertain about the effect of hypofractionation on acute pneumonitis.
Late pneumonitis (grade ≥ 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 5% difference | 2 year; N = 177; (1 RCT)^71^ | RR = 1.08; (0.02, 53.95) | 0.0%; (0, 0) | 0.0% | 0.0% fewer; (0 fewer to 0 fewer) | ⨁◯◯◯; Very low^a,c,d^ | The evidence is very uncertain about theeffect of hypofractionation on late pneumonitis.
Acute esophagitis (grade ≥ 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 5% difference | 2 year; N = 177; (1 RCT)^71^ | RR = 0.88; (0.45, 1.72) | 15.3%; (7.8, 29.9) | 17.4% | 2.1% fewer; (9.6 fewer to 12.5 more) | ⨁◯◯◯; Very low^a,b,c^ | The evidence is very uncertain about the effect of hypofractionation on acute esophagitis.

Notes. The risk in the intervention group (and its 95% confidence interval) is based on the assumed risk in the comparison group and the relative effect of the intervention (and its 95% CI).

* Study authors did not provide count level data to allow for calculation of a relative effect.

† Estimated using data from Qiu et al.^71^

GRADE Working Group grades of evidence

High certainty: we are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: we are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: we have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded one level for study limitations (small n, short follow up, etc)

b Downgraded one level for imprecision (CI crossing MCID in one direction)

c Downgraded one level for indirectness (acute and late harms grouped together or study did not include grade 2 harms)

d Downgraded one level for other considerations (0 events observed in 1 or more arms)

Abbreviations. CI=confidence interval; PFS=progression-free survival; MCID=minimal clinically important difference; NR=not reported; OS=overall survival; RCT=randomized controlled trial; RR=risk ratio.

#### Overall Survival

##### NSCLC

Four trials included non-small cell lung cancer (NSCLC) populations. Two of the included trials compared hypofractionation to conventional radiotherapy.^73,74^ The evidence is very uncertain regarding the impact of hypofractionation on overall survival in comparison to conventional radiotherapy in NSCLC populations (very low COE). Roy et al^73^ included locally advanced squamous cell lung cancer patients, while Iyengar et al^74^ included patients with stage II or III NSCLC. Roy et al reported a median overall survival of 24.7 months for those in the hypofractionation arm in comparison to 12.3 months for those in the conventional radiotherapy arm. Roy et al reported an overall survival at 1 year of 75% for the hypofractionated arm and 52% for those treated with conventional radiation.^73^ In contrast, Iyengar et al reported a median overall survival of 8.2 months (95% CI [5.4, 12.4]) for the hypofractionation arm compared to 10.6 months (95% CI [8.4, 15.3]) for those in the conventional radiotherapy arm. A 1 year overall survival of 37.7% (95% CI [24.2, 51.0%]) was reported for the hypofractionated arm and 44.6% (95% CI [29.9, 58.3%]) for those in the conventional radiotherapy arm.^74^ A key difference between these 2 trials centers around the allowance for concurrent chemotherapy during radiotherapy. Roy et al allowed for the administration of chemotherapy prior to radiotherapy and during the radiotherapy schedule. Iyengar et al included only patients that were ineligible for concurrent chemoradiotherapy, but allowed patients to have sequential consolidative chemotherapy after radiotherapy at the discretion of the treating physician.

The evidence suggests that SABR probably results in better overall survival in NSCLC populations (moderate COE). The evidence suggests that SBRT may result in little to no difference in overall survival in NSCLC populations (low COE). Two trials compared SABR/SBRT with either conventional or moderate hypofractionation^10^ or conventional radiotherapy.^72^ Both included stage 1 NSCLC, though the latter required patients be medically inoperable. Ball et al reported a 2 year overall survival of 77% (95% CI [67, 88%]) for those who had received SABR and 59% (95% CI [44, 78%]) for those that received conventional radiotherapy.^10^ Nyman et al reported a hazard ratio of 0.75 (95% CI [0.43, 1.30]) for overall survival, with a 2 year overall survival of 72% for those receiving SBRT and 68% for those receiving conventional radiotherapy.^72^

##### SCLC

The single small cell lung cancer trial by Qiu et al^71^ compared hypofractionation to hyperfractionation. The evidence suggests that hypofractionation may result in little to no difference in overall survival compared to hyperfractionation in SCLC populations (low COE). The authors reported no difference in overall survival between the 2 groups. Patients were enrolled if their lung cancer was determined to be limited stage. Qiu reported a 2 year overall survival of 69.9% (95% CI [59.9, 79.9]) among those in the hyperfractionation group compared to 74.2% (95% CI [64.0, 84.3%]) for those in the hypofractionation group.^71^

#### Progression-free Survival

##### NSCLC

The 2 trials for NSCLC comparing hypofractionation to conventional radiotherapy report disparate findings for PFS. The evidence is very uncertain regarding the impact of hypofractionation on PFS in comparison to conventional radiotherapy in NSCLC populations (very low COE). Roy et al reported a PFS of 17 months for those in the hypofractionation arm and 5.36 months in the conventional radiotherapy arm. In contrast, Iyengar et al reported a PFS of 6.4 (95% CI [4.1, 7.8]) months for those in the hypofractionation arm compared to 7.3 (95% CI [5.0, 10.6]) months for those that received conventional radiotherapy (p = 0.77).

Of the 2 trials reporting on SABR/SBRT compared to conventional radiotherapy, only the Nyman et al trial reported findings for PFS. The evidence suggests that SBRT probably results in little to no difference in PFS in NSCLC populations (moderate COE). Nyman et al reported a hazard ratio of 0.85 (95% CI [0.52, 1.36]) for PFS, with a 2 year PFS of 53% for those receiving SBRT and 54% for those receiving conventional radiotherapy.^72^

##### SCLC

Hypofractionation may result in little to no difference in PFS at 2 years when compared to hyperfractionation in SCLC populations (low COE). Qiu et al reported a 2 year PFS of 28.4% (95% CI [18.2, 38.6%]) for those in the hyperfractionation trial arm compared to 42.3% (95% CI [31.1, 53.5%]) for those in the hypofractionation trial arm.^71^

#### Lung-cancer-specific Survival

The evidence suggests that SABR may result in little to no difference in lung-cancer-specific survival in NSCLC populations (low COE). Only Ball et al reported lung-cancer-specific survival with a HR of 0.49 (95% CI [0.21, 1.15]; p = 0.09) when comparing individuals receiving SABR to individuals receiving conventional radiotherapy.^10^

A consistent concern with the included lung cancer trials stems from the sample sizes. Qiu et al was the only trial to meet the established enrollment goal, whereas none of the studies in NSCLC did so. Iyengar et al designed the trial to demonstrate that hypofractionation would improve local control, and by extension this would improve overall survival. However, both this study and Roy et al closed enrollment early and then analyzed results for only half the number of participants as the enrollment goals. Similarly, Nyman et al also scaled the trial down due to slow enrollment accrual. The reduction in trial sample size leads to reduced power to detect meaningful differences. In combination with the relatively short follow-up periods (and thus less opportunity to detect events), this contributed to lower levels of confidence in these survival outcomes.

#### Harms

##### NSCLC

The evidence provides very low or low certainty of evidence for the effect of hypofractionation on harms outcomes when compared to conventional radiotherapy. Both trials used CTCAE v. 3.0 to classify harms; however, Roy et al reported harms grade ≥ 3, while Iyengar et al reported ≥ 2.0. Roy et al reported counts of acute pharyngitis/oesophagitis and acute pneumonitis, while Iyengar et al reported counts of acute and late cough, esophagitis, and pneumonitis. Roy et al reported counts of acute pharyngitis/oesophagitis as 3/18 (16.7%) among those in the conventional radiotherapy arm compared to 1/8 (5.5%) among those in the hypofractionation arm (p = 0.05).^73^ Iyengar et al reported counts of acute and late esophagitis as 12/50 (24.0%) among those in the hypofractionation arm compared to 5/46 (10.9%) among those in the conventional radiotherapy arm.^74^ Iyengar et al reported pneumonitis counts of 4/50 (8%) among those in the hypofractionation arm compared to 3/46 (6.5%) among those in the conventional radiotherapy arm.^74^ Only Iyengar et al included cough as an outcome of interest, with 1/50 (2%) among those in the hypofractionation arm compared to 3/46 (5.6%) among those in the conventional radiotherapy arm.^74^

The evidence provides very low or low certainty of evidence for the effect of SBRT/SABR on harms outcomes when compared to conventional radiotherapy. The Ball et al trial makes use of the CTCAE v. 4.0 and reports grade 3 and 4 to classify harms, while the Nyman et al trial makes use of the CTCAE v. 3.0 and reports grade 2 and 3. Ball et al report counts of acute and late cough as 2/66 (3%) among those in the SABR arm versus 0/35 (0%) among those in the conventional radiotherapy arm.^72^ Nyman et al reported acute and late cough counts of 6/48 (12.5%) among the SBRT arm compared to 3/53 (5.7%) among the conventional radiotherapy arm.^72^ Ball and Nyman both report counts of acute and late esophagitis. Ball et al report 0/66 (0%) for those in the SABR compared to (0%) among those in the conventional radiotherapy arm.^10^ Nyman et al reported 0/48 (0%) among those in the SBRT arm compared to 1/53 (1.9%) among those in the conventional radiotherapy arm.^72^ Both trials also reported a count of acute and late pneumonitis, with Ball et al reporting 0/66 (0%) among those in the SABR arm compared to 0/35 (0%), and Nyman et al reporting 2/48 (4.2%) among those in the SBRT arm compared to 5/53 (9.4%) among those in the conventional radiotherapy arm.

##### SCLC

The evidence is very uncertain regarding the impact of hypofractionation on PFS in comparison to hyperfractionation in SCLC populations (very low COE). Qiu et al used CTCAE v. 4.0 to report acute and late harms ≥ 3 for the SCLC trial population. Qiu et al reported 0 cases of acute or late cough and late pneumonitis for both the hypofractionation and hyperfractionation trial arms. Acute esophagitis counts were 13/85 (15.3%) for the hypofractionation arm compared to 16/92 (17.4%) for the hyperfractionation arm. Acute pneumonitis counts were 2/85 (2.4%) for the hypofractionation arm compared to 3/92 (3.3%) for the hyperfractionation trial arm.^71^

As the trials were primarily powered to assess differences in survival and harms and toxicities were listed as secondary outcomes of interest, the reduction in trial enrollment numbers and final trial population sizes are concerning. Secondly, as harms and toxicities can be rare events, the short trial duration and reduced trial population sizes contributed to the imprecision (wide confidence intervals) captured in the effect measures.

#### Quality of Life

Two studies reported quality of life outcomes, both in NSCLC populations.^10,73^ Ball et al and Roy et al both reported a quality of life measure using the EORTC QLQ-C30. Ball et al assessed quality of life at 1 month before treatment, 3 months post-treatment, then every 3 months for 2 years and every 6 months for 2–5 years. Authors used these data to estimate the area under the curve (AUC) for quality of life over 3.5 years, and used linear mixed effects models to calculate differences in AUC overall and at 3 and 6 months for the global score and subdomains; no significant differences between treatment arms were found for any of these comparisons.^10^ Roy et al reported quality of life pre and post-treatment: there were no differences in pre-treatment scores between the hypofractionation arm (median 50, range 8.3–66.7) and the conventional radiotherapy arm (median 41.7, range 0-58.3; p = 0.24), or at post-treatment (hypofractionation arm median 66.7, range 41.7–100; conventional arm median 58.3, range 8.3–100; p = 0.44).^73^

A final concern of note is the variation in disease location and cancer stage of the included participants in each trial. These differences across trials are a challenge for reviewers as it can preclude grouping of trials, thereby preventing a strong assessment of the evidence. These nuances in disease site and progression are important and trials that provide a replicated approach and design are a necessity to understand the comparative effectiveness of hypofractionation/SBRT/SABR to conventional radiotherapy.

### Key Question 2

Trials did not stratify outcomes by the subgroups of interest; as such, there was no information to address KQ2 regarding whether results of a specific treatment regimen varied by patient or tumor characteristics in either lung cancer type. However, 1 study specifically enrolled individuals with stage I disease while 2 other trials enrolled individuals with stage II–III disease.^10,72,74^ We did not observe any large differences in comparative outcomes in studies enrolling individuals with different stage disease, though other factors may account for findings.

## HEAD AND NECK CANCER

### Overview

Of 8 eligible studies addressing head and neck cancer, we focus here on results from the 4 trials rated as low or some concerns for RoB. Two trials examined the effects of moderate hypofractionation compared with conventional radiotherapy for stage I–II glottic squamous cell carcinoma.^75,76^ The third trial evaluated salvage IMRT, hypofractionation versus conventional dosing, for locally recurrent nasopharyngeal carcinoma.^77^ The fourth trial compared moderate hypofractionation with conventional radiation therapy for locally advanced (stage III–IVB) squamous cell carcinoma of the head and neck.^78^ All 4 trials were conducted in Asia (Korea,^75^ Japan,^76^ China,^77^ and India^78^). Detailed study characteristics, results, and RoB ratings for all eligible trials are found in Appendix G. Because of the low number of studies, we were unable to perform quantitative meta-analyses. Below, we first describe the main results from the 2 trials addressing early stage glottic cancer. Then, we present findings from the other trials which evaluated recurrent nasopharyngeal carcinoma and locally advanced head and neck cancer.

### Hypofractionation versus Conventional Radiation Therapy for Early Stage Glottic Cancer

Moon et al^75^ evaluated the efficacy and harms of moderate hypofractionation (total dose range 63–67.5 Gy, dose per fraction 2.25 Gy) with conventional radiation (total dose range 66–70 Gy, dose per fraction 2.0 Gy) (approximately 29 vs 34 treatments, respectively) for 156 participants with T1 (N = 139) or T2 (N = 16) glottic squamous cell cancer; none had nodal involvement or distant metastasis. Most participants were male (N = 151, 97%) and smokers (N = 122, 78%). Half were 65 years or older (N = 81, 52%). Both radiation therapies were given once per day, lasting a median of 42 days in the hypofractionation arm and 50 days in the conventional arm. The primary goal was to demonstrate non-inferiority in local control rates, with a margin of 10%. The estimated sample size needed was 282 patients, but the trial was stopped early (at 55% of total sample size) due to poor enrollment. Median follow-up was 67 months.

Kodaira et al^76^ examined the effects of moderate hypofractionation (total dose range 60–64.8 Gy, dose per fraction 2.4 Gy) with conventional radiation (total dose range 66–70 Gy, dose per fraction 2.0 Gy) for 370 participants with T1 (N = 278) or T2 (N = 92) glottic squamous cell cancer (approximately 26 versus 34 treatments, respectively). Although participants were required to be T1-2N0M0 at enrollment, subsequent staging after randomization demonstrated that 1 person was N2M1 in the hypofractionation arm and one was actually T3 in the conventional arm; 2 participants in each arm also had other active cancers. Most participants were male (N = 256, 96%), and the median ages were 67-68; smoking status was not reported. Both radiation therapies were given once per day for 5 days a week. The primary goal was to demonstrate non-inferiority in progression-free survival at 3 years, with a margin of 5%. Median follow-up was 4.8 years. Twelve participants did not complete the radiation therapy (3 in hypofractionation arm, 9 in conventional arm); all participants were included in the intention-to-treat analyses for effectiveness. Two participants in each group did not receive any of the prescribed radiation therapy, and these were excluded from analyses focused on harms of treatment.

#### Key Question 1

Table 12 summarizes the key findings and certainty of evidence for efficacy (survival and local recurrence) and harms of hypofractionation compared with conventional radiation therapy. Overall survival exceeded 90% at 3 years in both hypofractionation and conventional radiation therapy, and there was little to no difference in toxicity outcomes. Below, we describe these results in greater detail. Neither trial examined quality of life.

Hypofractionation (total dose range 50–67.5 Gy, dose per fraction 2.22–3.125 Gy) may result in little to no difference on overall survival or progression-free survival, compared with conventional radiotherapy (low COE). For 5-year overall survival, Moon et al^75^ reported 86.6% in the hypofractionation arm and 82.5% for conventional radiation (HR not reported [NR], p = 0.36), while Kodaira et al^76^ found at 3 years 93.5% and 98.4% survival for hypofractionation versus conventional radiation, respectively (comparison p-value NR). Moon et al^75^ reported 5-year progression-free survival of 88.5% for hypofractionation and 77.8% for conventional (HR = 1.55, p = 0.21). Local recurrence occurred in 9 participants (12%) in the hypofractionation arm and 16 (20%) for conventional radiation.^75^ Kodaira et al^76^ reported 3-year progression-free survival of 81.7% for hypofractionation and 79.9% for conventional radiation, giving a difference of 1.8% (95% CI [−5.1%, 8.8%]) slightly in favor of hypofractionation. However, the CI exceeded the pre-specified non-inferiority margin of −5%, indicating that non-inferiority was not confirmed. Local recurrence was found in 20 participants (11%) in the hypofractionation arm and 34 (18%) in the conventional arm. The main methodological limitations were the small sample size and relatively low event rates, particularly in the Moon et al trial,^75^ which reduced the ability to detect meaningful differences.

Regarding toxicity and harms from radiation therapy, hypofractionation may also result in little to no difference on acute mucositis, acute dysphagia, or late mucositis (low COE). Hypofractionation also probably results in little to no difference in late soft tissue (neck) necrosis (moderate COE). Moon et al^75^ used RTOG/EORTC criteria to assess toxicity, finding no differences in rates of acute or late mucositis or laryngeal harms between hypofractionation and conventional radiation therapy. However, rates of these events were very low, with no grade ≥ 2 mucositis or laryngeal harms in the acute period, and only 1 participant with grade 2 mucositis and 2 participants with grade 2 laryngeal harms in the late stage (all in the conventional arm). Kodaira et al^76^ used CTCAE v. 3 to evaluate toxicity and grouped grades 1-2 together in reporting the results. For acute toxicity, they found no grade 3 or 4 dysphagia, but there were some participants with grade 3 mucositis (eg, 11 participants [6%] with mucositis at any site in the hypofractionation arm, and 9 participants [5%] for conventional radiation). One participant in Kodaira et al^76^ had late grade 4 soft tissue necrosis in the conventional radiation arm (none in the hypofractionation arm). In addition to the methodological limitations related to low sample sizes and event rates, there were challenges with applying these findings related to grade 1-2 events being reported together in Kodaira et al.^76^

#### Key Question 2

Moon et al^75^ evaluated for differences in effects of hypofractionation versus conventional radiation therapy for progression-free survival by T stage, finding that these were similar (no difference in survival) for T1 and T2 participants. Kodaira et al^76^ did not report any findings on potential differences in comparative effectiveness by cancer stage or other participant characteristics.

Table 12 Certainty of Evidence for Moderate Hypofractionation versus Conventional Radiation Therapy for Early Stage Glottic Cancer Outcomes

Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Hypofractionation | Conventional | Difference | Certainty | What Happens
Overall survival (OS); Risk ratio and absolute effect size estimates based on control event rate within 3 years^*^; MCID: 5% difference | 3 years; N = 516; (2 RCTs)^75,76^ | RR = 0.95; (0.91, 0.99) | 93.5%; (89.7, 97.6) | 98.4% | 4.8% fewer; (−8.7, −0.8) | ⨁⨁◯◯; Low^a,b^ | Hypofractionation may result in little to no difference in overall survival.
Progression-free survival (PFS); Risk ratio and absolute effect size estimates based on control event rate within 3 years^*^; MCID: 10% difference | 3 years; N = 516; (2 RCTs)^75,76^ | RR = 1.02; (0.93, 1.13) | 81.7%; (74.0, 90.3) | 79.9% | 1.8% more; (−5.9, 10.4) | ⨁⨁◯◯; Low^a,b^ | Hypofractionation may result in little to no difference in progression-free survival.
Acute mucositis (grade 3-4); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^*^; MCID: 5% difference | 3 months; N = 516; (2 RCTs)^75,76^ | RR = 1.18; (0.50, 2.78) | 6.0%; (2.6, 14.2) | 5.1% | 0.9% more; (−2.5, 9.1) | ⨁⨁◯◯; Low^b,c^ | Hypofractionation may result in little to no difference in acute mucositis.
Acute dysphagia (grade 1-2); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^*^; MCID: 10% difference | 3 months; N = 360; (1 RCT)^76^ | RR = 1.07; (0.96, 1.20) | 80.3%; (71.8, 89.9) | 74.6% | 5.7 more; (−2.8, 15.3) | ⨁⨁◯◯; Low^b,c^ | Hypofractionation may result in little to no difference in acute dysphagia.
Late mucositis (grade ≥ 2); Absolute effect size estimates based on control event at 5 years^†^; MCID: 10% difference | 5 years; N = 156; (1 RCT)^75^ | Not estimable | 0% | 1.2% | 1.2% fewer; (−3.6, 1.2) | ⨁⨁◯◯; Low^a,d^ | Hypofractionation may result in little to no difference in late mucositis.
Late soft tissue necrosis (neck, grade 3-4); Absolute effect size estimates based on control event rate from 1 trial^*^; MCID: 5% difference | 4.8 years; N = 360; (1 RCT)^76^ | Not estimable | 0% | 0.6% | 0.1% fewer; (−1.5, 1.5) | ⨁⨁⨁◯; Moderate^d^ | Hypofractionation probably results in little to no difference in late soft tissue necrosis.

Notes. The risk in the intervention group (and its 95% confidence interval) is based on the assumed risk in the comparison group and the relative effect of the intervention (and its 95% CI).

* Estimated using data from from Kodaira et al.^76^

† Estimated using data from Moon et al.^75^

GRADE Working Group grades of evidence

High certainty: we are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: we are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: we have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded one level for study limitations

b Downgraded one level for imprecision (CI crossing MCID in one direction)

c Downgraded one level for indirectness (used data for grade 1-2)

d Downgraded for other concerns (rare events with few detected in control group and none in hypofractionation arm)

Abbreviations. CI=confidence interval; MCID=minimal clinically important difference; NA=not applicable; OS=overall survival; PFS=progression-free survival; RCT=randomized controlled trial; RR=risk ratio.

### Hypofractionation versus Conventional Radiation Therapy for Recurrent Nasopharyngeal Cancer and Locally Advanced Head and Neck Cancer

Tian et al^77^ evaluated the efficacy and harms of IMRT moderate hypofractionation (total dose 60 Gy, dose per fraction 2.22 Gy; 27 treatments) compared with conventional dose (total dose 68 Gy, dose per fraction 2 Gy; 34 treatments) for 117 participants with T1-2 (N = 25), T3 (N = 46), and T4 (N = 26) nasopharyngeal carcinoma. Most participants had no nodal involvement but 15 were N1-2. Most participants were male (N = 94, 80%), and the median age was 47.5 in the hypofractionation arm and 46.0 years in the conventional group. Smoking status was not reported. Both radiation therapies were given once per day for 5 days a week. The primary goal was to demonstrate non-inferiority in overall survival at 5 years, with a margin of 5%. Median follow-up was 25 months. Two participants did not complete the assigned radiation treatment (1 in each arm). All participants were included in the intention-to-treat analysis for efficacy and harms.

Choudhury et al^78^ compared moderate hypofractionation (total dose 50 Gy, dose per fraction 3.125 Gy; 16 treatments) with conventional radiation therapy (total dose 66 Gy, dose per fraction 2 Gy; 33 treatments). Hypofractionation treatment lasted 3 weeks, while the conventional radiation occurred over either 5.5 weeks (6 daily fractions per week) or 6.5 weeks (5 daily fractions per week). Participants had stage III (N = 48), IVA (N = 55), or IVB (N = 31) squamous cell carcinoma. Additionally, they had to be older than 50 years and have significant comorbidities (eg, diabetes, chronic kidney disease, and cardiac condition) and/or poor performance status (Eastern Cooperative Oncology Group [ECOG] 3-4). Smoking status was not reported. The primary outcome was overall response rates, and the median follow-up was 11 months. Sixteen participants did not complete the assigned treatment (6 in the hypofractionation arm and 18 in the conventional arms), and baseline data were not reported for these individuals. Per-protocol analyses were conducted for efficacy and harms.

#### Key Question 1

Table 13 summarizes the key findings and certainty of evidence for efficacy and harms of moderate hypofractionation compared with conventional radiation therapy for recurrent and locally advanced head and neck cancer. The evidence is very uncertain about the effect of hypofractionation on overall survival and progression-free survival (very low COE) as well as most treatment toxicities.

Tian et al^77^ reported 57% overall survival in the hypofractionation arm and 38% in the conventional arm at 3 years, and 44% in the hypofractionation arm and 30% in the conventional arm for 5 years (p = 0.06). For 5-year progression-free survival, there were also no differences (57% for hypofractionation and 55% in the conventional arm, p = 0.58).^77^ Local recurrence occurred in 12 participants (20%) in the hypofractionation arm and in 11 participants (19%) in the conventional arm.^77^ Main concerns for these findings were due to limitations in the study design (unclear allocation concealment), imprecision of the estimates (related to small sample sizes), and limited applicability of these results (as the study only enrolled patients with recurrent cancer). Survival outcomes from Choudhury et al^78^ were rated high ROB due to substantial deviations from the protocol (12–17% of participants did not receive the allocated treatment) and missing outcomes assessment (median follow-up was far shorter than the goal of 4 years for overall survival).

Regarding toxicity and harms from radiation therapy, the evidence is also very uncertain on the effects of hypofractionation compared with conventional radiation therapy for acute mucositis, temporal lobe necrosis, and late xerostomia (very low COE). However, hypofractionation may result in an increase in late mucositis (low COE). Both trials used RTOG criteria to assess toxicity. Tian et al^77^ found no difference in rates of grade 3 acute mucositis (8.4% hypofractionation vs 13.7% conventional, p = 0.39), while Choudhury et al^78^ reported unclear results for grade 2-3 acute mucositis (64% hypofractionation vs 37–69% conventional arms, p = 0.01 for comparison across all 3 arms). Regarding late grade 3 xerostomia, Tian et al^77^ once again found no difference (13.5% hypofractionation vs 10.3% conventional, p = 0.42), but Choudhury et al^78^ showed more grade 2-3 events in the hypofractionation arm (52% hypofractionation vs 13–36% conventional arms, p = 0.005 for comparison across all 3 arms). Choudhury et al^78^ also found greater rates of grade 2-3 late mucositis for hypofractionation (45% vs 11–36% conventional arms, p = 0.001). Tian et al^78^ reported no difference in temporal lobe necrosis (20.3% hypofractionation vs 22.4% conventional, p = 0.59). There were similar concerns as noted above for survival outcomes.

#### Key Question 2

Neither trial evaluated whether outcomes for hypofractionation versus conventional radiation therapy were different for various patient, disease, or treatment characteristics.

Table 13 Certainty of Evidence for Moderate Hypofractionation versus Conventional Radiation Therapy for Recurrent Nasopharyngeal Cancer and Locally Advanced Head and Neck Cancer

Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome and MCID | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% Cl) | Hypofractionation | Conventional | Difference | Certainty | What Happens
Overall survival (OS); Risk ratio and absolute effect size estimates based on control event rate at 5 years^*^; MCID: 5% difference | 5 years; N = 117; (1 RCT)^77^ | RR = 1.45; (0.89, 2.37) | 44.1%; (27.0, 71.9) | 30.4% | 19.0 more; (2.6, 35.4) | ⨁◯◯◯; Very Low^a,b,c^ | Hypofractionation may result in better overall survival.
Progression-free survival (PFS); Risk ratio and absolute effect size estimates based on control event rate at 5 years^*^; MCID: 10% difference | 5 years; N = 117; (1 RCT)^77^ | RR = 1.02; (0.78, 1.32 | 67.9%; (53.0, 82.7) | 66.7% | 1.2 more; (−16.4, 18.7) | ⨁◯◯◯; Very Low^a,d^ | The evidence is very uncertain about the effect of hypofractionation on progression-free survival.
Acute mucositis (grade 3); Risk ratio and absolute effect size estimates based on control event rate at 3 months^*^; MCID: 5% difference | 3 months; N = 117; (1 RCT)^77,78^ | RR = 0.61; (0.21, 1.77) | 8.5%; (3.0, 24.4) | 13.8% | 5.3 fewer; (−10.8, 10.6) | ⨁◯◯◯; Very Low^a,d^ | The evidence is very uncertain about the effect of hypofractionation on acute mucositis.
Late xerostomia (grade 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^*^; MCID: 5% difference | 11-25 months; N = 249; (2 RCTs)^77,78^ | RR = 1.31; (0.48, 3.54) | 13.6%; (5.0, t 36.7) | 10.3% | 3.2 more; (−5.3, 26.3) | ⨁◯◯◯; Very Low^a,d,e^ | The evidence is very uncertain about the effect of hypofractionation on late xerostomia.
Late mucositis (grade 3); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^†^; MCID: 5% difference | 11 months; N = 132; (1 RCT)^78^ | RR = 4.00; (1.05, 15.24) | 13.6%; (3.6, 52.0) | 3.4% | 10.2 more; (0.2, 48.6) | ⨁⨁◯◯; Low^b,c^ | Hypofractionation may result in an increase in late mucositis.
Temporal lobe necrosis (grade NR); Risk ratio and absolute effect size estimates based on control event rate from 1 trial^*^; MCID: 10% difference | 25 months; N = 117; (1 RCT)^77^ | RR = 0.907; (0.45, 1.82) | 20.3%; (10.1,40.8) | 22.4% | 2.1 fewer; (−12.3, 18.4) | ⨁◯◯◯; Very low^a,c,d^ | The evidence is very uncertain about the effect of hypofractionation on temporal lobe necrosis.

Notes. The risk in the intervention group (and its 95% confidence interval) is based on the assumed risk in the comparison group and the relative effect of the intervention (and its 95% CI).

* Estimated using data from Tian et al.^77^

† Estimated using data from Choudhury et al.^78^

GRADE Working Group grades of evidence

High certainty: we are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: we are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: we have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded one level for study limitations

b Downgraded one level for imprecision (CI crossing MCID in one direction)

c Downgraded one level for indirectness

d Downgraded two levels for imprecision (CI crossing MCID in both directions)

e Downgraded one level for inconsistency

Abbreviations. CI=confidence interval; MCID=minimal clinically important difference; NR not reporte; OS=overall survival; PFS=progression-free survival; RCT=randomized controlled trial; RR=risk ratio.

## RECTAL CANCER

### Overview

Two trials investigating the comparative effectiveness of hypofractionation versus conventional radiotherapy were identified and included in the review. Bujko et al^80^ was assessed as low RoB for the survival outcomes and some concerns for the harms outcomes. The Stockholm III^81^ trial was assessed as low RoB for all outcomes. Both trials^80,81^ included a patient population diagnosed with adenocarcinoma of the rectum. Bujko et al^80^ was conducted in Poland and reported a median follow-up of 35 months. There were 515 participants in the trial, which compared ultra-hypofractionation (5 Gy/fraction; 5 treatments) to conventional radiotherapy (1.8 Gy/fraction; 28 treatments). Stockholm III^81^ was conducted in Sweden, had 385 participants, and reported a median follow-up of 5.2 years. Additionally, Stockholm III^81^ reported outcomes for 3 different arms: ultra-hypofractionation (5 Gy/fraction; 5 treatments) with surgery within 1 week, ultra-hypofractionation (5 Gy/fraction; 5 treatments) with surgery within 4–8 weeks, and conventional radiotherapy (2 Gy/fraction; 25 treatments) with surgery within 4–8 weeks. The 2 arms that are relevant to our review compared hypofractionation and conventional radiotherapy with surgery within 4–8 weeks.

Detailed summary characteristics, outcomes, and RoB ratings for all included trials are presented in Appendix H.

### Key Question 1

Table 14 provides the key findings and certainty of evidence for efficacy and harms in comparing moderate hypofractionation and conventional radiation therapy in the treatment of rectal cancer. Overall survival was approximately 70% and disease-free survival approximately 50% at 3 years regardless of treratment groups.

#### Survival

Hypofractionation probably results in little to no difference in overall survival compared to conventional radiotherapy (moderate COE). Bujko et al^80^ reported a 3-year overall survival rate (hypofractionation: 73%, conventional: 65%; HR = 0.73, 95% CI [0.53, 1.01]). Detailed results for this trial are provided in Appendix Table 22.

#### Disease-free Survival

Hypofractionation may result in little to no difference in disease-free survival (low COE). Stockholm III^81^ reported a hazard ratio and 95% CI for overall survival at the end of follow-up (0.81, 95% CI [0.53, 1.24]; overall p = 0.62). Bujko et al^80^ reported a 3-year disease-free survival rate (hypofractionation: 53%, conventional: 52%; HR = 0.96, 95% CI [0.75, 1.24]; p = 0.85).

Stockholm III^81^ also reported distant metastases (hypofractionation: 38/128 [29.7%], conventional: 35/128 [27.3%]; HR = 1.25, 95% CI [0.76, 2.04]) and local recurrence (hypofractionation: 1/128 [0.7%], conventional: 4/128 [3.1%]; HR = 1.22, 95% CI [0.33, 3.45]). Detailed results for these trials are provided in Appendix Table 22.

#### Harms

Bujko et al^80^ reported any acute toxicity (hypofractionation: 119/256 [46.5%], conventional: 155/259 [59.8%], effect measure NR), while Stockholm III^81^ reported overall late toxicity (hypofractionation: 51/128 [39.8%], conventional: 60/128 [46.9%]; p = 0.53). Hypofractionation may result in a decrease in acute diarrhea and late bowel obstruction but may result in little to no difference in late anal incontinence compared to conventional radiotherapy (low COEs). Bujko et al^80^ reported acute diarrhea (hypofractionation: 36/256 [14%], conventional: 70/259 [27.0%], effect measure NR). Stockholm III^81^ reported 2 late outcomes: anal incontinence (hypofractionation: 5/128 [3.9%], conventional: 8/128 [6.3%]; p = 0.32) and bowel obstruction (hypofractionation: 11/128 [8.5%], conventional: 19/128 [14.8%]; p = 0.25). Due to clinical variability in disease type and a sparsity of outcome data, we did not conduct pooled analyses. Detailed results for these trials are provided in Appendix Table 23.

#### Quality of Life

We found no studies that measured quality of life in rectal cancer.

### Key Question 2

Trials did not stratify outcomes by the subgroups of interest. As such, there was no information to address KQ2 regarding whether results varied by patient or tumor characteristics.

Table 14 Certainty of Evidence for Moderate Hypofractionation versus Conventional Radiation Therapy for Rectal Cancer Outcomes

Outcome Minimal Clinically Important Difference (MCID) | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% CI) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome Minimal Clinically Important Difference (MCID) | Follow-up; No. of Participants; (Studies) | Relative Effect; (95% CI) | Hypofractionation | Conventional | Difference | Certainty | What Happens
Overall survival (OS); MCID: 5% difference | 3 years; N = 771; (2 RCTs)^80,81^ | RR = 1.07; (0.94, 1.22) | 69.7%; (61.3, 79.5) | 65.2% | 4.6% more; (3.9 fewer to 14.3 more) | ⨁⨁⨁◯; Moderate^a^ | Hypofractionation probably results in little to no difference in overall survival.
Disease-free survival (DFS); MCID: 5% difference | 3 years; N = 515; (1 RCT)^80^ | RR = 1.04; (0.79, 1.38) | 29.5%; (22.4, 39.1) | 28.3% | 1.1% more; (6 fewer to 10.8 more) | ⨁⨁◯◯; Low^a,b^ | Hypofractionation may result in little to difference in disease-free survival.
Acute diarrhea (grade ≥ 2); MCID: 10% difference | < 30 days; N = 515; (1 RCT)^80^ | RR = 0.58; (0.40, 0.84) | 15.7%; (10.8, 22.7) | 27% | 11.4% fewer; (16.2 fewer to 4.3 fewer) | ⨁⨁◯◯; Low^a,b^ | Hypofractionation may result in a reduction in acute diarrhea.
Late anal incontinence; (grade ≥ 3); MCID: 5% difference | After 30 days; N = 256; (1 RCT)^81^ | RR = 0.64; (0.21, 1.90) | 4.0%; (1.3, 11.9) | 6.3% | 2.3% fewer; (4.9 fewer to 5.6 more) | ⨁⨁◯◯; Low^a,b^ | Hypofractionation may result in little to no difference in late anal incontinence.
Late bowel obstruction; (grade ≥ 3); MCID: 5% difference | After 30 days; N = 256; (1 RCT)^81^ | RR = 0.61; (0.30, 1.20) | 9.1%; (4.5, 17.8) | 14.8% | 5.8% fewer; (10.4 fewer to 3.0 more) | ⨁⨁◯◯; Low^a,b^ | Hypofractionation may result in a reduction in late bowel obstruction.

Notes. The risk in the intervention group (and its 95% confidence interval) is based on the assumed risk in the comparison group and the relative effect of the intervention (and its 95% CI).

GRADE Working Group grades of evidence

High certainty: we are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: we are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: we have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded one level for imprecision (wide CI)

b Downgraded one level for study limitations

Abbreviations. CI=confidence interval; DFS=disease-free survival; OS=overall survival; RCT=randomized controlled trial; RR=risk ratio.