# METHODS

## TOPIC DEVELOPMENT

In response to a request from the National VA Radiation Oncology Quality Task Force, this evidence review topic was developed to aid the Task Force in guideline development for radiation treatment in select cancers within VA. In collaboration with our Operational Partners and technical expert panel (TEP), we developed the analytic framework, scope, protocol, and key questions for this review.

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number [CRD42021287645]).

## DATA SOURCES AND SEARCHES

We searched MEDLINE and Embase from inception to January 5, 2022. We supplemented this search with a review of systematic reviews identified by keyword search through Cochrane and AHRQ databases. We limited the search to randomized controlled trials and the English language. See Appendix A for complete search strategies.

## STUDY SELECTION

After duplicates were removed, citations were uploaded into DistillerSR.^6^ Using prespecified inclusion and exclusion criteria, titles and abstracts were screened by 2 reviewers for potential relevance to the key questions. Articles included by either reviewer underwent full-text screening. At the full-text screening stage, 2 independent reviewers agreed on the final inclusion or exclusion decision. Articles that met eligibility criteria (below) were included for data abstraction.

| Eligibility Criteria
Population | Adults, 18 years or older, diagnosed with 1 of the following cancers: breast, prostate, lung, rectal, head and neck, bladder, pancreas, melanoma, and non-melanoma skin cancer receiving radiation with definitive treatment intent (ie, non-palliative)
Intervention | Hypofractionation (>220 cGy (2.2 Gy) per fraction); - Moderate hypofractionation; - Ultrahypofractionation/extreme hypofractionation; - Stereotactic body radiation therapy (SBRT)/Stereotactic ablative body radiation therapy (SABR)
Comparator | Standard or conventional or long-course radiation [180 to 220 cGy (1.8 – 2.2 Gy) per fraction] (unless SCLC in which hyperfractionation is the standard of care)
Outcomes | Survival: Overall, Disease-specific; Recurrence (evidence of progression)/Control (no evidence of progression): Biochemical (prostate), Local, Regional, Systemic/distant metastatic; Toxicity: All adverse events of grade 2-5, Specific adverse events grade 2-5 relevant to each cancer; Quality of Life: Overall and cancer-specific; Cost/resource use
Timing | Effectiveness outcomes timing: short-term (≤2 years) vs long-term (>2 years); Toxicity timing: Any [(acute = during and within 90 days post treatment) (late = greater than 90 days post treatment)]
Setting | Any non-hospice setting
Study Design | RCT or SR with RCT inclusion

## DATA ABSTRACTION AND ASSESSMENT

Data from published articles were abstracted by 1 reviewer and verified by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus could not be reached. The following elements were abstracted for included articles: study characteristics (country, funding source, inclusion and exclusion criteria), population characteristics (age, sex, cancer stage, risk stage), tumor characteristics, intervention and comparator characteristics (dose, fractions and duration of treatment), and outcomes (overall and disease-specific survival, recurrence, toxicity, overall quality of life, and cost/resource use).

Two reviewers independently assessed the articles risk of bias (RoB) using the Cochrane risk of bias tool for randomized trials (RoB 2).^7^

## KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1: What are the comparative efficacy and harms of hypofractionation (see Table 1) versus conventional radiation therapy in the definitive treatment of adults with breast, prostate, lung, rectal, head and neck, bladder, pancreas, melanoma, or non-melanoma skin cancer?
KQ2: In the treatment of adults with the above types of cancer, do the efficacy and harms of hypofractionation strategies vary by cancer stage, prostate cancer NCCN risk stratification, or other patient characteristics?

Table 1 Hypofractionation Definitions by Dose

Term | Dose (EBRT Fraction Size)
Conventional fractionation | 180 to 220 cGy (1.8-2.2 Gy)
Moderate hypofractionation | > 220 to 499 cGy (> 2.2-4.99 Gy)
Ultrahypofractionation/extreme hypofractionation/stereotactic body radiation therapy (SBRT)/stereotactic ablative body radiation therapy (SABR) | ≥ 500 cGy (≥ 5.00 Gy)

## SYNTHESIS

The eligible articles were summarized by cancer type (including cell type for lung cancer) and outcomes (eg, survival, recurrence, and toxicity). Studies that were assessed to be high RoB had study characteristics but not outcome data extracted. These studies were not included in any pooled analyses. Meta-analysis was conducted using R version 4.2.1 for each cancer type when 5 or more sufficiently comparable studies were available.

Prior to the pooling of data, we examined clinical and methodological variation to determine appropriateness of quantitative synthesis. If applicable, we pooled outcomes from clinically homogeneous studies. We pooled studies with cancers of similar disease site and cell type and stage (eg, lung but stratified by NSCLC vs SCLC), hypofractionation category (hypofractionation vs ultra-hypofractionation), and radiotherapy approach (eg, partial breast vs whole breast). We calculated absolute risk differences (ARD) and risk ratios (RR) with corresponding 95% confidence intervals (CI) for categorical outcomes.

We did not pool effect measures for outcomes with 4 or fewer contributing RCTs. We used the Hartung–Knapp–Sidik–Jonkman random-effects model to estimate pooled effects and corresponding 95% CIs. Anticipated absolute event rates and corresponding risk differences were also generated in R.

Heterogeneity was assessed using the I² statistic, prediction interval, and visual inspection of forest plots. We anticipated conducting subgroup analyses to explore potential causes of heterogeneity (and address KQ2) by cancer stage, prostate cancer risk status, and radiotherapy categorization. When quantitative synthesis was not appropriate, findings were summarized narratively.

We used the Grading of Recommendations, Assessment, Development, and Evaluation (GRADE) methodology to rate overall certainty of evidence (COE) for critical outcomes as high, moderate, low, or insufficient using GRADEpro GDT.^8,9^ Briefly, for each prioritized outcome, we evaluated characteristics of the evidence across 5 domains: study limitations (risk of bias), imprecision (number of events, sample size, and precision of effect estimates reported by included studies), inconsistency (whether the direction and magnitude of effects are similar [or different] across the included studies), indirectness (how applicable the results were to our key questions), and publication bias (preferential reporting of positive results). The overall certainty of evidence takes into consideration individual ratings in each of these 5 domains, but domains may not be weighted equally in determining the overall rating.

Specific thresholds indicating clinically meaningful effects for decision-making of hypofractionation versus conventional radiation therapy for each of our critical outcomes were derived a priori through consensus input by our internal content experts, Operational Partners, and TEP members. These thresholds (Table 2) were used to define clinically meaningful differences and assess certainty of evidence when comparing the intervention to comparator for each outcome. When appraising the threshold, a difference of that size would be enough to impact clinical management. Consistent with GRADE methodology, when more than 1 trial provided outcome estimates, we calculated ARD for those outcomes by applying the pooled RR to the control event rate and specified follow-up time periods from exemplar studies. After discussion with our content experts and Operational Partners, the following outcomes were prioritized for certainty of evidence assessment. GRADE was not performed for subgroups such as radiotherapy approach, disease location, or disease severity.

- Survival outcomes:
  ○ Overall survival
  ○ Disease-free survival
  ○ Local-regional survival/recurrence
- Harms outcomes (acute or late):
  ○ Overall adverse events
  ○ Specific adverse events by cancer:
    ■ Prostate: genitourinary (GU) and gastrointestinal (GI)
    ■ Breast: Skin, lymphedema, and pneumonitis
    ■ Head and Neck: Mucositis, dysphagia, radionecrosis, and xerostomia
    ■ Lung: Pneumonitis and esophagitis
    ■ Bladder: GU and GI
    ■ Rectal: GU and GI

Table 2 Clinically Meaningful Thresholds

Outcome | Threshold Level | Notes
Overall survival | 5% absolute difference over any length of follow-up | Context: follow-up length of the study and the number of events will be a limiter to consider (ie, the study design limits the measurement)
Disease-specific survival | 5% absolute difference over any length of follow-up | Context: follow-up length of the study will be a limiter to consider (ie, the study design limits the measurement)
Local-regional survival | 10% absolute difference over any length of follow-up | Context: follow-up length of the study will be a limiter to consider (ie, the study design limits the measurement)
Harms ≥grade 2 | 10% difference
Harms ≥grade 3 | 5% difference | Grade 3 or greater will be used as a measure of harm when grade 2 or greater not presented by the author