# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) is responding to a request from the Department of Veterans Affairs (VA) National Radiation Oncology Quality Task Force for an evidence review on the comparative effectiveness of hypofractionation versus conventional or long-course radiation among adults with breast, prostate, lung, rectal, head and neck, bladder, pancreas, melanoma, or non-melanoma skin cancer. Findings from this review will be used to establish treatment guidelines for the VA and community clinicians who treat Veterans with cancer. An understanding of the evidence on hypofractionation compared to conventional radiation treatment will inform use of hypofractionation in the VA and community settings.

## BACKGROUND

In 2018, 1.7 million new cancer cases were reported to the Centers for Disease Control and Prevention (CDC) and the National Cancer Institute (NCI) in the United States (US). Of those 1.7 million newly diagnosed cancer cases, the most common diagnoses were breast, lung, and colorectal cancer among females and prostate, lung, and colorectal cancer among males.^1^ An estimated 40,000 cancer cases are reported annually to the VA Central Cancer Registry.^2^ Similar to the general US male population,^2^ the most frequently diagnosed and treated cancers within the VA are prostate, lung, and colorectal. Treatment regimens for each cancer type are complex and vary widely by patient and cancer characteristics. Treatments have also evolved dramatically over the past 3 decades.^3^ Radiotherapy for curative or definitive cancer therapy is an important and frequently used treatment option.

Hypofractionation is a treatment regimen in which the total dose of radiation is divided into larger doses per fraction (given once a day or less often), resulting in fewer fractions and shorter overall treatment durations compared to conventional fractionation. The reduction in number of fractions (thus treatment sessions) for hypofractionation regimens can improve patient convenience, increase treatment scheduling access, and potentially be cost effective. These factors are cited as potential reasons to prioritize hypofractionation over conventional radiotherapy.^3^ While hypofractionation has been recommended by the American Society for Radiation Oncology (ASTRO) for certain cancers, it has not been universally adopted.^4,5^ The ASTRO guideline cited the following rationale: “Hypofractionated radiation has the advantage of shortening treatment duration, is respectful of resource utilization, and appears cost-effective. While health economic endpoints were not considered, it is recognized that the very nature of hypofractionation is such that there are potential advantages in terms of cost and convenience for patients.”^5^ To date, the comparative effectiveness and harms of hypofractionation versus conventional radiation for definitive therapy has not been summarized for many cancer types; only breast and prostate cancers have had comprehensive assessments in previous systematic reviews.

The VA cares for an estimated 175,000 Veterans annually in their cancer treatment programs; many undergo “definitive treatment” with an intent to cure cancer, including through the use of radiation therapies.^2^ Effectiveness, harms, and patient quality of life are important factors to assess and understand when developing guidelines for clinicians who treat Veterans with cancer. Although the VA has implemented hypofractionation for common cancer types, such as prostate and breast, variation remains across facilities. Also, many Veterans receive their cancer care in community settings, with variation in treatments between community and academic clinicians. The National VA Radiation Oncology Quality Task Force has been tasked with developing and establishing treatment guidelines for the VA and community clinicians who treat Veterans with cancer. This systematic review was nominated to assist and guide their decision-making.

In this review, we summarize the available randomized trial evidence on the comparative efficacy (including health-related quality of life) and harms of hypofractionation versus conventional or long-course radiation as definitive therapy among adults with breast, prostate, lung, rectal, head and neck, bladder, pancreas, melanoma, or non-melanoma skin cancer. We also assessed whether comparative efficacy and harms varied by patient and tumor characteristics. The cancers captured in this review were prioritized by the Operational Partners and where radiotherapy treatment was deemed definitive.