# APPENDIX H RECTAL CANCER TRIALS

Appendix Table 20 Risk of Bias Ratings for All Eligible Rectal Cancer Trials

Trial | Outcome | Domain 1: Risk oif Bias Arising from the Randomization Process | Domain 2a: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Assignment to Intervention) | Domain 2b: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Adherence to Intervention) | Domain 3: Risk of Bias Due to Missing Outcome Data | Domain 4: Risk tf Bias in Measurement of the Outcome | Domain 5: Risk of Bias in Selection of the Reported Result | Overall Risk of Bias
Bujko | Harms^79,80^ | Low | Low | Low | Low | Low | Low^80^; Some^79^ concerns | Low^80^; Some^79^ concerns
Bujko | Survival^80^ | Low | Low | Low | Low | Low | Low | Low
Stockholm III | Harms^81^ | Low | Low | Low | Low | Low | Low | Low
Stockholm III | Mortality^81,141^ | Low | Low | Low | Low | Low | Low | Low
Stockholm III | Survival^81,141^ | Low | Low | Low | Low | Low | Low | Low
TROG | Harms^142^ | Some concerns | High | High | Low | Low | Low | High

Appendix Table 21 Study Characteristics for All Eligible Rectal Cancer Trials

Trial Name, Year Trial # Risk of Bias Country Funding Follow-up | Inclusion/Exclusion Criteria | Hypofractionation Characteristics | | Conventional Characteristics | | Outcomes Reported (Risk of Bias If Different by Outcome)
Trial Name, Year Trial # Risk of Bias Country Funding Follow-up | Inclusion/Exclusion Criteria | N Baseline Characteristics (N, %) | Dose/Fraction Total Dose Time | N Baseline Characteristics (N, %) | Dose/Fraction Total Dose Time | Outcomes Reported (Risk of Bias If Different by Outcome)
Stockholm III, 2017 ^81^; NCT00904813; LOW; Sweden (multicenter); Swedish Research Council, Swedish Cancer Society, Stockholm Cancer Society, Stockholm County Council, Karolinska Institute; Median follow-up was 5.2 years (IQR 3.7–6.1; range 2.0–14.6). | Inclusion: Patients scheduled for an open abdominal procedure with a biopsy-proven primary adenocarcinoma of the rectum, defined as an adenocarcinoma within 15 cm of the anal verge, without signs of non-resectability or distant metastases, and without previous radiotherapy to the abdominal or pelvic regions, signs of severe ischemic disease, or symptoms of severe arteriosclerosis, with no age restriction, were eligible. | Arm A: hypo with surgery within 1 week | | N = 128; Median age (IQR); 66 (61,73); Female N = 55 (43); ypStage; I^*^: 37(29); II: 46(37); III: 37(30); IV: 5(4); Stage x: 1(1) | 50 Gy/25 fractions with surgery after 4–8 weeks | Primary endpoint: Time to local recurrence; Survival:; - Local recurrence; - Distant metastases; - OS; - Recurrence-free survival; Harms:; Toxicity; - Overall; - Bowel obstruction (late); - Anal incontinence (late)
| | N = 129; Median age (IQR) 67 (62,74); Female N = 48 (37); ypStage; I: 38 (29); II: 43 (33); III: 48 (37); IV: 0 (0); Unknown: 0 (0) | 25 Gy/5 fractions with surgery within 1 week | N = 128; Median age (IQR); 66 (61,73); Female N = 55 (43); ypStage; I^*^: 37(29); II: 46(37); III: 37(30); IV: 5(4); Stage x: 1(1) | 50 Gy/25 fractions with surgery after 4–8 weeks
| | Arm B: hypo with surgery within 4–8 weeks | | N = 128; Median age (IQR); 66 (61,73); Female N = 55 (43); ypStage; I^*^: 37(29); II: 46(37); III: 37(30); IV: 5(4); Stage x: 1(1) | 50 Gy/25 fractions with surgery after 4–8 weeks
| | N = 128; Median age (IQR) 67 (62,75); Female n=49 (38); ypStage; I: 55 (43); II: 31 (24); III: 31 (24); IV: 7 (6); Unknown: 3 (2) | 25 Gy/5 fractions with surgery after 4–8 weeks | N = 128; Median age (IQR); 66 (61,73); Female N = 55 (43); ypStage; I^*^: 37(29); II: 46(37); III: 37(30); IV: 5(4); Stage x: 1(1) | 50 Gy/25 fractions with surgery after 4–8 weeks
Bujko, 2016 ^80^; NCT00833131; LOW/SOME CONCERNS^*^; Poland (multicenter); Grant No. N N403 580538 Polish Ministry of Science and Higher Education; Median follow-up was 35 months | Inclusion: Primary or locally recurrent rectal cancer involving or abutting adjacent organs or structures (cT4) or a palpably fixed cT3 lesion, pathologically proven adencarcinoma, ≤ 75 years of age, WHO performance status ≤ 2 in patients fit for major surgery and chemotherapy along with informed written consent signed by patients. The involvement of mesorectal fascia as diagnosed by MRI was not used as the entry criterion, because of the long waiting time for pelvic MRI in Poland.; Exclusion: Distant metastases, active coronary artery disease, cardiac arrhythmia, congestive heart failure, history of peripheral neuropathy and a history of cerebral stroke. | N = 261; Median Age (IQR) 60 (54,66); Female N = 78 (30); T Stage; 0: 37 (17); 1: 3 (1); 2: 47 (22); 3: 110 (51); 4a: 4 (2); 4b: 15 (7); Residual cancer after resection: 4; N/A: 41; N stage; 0: 150 (69); 1: 43 (20); 2: 26 (12); No data: 1; N/A: 41 | 25 Gy/ 5 fractions over 5 days, once daily (consolidation chemotherapy of 3 cycles of FOLFAX) | N = 254; Median age (IQR) 60 (56,65); Female N = 85 (33); T stage; 0: 24 (12); 1: 5 (3); 2: 53 (26); 3: 92 (46); 4a: 9 (5); 4b: 19 (9); Residual cancer after resection: 3; N/A: 49; N stage; 0: 136 (68); 1: 37 (19); 2: 26 (14); No data: 5; N/A: 49 | 50.4 Gy/ 28 fractions over 5.5 weeks, once daily (concomitantly with oxliplatin and boluses of 5-fluorouracil and leucovorin) | Primary endpoint: R0 resection rate (correlated with DFS)^**^; Survival (low):; - OS; - DFS; Harms (some concerns):; Toxicity (acute); - Overall; - Diarrhea
Trans-Tasman Radiation Oncology Group (TROG), 2017 ^142^; HIGH; Australia & New Zealand (27 centers); The National Health and Medical Research Council (NHMRC, No 209123), Cancer Council Victoria, and The Royal Australian and New Zealand College of Radiologists (RANZCR). Dr Nabila Ansari was supported by the NOTARAS Scholarship of the University of Sydney and the Post Fellowship Training Board in Colorectal Surgery of the Colorectal Surgical Society of Australia and New Zealand (CSSANZ) and the Royal Australasian College of Surgeons (RACS).; Follow-up NR | Inclusion: were those with clinically resectable adenocarcinoma of the rectum, ultrasound or magnetic resonance imaging staged as T3, with the lower border of the tumor within 12 cm of the anal verge and with no evidence of any distant metastases.; Exclusion: Recurrent rectal cancer, other cancers in the prior 5 years, unstable cardiac disease, active infection, and prior radio therapy. All patients had an Eastern Cooperative Oncology Group performance status of 0 to 2. | N = 161; Median age (range) 63 (26,80); Female N = 46 (29); ECOG performance status; 0: 101 (63); 1: 59 (37); 2: 1 (1); T3 stage: 161 (100); N stage; 0: 90 (56); 1: 59 (37); 2: 1 (1); X: 11 (7); M0 stage: 161 (100) | 25 Gy/5 fractions over 5 days, followed by resection 3–7 days later; Six monthly cycles of 5FU 425 mg/m^2^ and folinic acid 20 mg/m^2^ given daily for 5 days commenced 4–6 weeks after surgery | N = 161; Median age (range) 64 (29,82); Female N = 41 (25); ECOG performance status; 0: 87 (54); 1: 71 (44); 2: 3 (2); T3 stage: 161 (100); N stage; 0: 90 (56); 1: 59 (37); 2: 2 (1); X: 10 (6); M0 stage: 161 (100) | 50.4 Gy/ 28 fractions over 5 weeks & 3 days; Concurrent chemotherapy with continuous infusion of 5FU (225 mg/m^2^/d) was administered daily for the duration of radiation. Surgery was performed 4 to 6 weeks after chemotherapy | Primary endpoint: 3-year local recurrence; Harms:; Toxicity (acute); Preop. radiation AEs (Grade 1–4); - Radiation dermatitis^**^; - Diarrhea^**^; - Proctitis^**^; - Pain due to radiation^**^; - Dysuria^**^; - Urinary frequency/urg ency^**^; - Hematuria^**^; - Neuropathic pain^**^; - Perineal pain^**^

Notes.

* Risk of bias differed by outcome.

** Unable to extract.

Abbreviations. OS=Overall Survival; DFS=Disease-Free Survival; CTCAE=Common Terminology Criteria for Adverse Events (version 4.0), ypStage=pathological stage after neoadjuvant treatment.

Appendix Table 22 Detailed Results for Survival Outcomes for Rectal Cancer Trials Rated “Low” or “Some Concerns” for Risk of Bias

Trial Name, Year; Trial #; Risk of Bias | Effect Measure/Definition | Hypofractionation N Events/Total N, (%) | Comparison N Events/Total N, (%) | Results
Overall Survival
Bujko, 2016 ^79^ ^,^ ^80^; NCT00833131; LOW | 3-year overall survival rate | 73% | 65% | HR (95% CI): 0.73 (0.53, 1.01), P = 0.046
Stockholm III, 2017 ^81^; NCT00904813; LOW | Hazard ratio/overall survival at the end of follow-up | NR | NR | Surgery within 1 week HR (95% CI): 0.94 (0.63, 1.4) | Overall P value = 0.62 (ref group Arm A)
Stockholm III, 2017 ^81^; NCT00904813; LOW | Hazard ratio/overall survival at the end of follow-up | NR | NR | Surgery within 4-8 weeks HR (95% CI): 0.81 (0.53, 1.24) | Overall P value = 0.62 (ref group Arm A)
Disease-free Survival
Bujko, 2016 ^79^ ^,^ ^80^; NCT00833131; LOW | 3 year DFS rate | 53% | 52% | HR (95% CI): 0.96 (0.75, 1.24), P = 0.85
Distant Metastases
Stockholm III, 2017 ^81^; NCT00904813; LOW | HR for time to first metastases event | Arm A (surgery within 1 week): 29/129 (22.4) | 35/128 (27.3) (surgery within 4-8 weeks) | HR (95% CI): 1.45 (0.89, 2.37) | Overall P = 0.33 (ref group Arm A)
Stockholm III, 2017 ^81^; NCT00904813; LOW | HR for time to first metastases event | Arm B (surgery within 4-8 weeks): 38/128 (29.7) | 35/128 (27.3) (surgery within 4-8 weeks) | HR (95% CI): 1.25 (0.76, 2.04) | Overall P = 0.33 (ref group Arm A)
Local Recurrence (Recurrence-free Survival)
Stockholm III, 2017 ^81^; NCT00904813; LOW | HR for time to first recurrence event | Arm A (surgery within 1 week): 3/129 (2.4) | 4/128 (3.1) (surgery within 4-8 weeks) | HR (95% CI): 0.38 (0.06, 2.56) | Overall P = 0.52 (ref group Arm A)
Stockholm III, 2017 ^81^; NCT00904813; LOW | HR for time to first recurrence event | Arm B (surgery within 4-8 weeks): 1/128 (.7) | 4/128 (3.1) (surgery within 4-8 weeks) | HR (95% CI): 1.22 (0.33, 3.45) | Overall P = 0.52 (ref group Arm A)
Mortality
Bujko, 2016 ^79^ ^,^ ^80^; NCT00833131; LOW | Median follow-up of 35 months Total deaths | 64/261 (24.5) | 84/254 (33.1) | NR
Bujko, 2016 ^79^ ^,^ ^80^; NCT00833131; LOW | Deaths in patients with cancer | 52/64 (81.3) | 67/84 (79.8) | NR
Bujko, 2016 ^79^ ^,^ ^80^; NCT00833131; LOW | Deaths from treatment complications | 6/64 (9.4) | 13/84 (15.4) | NR
Bujko, 2016 ^79^ ^,^ ^80^; NCT00833131; LOW | Deaths from intercurrent disease | 4/64 (6.3) | 2/84 (2.4) | NR
Bujko, 2016 ^79^ ^,^ ^80^; NCT00833131; LOW | Death from unknown causes | 2/64 (3) | 2/84 (2.4) | NR
Stockholm III, 2017 ^81^; NCT00904813; LOW | Total deaths | Arm A (surgery within 1 week): 51/129 (39.5) | 49/128 (38.2) (surgery within 4-8 weeks) | NR
Stockholm III, 2017 ^81^; NCT00904813; LOW | Total deaths | Arm B (surgery within 4-8 weeks): 43/128 (33.6) | 49/128 (38.2) (surgery within 4-8 weeks) | NR
Stockholm III, 2017 ^81^; NCT00904813; LOW | Intercurrent deaths | Arm A (surgery within 1 week): 29/51 (56.9) | 19/49 (38.8) | HR (95% CI) (surgery within 1 week): 0.46 (0.24, 0.90) | Overall P = 0.06 (ref group = Arm A)
Stockholm III, 2017 ^81^; NCT00904813; LOW | Intercurrent deaths | Arm B (surgery within 4-8 weeks): 15/43 (34.9) | 19/49 (38.8) | HR (95% CI) (surgery within 4-8 weeks): 0.70 (0.38, 1.26) | Overall P = 0.06 (ref group = Arm A)

Appendix Table 23 Detailed Results for Toxicity Outcomes for Rectal Cancer Trials Rated “Low” or “Some Concerns” for Risk Of Bias

Trial Name, Year; Trial #; Risk of Bias | Effect Measure/Definition | Hypofractionation N Events/Total N, (%) | Comparison N Events/Total N, (%) | Results
Any Toxicity (Acute)
Bujko, 2016 ^79^ ^,^ ^80^; NCT00833131; SOME CONCERNS | Early toxicity occurring during radio(chemo)therapy or within the interval to surgery/CTCAE grade ≥ 2 | 119/256 (46.5) | 155/259 (59.8) | NR
Acute Diarrhea
Bujko, 2016 ^79^ ^,^ ^80^; NCT00833131; SOME CONCERNS | Early toxicity occurring during radio(chemo)therapy or within the interval to surgery/CTCAE grade ≥ 2 | 36/256 (14.0) | 70/259 (27.0) | NR
Late Anal Incontinence
Stockholm III, 2017 ^81^; NCT00904813; LOW | Late toxicity after 30 days from surgery/RTOG grade 3-4 | Arm A (surgery within 1 week): 11/129 (8.5) | 8/128 (6.3) (surgery within 4-8 weeks) | P = 0.32
Stockholm III, 2017 ^81^; NCT00904813; LOW | Late toxicity after 30 days from surgery/RTOG grade 3-4 | Arm B (surgery within 4-8 weeks): 5/128 (3.9) | 8/128 (6.3) (surgery within 4-8 weeks) | P = 0.32
Late Bowel Obstruction
Stockholm III, 2017 ^81^; NCT00904813; LOW | Late toxicity after 30 days from surgery/RTOG grade 3-4 | Arm A (surgery within 1 week): 12/129 (9.3) | 19/128 (14.8) (surgery within 4-8 weeks) | P = 0.25
Stockholm III, 2017 ^81^; NCT00904813; LOW | Late toxicity after 30 days from surgery/RTOG grade 3-4 | Arm B (surgery within 4-8 weeks): 11/128 (8.5) | 19/128 (14.8) (surgery within 4-8 weeks) | P = 0.25
Overall Late Toxicity
Stockholm III, 2017 ^81^; NCT00904813; LOW | Late toxicity after 30 days from surgery/RTOG grade 3-4 | Arm A (surgery within 1 week): 56/129 (43.4) | 60/128 (46.9) (surgery within 4-8 weeks) | P = 0.53
Stockholm III, 2017 ^81^; NCT00904813; LOW | Late toxicity after 30 days from surgery/RTOG grade 3-4 | Arm B (surgery within 4-8 weeks): 51/128 (39.8) | 60/128 (46.9) (surgery within 4-8 weeks) | P = 0.53

Abbreviations. CTCAE=Common Terminology Criteria for Adverse Events (version 4.0); RTOG=Radiation Therapy Oncology Group.