# APPENDIX G HEAD AND NECK CANCER TRIALS

Appendix Table 16 Risk of Bias Ratings for All Eligible Head and Neck Cancer Trials

Trial | Outcome | Domain 1: Risk of Bias Arising from the Randomization Process | Domain 2a: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Assignment to Intervention) | Domain 2b: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Adherence to Intervention) | Domain 3: Risk of Bias Due to Missing Outcome Data | Domain 4: Risk of Bias in Measurement of the Outcome | Domain 5: Risk of Bias in Selection of the Reported Result | Overall Risk of Bias
Bjordal^137^ | QoL | Some concerns | High | Some concerns | High | Low | Low | High
Choudhury^78^ | Harms | Low | Low | Low | Low | Low | Low | Low
Choudhury^78^ | Survival | Low | Low | Some concerns | High | Low | Low | High
Kachhwaha^138^ | Harms | Some concerns | High | High | Low | Low | Some concerns | High
Kachhwaha^138^ | Survival | Some concerns | High | High | Low | Low | Some concerns | High
Kodaira^76^ | Harms | Low | Low | Low | Low | Low | Low | Low
Kodaira^76^ | Survival | Low | Low | Low | Low | Low | Low | Low
Moon^75^ | Harms | Low | Low | Some concerns | Low | Low | Some concerns | Some concerns
Moon^75^ | Survival | Low | Low | Some concerns | Low | Low | Low | Some concerns
Tian^77^ | Harms | Some concerns | Low | Low | Low | Low | Low | Some concerns
Tian^77^ | Survival | Some concerns | Low | Low | Low | Low | Low | Some concerns
Tolia^139^ | QoL | High | Some concerns | Some concerns | Low | Low | Some concerns | High
Yamazaki^140^ | Harms | Some concerns | High | High | Low | Low | Some concerns | High
Yamazaki^140^ | Survival | Some concerns | High | High | Low | Low | Low | High

Appendix Table 17 Study Characteristics for Eligible Head and Neck Cancer Trials

Trial Name, Year Trial # Risk of Bias Country Funding Follow-up | Inclusion/Exclusion Criteria | Hypofractionation Characteristics | | Conventional Characteristics | | Outcomes Reported (Risk of Bias If Different by Outcome)
Trial Name, Year Trial # Risk of Bias Country Funding Follow-up | Inclusion/Exclusion Criteria | N Baseline Characteristics (N, %) | Dose/Fraction Total Dose Time | N Baseline Characteristics (N, %) | Dose/Fraction Total Dose Time | Outcomes Reported (Risk of Bias If Different by Outcome)
Bjordal, 1994 ^137^; HIGH; Norway; Norwegian Cancer Society; Follow-up survey 7–11 years after original RCT | NR; The study was based on a larger randomized study that was carried out at the Norwegian Radium Hospital (NRH) between 1979 and 1984. | N = 101; Mean age (range) 68 (34, 92); Female N = 23 (22.8); Stage; I: 58 (57.4); II: 18 (17.8); III: 13 (12.9); IV: 12 (11.9); No stage: 0 (0) | 65.8 Gy/28 fractions days a week for 7 weeks | N = 103; Mean age (range) 67 (32, 91); Female N = 26 (25.2); Stage; I: 39 (37.9); II: 21 (20.4); III: 18 (17.5); IV: 22 (21.4); No stage: 3 (2.9) | 70 Gy/35 fractions 5 days a week for 7 weeks | Primary endpoint: Quality of life
Choudhury, 2012 ^78^; SOME CONCERNS; Country NR (Single-center); Funding NR; Median follow-up of 11 months | Inclusion: Patients with chemotherapy, surgery (other than biopsy from primary and or neck nodes for histology confirmation), and radiation naïve non-metastatic, inoperable, locally advanced squamous cell carcinoma of head and neck, AJCC stages III to IVB with tumor characteristics of T3 and T4 with or without N2-3, M0, with reduced creatinine clearance (<60 ml/min), age more than 50 years, significant comorbidities like uncontrolled diabetes, cardiac disease, poor performance status (ECOG 3 and 4). | N = 44 (18 for disease-free survival outcome); Mean age (range) 61.3 (50, 72); Female N = 5 (11.4); Stage; III: 16 (36.4); IV A: 18 (40.9); IV B: 10 (22.7); ECOG performance status; 3: 30 (68.2); 4: 14 (31.8) | 50 Gy/16 fractions over weeks | Arm B (Conventional) | | Primary endpoint: Toxicities; Survival; - OS; - Disease-free survival; Harms:; Acute toxicity; - Mucositis; Late toxicity; - Xerostomia (parotid)
Choudhury, 2012 ^78^; SOME CONCERNS; Country NR (Single-center); Funding NR; Median follow-up of 11 months | | | 50 Gy/16 fractions over weeks | N = 42 (22 for disease-free survival outcome); Mean age (range) 61.1 (50, 71); Female N = 7 (16.7); Stage; III: 16 (38.1); IV A: 17 (40.5); IV B: 9 (21.4); ECOG performance status; 3: 33 (78.6); 4: 9 (21.4) | 66 Gy/33 fractions 6 fractions per week over 5.5 weeks | Primary endpoint: Toxicities; Survival; - OS; - Disease-free survival; Harms:; Acute toxicity; - Mucositis; Late toxicity; - Xerostomia (parotid)
Choudhury, 2012 ^78^; SOME CONCERNS; Country NR (Single-center); Funding NR; Median follow-up of 11 months | | | 50 Gy/16 fractions over weeks | Arm C (Conventional) | | Primary endpoint: Toxicities; Survival; - OS; - Disease-free survival; Harms:; Acute toxicity; - Mucositis; Late toxicity; - Xerostomia (parotid)
Choudhury, 2012 ^78^; SOME CONCERNS; Country NR (Single-center); Funding NR; Median follow-up of 11 months | | | 50 Gy/16 fractions over weeks | N = 46 (18 for disease-free survival outcome); Mean age (range) 61.0 (50, 73); Female N = 5 (10.9); Stage; III: 14 (30.4); IV A: 20 (43.5); IV B: 12 (26.1); ECOG; 3: 35 (76.1); 4: 11 (23.9) | 66 Gy/33 fractions over 6.5 weeks | Primary endpoint: Toxicities; Survival; - OS; - Disease-free survival; Harms:; Acute toxicity; - Mucositis; Late toxicity; - Xerostomia (parotid)
Kachhwaha, 2021 ^138^; HIGH; India; Funding NR; Follow-up NR | Inclusion: Age < 70 years; ECOG 0–2; no previous history of malignancy-oriented treatment; adequate baseline organ functions (hematological, renal function test, liver function test, and others); and CT or MRI of head and neck was done to exclude node involvement and for tumor extension. Exclusion: Distant metastasis; other concurrent malignancies; history of previous surgery, radiotherapy, and/or chemotherapy; and pregnant and lactating women. | N = 25; Age; ≤ 55: 16 (64); 56–70: 9 (36); Female N = 1 (4); T stage; 1: 13 (52); 2: 12 (48); ECOG; 0: 9 (36); 1: 16 (64); 2: 0 (0); Tobacco use; Smoker: 21 (84); Chewer: 6 (24); Alcoholic: 6(24) | 55 Gy/20 fractions; 5 days a week for 4 weeks | N = 25; Age; ≤ 55: 13 (52); 56–70: 12 (48); Female n=2 (8); T stage; 1: 11 (44); 2: 14 (56); ECOG; 0: 7 (28); 1: 16 (64); 2: 2 (8); Tobacco use; Smoker: 19 (76); Chewer: 5 (20); Alcoholic: 5 (20) | 66 Gy/33 fractions; 5 days a week for 6.5 weeks | Primary endpoints: Overall survival, disease-free survival; Survival:; - OS; - DFS; Harms:; Toxicity (late); - Dysphagia
Kodaira, 2018 ^76^; LOW; Japan (Multicenter); Health Sciences Research Grants from the Ministry of Health, Labour and Welfare of Japan (20S-5, 20S-6, 17–17, 16–12, 17S-5 H21-018, H24-007 to all authors), and the National Cancer Center Research and Development Funds (23-A-16, 23-A-21, 26-A-4 and 29-A-3 to all authors).; Median follow-up of 4.8 years (IQR, 3.4, 6.2 years) | Inclusion: Patients with histologically confirmed squamous cell carcinoma of the glottis, diagnosed with T1 or T2 (no impaired cord morbidity) N0M0 disease. Radiation therapy was expected to be completed within the recommended duration without interruption due to national holidays. Age 20–80 years, ECOG 0–1, no previous surgery or RT, and no previous cancer or additional current cancers. Patients were required to have sufficient organ function. | N = 186; Median age (IQR) 67 (62, 72); Female N = 6 (3.2); Stage: T; T1a: 100 (53.8); T1b: 40 (21.5); T2: 46 (24.7); T3: 0 (0); Stage: N; N0: 185 (99.5); N2: 1 (0.5); M0: 185 (99.5); M1: 1 (0.5) | T1 Patients (N = 140) | N = 184; Median age (IQR) 68 (63, 73); Female N = 8 (4.3); Stage: T; T1a: 104 (56.5); T1b: 33 (17.9); T2: 46 (25); T3: 1 (0.5); Stage: N; N0: 184 (100); N2: 0 (0); M0: 184 (100); M1: 0 (0) | T1 Patients (N = 137) | Primary endpoint: Progression-free survival at 3 years; Survival; - PFS; - OS; Harms:; Toxicity (acute); - Mucositis (larynx); - Any mucositis; - Dysphagia; Toxicity (late):; - Soft-tissue necrosis
| | N = 186; Median age (IQR) 67 (62, 72); Female N = 6 (3.2); Stage: T; T1a: 100 (53.8); T1b: 40 (21.5); T2: 46 (24.7); T3: 0 (0); Stage: N; N0: 185 (99.5); N2: 1 (0.5); M0: 185 (99.5); M1: 1 (0.5) | 2.4 Gy × 25 fractions 60 Gy | N = 184; Median age (IQR) 68 (63, 73); Female N = 8 (4.3); Stage: T; T1a: 104 (56.5); T1b: 33 (17.9); T2: 46 (25); T3: 1 (0.5); Stage: N; N0: 184 (100); N2: 0 (0); M0: 184 (100); M1: 0 (0) | 66 Gy/33 fractions | Primary endpoint: Progression-free survival at 3 years; Survival; - PFS; - OS; Harms:; Toxicity (acute); - Mucositis (larynx); - Any mucositis; - Dysphagia; Toxicity (late):; - Soft-tissue necrosis
| | N = 186; Median age (IQR) 67 (62, 72); Female N = 6 (3.2); Stage: T; T1a: 100 (53.8); T1b: 40 (21.5); T2: 46 (24.7); T3: 0 (0); Stage: N; N0: 185 (99.5); N2: 1 (0.5); M0: 185 (99.5); M1: 1 (0.5) | ≥ T2 Patients (N = 46) | N = 184; Median age (IQR) 68 (63, 73); Female N = 8 (4.3); Stage: T; T1a: 104 (56.5); T1b: 33 (17.9); T2: 46 (25); T3: 1 (0.5); Stage: N; N0: 184 (100); N2: 0 (0); M0: 184 (100); M1: 0 (0) | ≥ T2 Patients (N = 47) | Primary endpoint: Progression-free survival at 3 years; Survival; - PFS; - OS; Harms:; Toxicity (acute); - Mucositis (larynx); - Any mucositis; - Dysphagia; Toxicity (late):; - Soft-tissue necrosis
| | N = 186; Median age (IQR) 67 (62, 72); Female N = 6 (3.2); Stage: T; T1a: 100 (53.8); T1b: 40 (21.5); T2: 46 (24.7); T3: 0 (0); Stage: N; N0: 185 (99.5); N2: 1 (0.5); M0: 185 (99.5); M1: 1 (0.5) | 2.4 Gy × 27 fractions 64.8 Gy | N = 184; Median age (IQR) 68 (63, 73); Female N = 8 (4.3); Stage: T; T1a: 104 (56.5); T1b: 33 (17.9); T2: 46 (25); T3: 1 (0.5); Stage: N; N0: 184 (100); N2: 0 (0); M0: 184 (100); M1: 0 (0) | 70 Gy/25 fractions | Primary endpoint: Progression-free survival at 3 years; Survival; - PFS; - OS; Harms:; Toxicity (acute); - Mucositis (larynx); - Any mucositis; - Dysphagia; Toxicity (late):; - Soft-tissue necrosis
Moon, 2014 ^75^; SOME CONCERNS; Korea (Multicenter); NCC Grant No. 1310070 from the National Cancer Center; Median follow-up of 67 months (range, 2, 122 months) | Inclusion: histologically confirmed glottic squamous cell carcinoma, 18 years of age or older, Karnofsky Performance Score of 60 or higher, 1997 AJCC stage I or II (T1–2N0M0), no prior RT or chemotherapy for laryngeal cancer, and no history of malignancies for 5 years except non-melanoma skin cancer. Patients with gross residual disease despite stripping or laser excision of a glottic carcinoma were allowed to enroll. | N = 74; Age; < 65: 33 (45); ≥ 65: 41 (55); Female N = 2 (3); Stage: T; T1a: 45 (61); T1b: 20 (27); T2a: 7 (9); T2b: 2 (3); Smoker; Yes: 58 (78); No: 16 (21) | T1 Patients (N = 65) | N = 82; Age; < 65: 42 (51); ≥ 65: 40 (49); Female N = 3 (4); Stage: T; T1a: 48 (59); T1b: 26 (32); T2a: 7 (8); T2b: 1 (1); Smoker; Yes: 64 (78); No: 18 (22) | T1 Patients (n = 74) | Primary endpoint: Progression-free survival at 5 years; Survival:; - OS; - PFS; Harms:; Toxicity (acute and late); - Mucositis; - Larynx
Moon, 2014 ^75^; SOME CONCERNS; Korea (Multicenter); NCC Grant No. 1310070 from the National Cancer Center; Median follow-up of 67 months (range, 2, 122 months) | | N = 74; Age; < 65: 33 (45); ≥ 65: 41 (55); Female N = 2 (3); Stage: T; T1a: 45 (61); T1b: 20 (27); T2a: 7 (9); T2b: 2 (3); Smoker; Yes: 58 (78); No: 16 (21) | 63 Gy/28 fractions Once daily | N = 82; Age; < 65: 42 (51); ≥ 65: 40 (49); Female N = 3 (4); Stage: T; T1a: 48 (59); T1b: 26 (32); T2a: 7 (8); T2b: 1 (1); Smoker; Yes: 64 (78); No: 18 (22) | 66 Gy/33 fractions Once daily | Primary endpoint: Progression-free survival at 5 years; Survival:; - OS; - PFS; Harms:; Toxicity (acute and late); - Mucositis; - Larynx
Moon, 2014 ^75^; SOME CONCERNS; Korea (Multicenter); NCC Grant No. 1310070 from the National Cancer Center; Median follow-up of 67 months (range, 2, 122 months) | | N = 74; Age; < 65: 33 (45); ≥ 65: 41 (55); Female N = 2 (3); Stage: T; T1a: 45 (61); T1b: 20 (27); T2a: 7 (9); T2b: 2 (3); Smoker; Yes: 58 (78); No: 16 (21) | T2 Patients (N = 8) | N = 82; Age; < 65: 42 (51); ≥ 65: 40 (49); Female N = 3 (4); Stage: T; T1a: 48 (59); T1b: 26 (32); T2a: 7 (8); T2b: 1 (1); Smoker; Yes: 64 (78); No: 18 (22) | T2 Patients (N = 8) | Primary endpoint: Progression-free survival at 5 years; Survival:; - OS; - PFS; Harms:; Toxicity (acute and late); - Mucositis; - Larynx
Moon, 2014 ^75^; SOME CONCERNS; Korea (Multicenter); NCC Grant No. 1310070 from the National Cancer Center; Median follow-up of 67 months (range, 2, 122 months) | | N = 74; Age; < 65: 33 (45); ≥ 65: 41 (55); Female N = 2 (3); Stage: T; T1a: 45 (61); T1b: 20 (27); T2a: 7 (9); T2b: 2 (3); Smoker; Yes: 58 (78); No: 16 (21) | 67.5 Gy/30 fractions; Once daily | N = 82; Age; < 65: 42 (51); ≥ 65: 40 (49); Female N = 3 (4); Stage: T; T1a: 48 (59); T1b: 26 (32); T2a: 7 (8); T2b: 1 (1); Smoker; Yes: 64 (78); No: 18 (22) | 70 Gy/35 fractions; Once daily | Primary endpoint: Progression-free survival at 5 years; Survival:; - OS; - PFS; Harms:; Toxicity (acute and late); - Mucositis; - Larynx
Tian, 2014 ^77^; NR; SOME CONCERNS; China (Single-Center); Funding NR; Median follow-up of 25.0 months (range, 6,118 months) | Inclusion: 1) N = 59 histologically confirmed locally recurrent NPC or NPC diagnosed by clinical symptoms and radiological findings in those patients with disease located in the skull base or intracranial cavity that was inaccessible for biopsy; 2) no evidence of distant metastases at diagnosis; 3) > 6 months between the end of primary radiation therapy (RT) and disease recurrence; and 4) a Karnofsky performance status score of at least 70; Exclusion: Previous chemotherapy, RT, or definitive surgery after the diagnosis of locally recurrent NPC. Patients with another active cancer or unstable cardiac or renal disease that required treatment. | N = 59; Median age (range) 47.5 (25,61); Female N = 10 (16.9); Stage: T; T1: 6 (10.2); T2: 7 (11.9); T3: 24 (40.7); T4: 22 (37.3); Stage: N; N0: 50 (84.7); N1-2: 9 (15.3) | 60 Gy/27 fractions 5 days per week | N = 58; Median age (range) 46.0 (28,65); Female N = 13 (22.4); Stage: T; T1: 4 (6.9); T2: 8 (13.8); T3: 22 (37.9); T4: 24 (41.4); Stage: N; N0: 52 (89.7); N1-2: 6 (10.3) | 68 Gy/34 fractions 5 days per week | Primary endpoint: Overall survival; Survival:; - OS; - Progression-free survival; - Local recurrence; Harms:; Toxicity (acute); - Mucositis; Toxicity (late); - Xerostemia; - Mucosal necrosis; - Temporal lobe necrosis
Tolia, 2013 ^139^; HIGH; Greece; Funding NR; Follow-up NR | Inclusion: a) 18 years or older; b) Inoperable disease (the constitutional state of all patients precluded an operation for medical reasons and/or severe comorbidities); c) Newly diagnosed moderately advanced head and neck carcinoma; d) Pathologically proven squamous cell tumor. e) Receiving RT and regular follow-up at the radiation oncology Unit of Attikon University Hospital; f) Prospectively randomized selected patients; & g) Completion of the self-reported questionnaire. | N = 13; Median Age (Range) 61 (46,76); Female N = 3 (23.1); Stage; IVa: 10 (76.9); IVb: 3 (23.1) | 64.4 Gy/28 fractions 5 day per weeks | N = 9; Median age (range) 67 (54,78); Female N = 2 (22.2); Stage; IVa: 6 (66.7); IVb: 3 (33.3) | 70 Gy/35 fractions 5 days per week | Primary endpoint: overall survival; Survival:; - OS; Quality of Life: (EORTC QLQ-H&N35); Harms:; Overall toxicity (acute and late)
Yamazaki, 2006 ^140^; HIGH; Japan; Supported by a grant from the Ministry of Health and Welfare of Japan; Median follow-up of 64 months (Range, 24,122 months) | Inclusion: Patientswith invasive, previously untreated, T1 squamous cell carcinoma of the true vocal cords were enrolled in this trial with curative intent at the Department of Radiation Oncology, Osaka Medical Center for Cancer and Cardiovascular Diseases. | N = 88; Mean Age (SD) 64 (9); Female N = 3 (3); Stage: T; T1a: 71 (81); T1b: 17 (19); Smoker; Yes: 82 (93); No: 6 (7) | Arm A-1 (N = 71) | N = 92; Mean age (SD) 65 (10); Female N = 7 (8); Stage: T; T1a: 73 (79); T1b: 19 (21); Smoker; Yes: 83 (90); No: 9 (10) | Arm B-1 (N = 73) | Primary endpoint: progression-free survival; Survival:; - PFS; - OS; Harms:; Toxicity (acute); - Dermatitis; - Mucositis
Yamazaki, 2006 ^140^; HIGH; Japan; Supported by a grant from the Ministry of Health and Welfare of Japan; Median follow-up of 64 months (Range, 24,122 months) | | N = 88; Mean Age (SD) 64 (9); Female N = 3 (3); Stage: T; T1a: 71 (81); T1b: 17 (19); Smoker; Yes: 82 (93); No: 6 (7) | 60 Gy/30 fractions over 6 weeks | N = 92; Mean age (SD) 65 (10); Female N = 7 (8); Stage: T; T1a: 73 (79); T1b: 19 (21); Smoker; Yes: 83 (90); No: 9 (10) | 56.25 Gy/25 fractions over 5 weeks | Primary endpoint: progression-free survival; Survival:; - PFS; - OS; Harms:; Toxicity (acute); - Dermatitis; - Mucositis
Yamazaki, 2006 ^140^; HIGH; Japan; Supported by a grant from the Ministry of Health and Welfare of Japan; Median follow-up of 64 months (Range, 24,122 months) | | N = 88; Mean Age (SD) 64 (9); Female N = 3 (3); Stage: T; T1a: 71 (81); T1b: 17 (19); Smoker; Yes: 82 (93); No: 6 (7) | Arm A-2 (N = 17) | N = 92; Mean age (SD) 65 (10); Female N = 7 (8); Stage: T; T1a: 73 (79); T1b: 19 (21); Smoker; Yes: 83 (90); No: 9 (10) | Arm B-2 (N = 19) | Primary endpoint: progression-free survival; Survival:; - PFS; - OS; Harms:; Toxicity (acute); - Dermatitis; - Mucositis
Yamazaki, 2006 ^140^; HIGH; Japan; Supported by a grant from the Ministry of Health and Welfare of Japan; Median follow-up of 64 months (Range, 24,122 months) | | N = 88; Mean Age (SD) 64 (9); Female N = 3 (3); Stage: T; T1a: 71 (81); T1b: 17 (19); Smoker; Yes: 82 (93); No: 6 (7) | 66 Gy/33 fractions over 6.6 weeks | N = 92; Mean age (SD) 65 (10); Female N = 7 (8); Stage: T; T1a: 73 (79); T1b: 19 (21); Smoker; Yes: 83 (90); No: 9 (10) | 63 Gy/28 fractions over 5.6 weeks | Primary endpoint: progression-free survival; Survival:; - PFS; - OS; Harms:; Toxicity (acute); - Dermatitis; - Mucositis

Notes. *Risk of bias differed by outcome.

Abbreviations. AJCC=American Joint Committee on Cancer; CT=computed tomography; CTCAE=Common Terminology Criteria for Adverse Events; DFS=Disease-Free Survival; ECOG=Eastern Cooperative Oncology Group performance assessment; EORTC QLQ-H&N 35=European Organization for Research and Treatment of Cancer Quality of Life Questionnaire Head and Neck module; MRI=magnetic resonance imaging; NPC=nasopharyngeal cancer; OS=Overall Survival; PFS=progression-free survival.

Appendix Table 18 Detailed Results for Survival Outcomes for Head and Neck Cancer Trials Rated “Low” or “Some Concerns” Risk of Bias

Trial Name, Year Trial # Risk of Bias | Effect Measure/Definition | Hypofractionation N Events/Total N, (%) | Comparison N Events/Total N, (%) | Results
Overall Survival
Tian, 2014 ^77^; NR; SOME CONCERNS | 3-year overall survival | 57.4% (deaths: 25/59) | 38.0% (deaths: 36/58) | P = 0.06
Tian, 2014 ^77^; NR; SOME CONCERNS | 5-year overall survival | 44.2% (deaths: 33/59) | 30.3% (deaths: 39/56) | P = 0.06
Kodaira, 2018 ^76^; NR; LOW | 3-year overall survival | 174/186 (93.5%); 95% CI: (88.9%, 96.3%) | 181/184 (98.4%); 95% CI: (95%, 99.5%) | NR
Moon, 2014 ^75^; NR; SOME CONCERNS | 2-year overall survival | 100% | 96.2% | P = 0.359
Moon, 2014 ^75^; NR; SOME CONCERNS | 5-year overall survival | 86.6% | 82.5% | P = 0.359
Progression-free Survival
Kodaira, 2018 ^76^; NR; LOW | 3-year | 152/186 (81.7%); 95% CI: (75.4%,87.0%) | 147/184 (79.9%); 95% CI: (73.4%, 85.4%) | P = 0.047
Moon, 2014 ^75^; SOME CONCERNS | 5-year | 88.5% | 77.8% | HR: 1.55; P = 0.213
Tian, 2014 ^77^; NR; SOME CONCERNS | 5-year | 56.8% | 55.2% | P = 0.58
Local Recurrence
Kodaira, 2018 ^76^; NR; LOW | 3-year | 8/186 (4.3%) | 5/184 (2.7%) | NR
Moon, 2014 ^75^; NR; SOME CONCERNS | 5-year | 9/74 (12.2%) | 16/82 (19.5%) | NR
Tian, 2014 ^77^; NR; SOME CONCERNS | 5-year | 12/35 (34.2%) | 11/44 (25%) | NR
Mortality
Tian, 2014 ^77^; NR; SOME CONCERNS | Median follow-up 25.0 months; Total deaths | 35/59 | 44/58 | NR
Tian, 2014 ^77^; NR; SOME CONCERNS | Death due to disease progression | 18/35 (51.4%) | 18/44 (40.9%) | P value = 0.95
Tian, 2014 ^77^; NR; SOME CONCERNS | Death due to late complications | 14/35 (40.0%) | 24/58 (54.5%) | P value = 0.02
Tian, 2014 ^77^; NR; SOME CONCERNS | Death due to other causes | 3/35 (8.5%) | 2/44 (4.5%) | NR
Kodaira, 2018 ^76^; NR; LOW | Death due to glottic cancer | 8 (4.3) | 5 (2.7) | NR
Kodaira, 2018 ^76^; NR; LOW | Death due to other diseases | 11 (5.9) | 10 (5.4) | NR

Abbreviations. CTCAE=Common Terminology Criteria for Adverse Events; EORTC QLQ-H&N 35=European Organization for Research and Treatment of Cancer Quality of Life Questionnaire Head and Neck module.

Appendix Table 19 Detailed Results for Toxicity Outcomes for Head and Neck Cancer Trials Rated “Low” or “Some Concerns” Risk of Bias

Trial Name, Year Trial # Risk of Bias | Effect Measure/Definition | Hypofractionation N Events/Total N, (%) | Comparison N Events/Total N, (%) | Results
Acute Dysphagia
Kodaira, 2018 ^76^; NR; LOW | Acute grade 3–4 (no specified time period)/CTCAE v. 3.0 | 0/177 (0) | 0/183 (0) | NR
Acute Mucositis
Kodaira, 2018 ^76^; NR; LOW | Acute CTCAE v.3.0 (time period NR) | [underlined: Mucositis (laryngeal)]; - Grade 1–2: 164/183 (89.6); - Grade 3–4: 10/183 (5.5); [underlined: Any mucositis]; - Grade 1–2: 172/183 (94); - Grade 3–4: 11/183 (6) | [underlined: Mucositis (laryngeal)]; - Grade 1–2: 159/177 (89.8); - Grade 3–4: 7/177 (4); [underlined: Any mucositis]; - Grade 1–2: 165/177 (93.2); - Grade 3–4: 9 (5.1) | NR
Moon, 2014 ^75^; NR; SOME CONCERNS | Acute grade ≥ 2 RTOG/EORTC | [underlined: 0/74] | [underlined: 0/82] | P = 1.0
Tian, 2014 ^77^; NR; SOME CONCERNS | Acute grade 3 RTOG/EORTC | 5/59 (8.5) | 8/58 (13.8) | P = 0.39
Late Mucositis
Moon, 2014 ^75^; NR; SOME CONCERNS | Late RTOG/EORTC (median follow-up 67 months) | Grade 2: 0; Grade 3–4: 0 | Grade 2: 1; Grade 3–4: 0 | P = 0.78
Choudhury, 2012 ^78^; NR; LOW | Late RTOG/EORTC mucositis 2 and 3 | Grade 2: 14/44; Grade 3: 6/44 | Grade 2: 30/88; Grade 3: 3/88 | P = 0.001
Late Laryngeal
Moon, 2014 ^75^; NR; SOME CONCERNS | Late RTOG/EORTC (median follow-up 67 months) | Grade 2: 0; Grade 3–4: 0 | Grade 2: 2; Grade 3–4: 0 | P = 0.84
Late Xerostomia
Choudhury, 2012 ^78^; NR; LOW | Late RTOG/EORTC grade 2 and 3 (parotid only) | Grade 2: 14/44; Grade 3: 6/44 | Grade 2: 30/88; Grade 3: 3/88 | P = 0.005
Tian, 2014 ^77^; NR; SOME CONCERNS | Late grade 3 RTOG/EORTC | 8/59 (13.6) | 6/58 (10.3) | P = 0.42
Late Tissue Necrosis
Kodaira, 2018 ^76^; NR; LOW | Late soft tissue (cervix) CTCAE v.3.0 (time period NR) | Grade 1–2: 1/184 (0.5); Grade 3: 0/184 (0); Grade 4: 0/184 (0) | Grade 1–2: 0/182 (0); Grade 3: 0/182 (0); Grade 4: 1/182 (0.6) | NR
Tian, 2014 ^77^; NR; SOME CONCERNS | Temporal lobe necrosis | 12/59 (20.3) | 13/58 (22.4) | P = 0.59

Abbreviations. CTCAE=Common Terminology Criteria for Adverse Events; EORTC QLQ-H&N 35=European Organization for Research and Treatment of Cancer Quality of Life Questionnaire Head and Neck module; RTOG=Radiation Therapy Oncology Group.