# APPENDIX F LUNG CANCER TABLES

Appendix Table 11 Risk of Bias Ratings for All Eligible Lung Cancer Trials

Trial | Outcome | Domain 1: Risk of Bias Arising from the Randomization Process | Domain 2a: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Assignment to Intervention) | Domain 2b: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Adherence to Intervention) | Domain 3: Risk of Bias Due to Missing Outcome Data | Domain 4: Risk of Bias in Measurement of the Outcome | Domain 5: Risk of Bias in Selection of the Reported Result | Overall Risk of Bias
Ball^10^ | Harms | Low | Low | Low | Low | Low | Low | Low
Ball^10^ | Survival | Low | Low | Low | Low | Low | Low | Low
Ball^10^ | QoL | Low | Low | Low | Low | Low | Low | Low
Gronberg^133^ | Harms | Some concerns | High | High | Low | Low | Some concerns | High
Gronberg^133^ | Survival | Some concerns | High | High | Low | Low | Some concerns | High
Gronberg^133^ | QoL | Some concerns | High | High | Low | Low | Some concerns | High
Iyengar^74^ | Harms | Low | Low | Low | Low | Low | Low | Low
Iyengar^74^ | Survival | Low | Low | Low | Low | Low | Low | Low
Roy^73^ | Harms | Low | Some concerns | Some concerns | Low | Some concerns | Some concerns | Some concerns
Roy^73^ | Survival | Low | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns
Roy^73^ | QoL | Low | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns
Singh^134^ | Harms | High | Low | Low | Some concerns | Low | Low | High
Singh^134^ | Survival | High | Low | Low | Some concerns | Low | Low | High
Singh^134^ | QoL | High | Low | Low | Some concerns | Low | Low | High
Slawson^135^ | Survival | Some concerns | High | High | Low | Low | Some concerns | High
Nyman^72^ | Harms | Some concerns | Low | Some concerns | Low | Low | Low | Some concerns
Nyman^72^ | Survival | Some concerns | Low | Some concerns | Low | Low | Low | Some concerns
Nyman^72^ | QoL | Some concerns | Low | Some concerns | Low | Low | Low | Some concerns
Qiu^71^ | Harms | Low | Low | Low | Low | Low | Low | Low
Qiu^71^ | Survival | Low | Low | Low | Low | Low | Low | Low

Appendix Table 12 Study Characteristics for All Eligible Lung Cancer Trials

Trial Name, Year; Trial #; Risk of Bias Country Funding; Follow-up | Inclusion/Exclusion Criteria | Hypofractionation Characteristics | | Standard of Care Characteristics | | Outcomes Reported (Risk of Bias If Different by Outcome)
Trial Name, Year; Trial #; Risk of Bias Country Funding; Follow-up | Inclusion/Exclusion Criteria | N; Baseline Characteristics (n, %) | Dose/Fraction; Total Dose; Time | N; Baseline Characteristics (n, %) | Dose/Fraction; Total Dose; Time | Outcomes Reported (Risk of Bias If Different by Outcome)
Qui, 2021 ^71^; NCT02337712; LOW; Multicenter; NR; NR; Median follow-up of 24.3 months | Eligibility criteria included being 18 to 75 years old and having pathologically confirmed SCLC with LS as defined by the Veterans Administration Lung Cancer Study Group; measurable lesions based on the Response Evaluation Criteria in Solid Tumors (RECIST) criteria; and Eastern Cooperative Oncology Group performance status (ECOG PS) of 0 to 1; an acceptable radiation therapy target volume as judged by the radiation oncologists; adequate bone marrow and hepatic renal functions; forced expiratory volume in 1 second greater than 1 L; no prior chemotherapy, radiation therapy, surgery, or other anticancer therapy; weight loss ≤10% within the past 3 months; and the ability to provide informed consent. Patients with mixed small and non-small cell carcinoma were excluded. | N = 88; Age, median(range): 58 (35-75); Female: 14 (15.9%); ECOG PS; 0 40(45.5%); 1 48(54.5%); Unknown 0; Nonsmoker 16(18.2%); Smoker 72(81.8%); Unknown 0; UICC/AJCC stage; IA-B 1(1.2%); IIA-B 3(3.5%); IIIA-B 84(95.3%) | 65 Gy in 26 daily fractions for 5 days a week over 36 days, once daily | N = 94; Age, median(range): 58 (19-75); Female: 11(11.7%); ECOG PS; 0 49(52.1%); 1 43(45.7%) Unknown 2(2.1%); Nonsmoker 11 (11.7%); Smoker 82(87.2%); Unknown 1(1.1%); UICC/AJCC stage; IA-B 2(2.2%); IIA-B 6(6.5%); IIIA-B 86(91.3%) | 45 GY in 30 twice-daily fractions, with an interfractional interval of at least 6 hours, for 5 days a week for 19 days | Survival:; - PFS; - OS; - LPFS; - DMFS; Harms:; Acute; - Cough; - Dyspnea^**^; - Pneumonitis; - Pleural effusion^**^; - Atelectasis^**^; - Esophagitis; - Nausea^**^; - Vomiting^**^; - Anemia^**^; - Leukopenia^**^; - Lymphopenia^**^; - Neutropenia^**^; - Thrombocytopenia^**^; - Fatigue^**^; - Fever^**^; - Weight loss^**^; Late:; - Cough; - Hemoptysis^**^; - Dyspnea^**^; - Pneumonitis; - Pleural effusion^**^; - Pulmonary fibrosis^**^; - Anemia^**^; - Leukopenia^**^; Primary Endpoint: PFS; Secondary Endpoint: OS, locoregional progression-free survival (LPFS), distant metastasis free survival (DMFS), and toxicities
Ball, 2021 (CHISEL) ^10^; NCT01014130; LOW; Multicenter: 11 hospitals in Australia and 3 hospitals in New Zealand; Funding: The Radiation and Optometry Section of the Australian Government Department of Health with the assistance of Cancer Australia, and the Cancer Society of New Zealand and the Cancer Research Trust New Zealand (formerly Genesis Oncology Trust).; Median follow-up per group for local treatment failure was 2.1 years (IQR 1.23. 6) for patients randomly assigned to standard radiotherapy and 2.6 years (IQR 1.6-3.6) for patients assigned to SABR | Eligible patients had cytologically or histologically proven stage T1N0M0 or T2aN0M0 NSCLC according to the seventh edition of the Union for International Cancer Control TNM staging manual. Eligible cancer types: squamous cell carcinoma, adenocarcinoma, large cell carcinoma, bronchioloalveolar cell carcinoma, large cell neuroendocrine carcinoma, and non-small-cell carcinoma not otherwise specified. Patients were aged 18 years or older and had an Eastern Cooperative Oncology Group (ECOG) performance status of 0 or 1. The tumour had to be noncentral, defined as at least 1 cm from the mediastinum and 2 cm from the bifurcation of the lobar bronchi. To be eligible, the patient’s tumour had to be assessed as medically inoperable by a multidisciplinary team including thoracic surgeons and respiratory physicians, or the patient had to have refused surgery. Patients were ineligible if they had had previous chemotherapy or radiotherapy for the index cancer, or had multiple synchronous primary tumours requiring radiotherapy. To be eligible, patients needed to have a life expectancy of 2 years or more. | N = 66; Age, median(IQR): 73.2 (68.9-78.6); Female: 30(45%); ECOG PS; 0 18(28%); 1 47(72%); Missing 1(1%); Current smoker; No 45 (69%); Yes 20 (31%); Missing 2 (1%); Current or previous smoker; No 2 (3%); Yes 63 (97%); Missing 1 (1%); T stage; 1 47 (71%); 2a 19 (29%) | 18 Gy/fraction; 54 Gy total; 3 fractions; For tumours <2 cm from chest wall:; 12 Gy/fraction; 48 Gy total; 4 fractions | N = 35; Age, median(IQR): 77 (69.6-81.2); Female: 15(43%); ECOG PS; 0 10 (29%); 1 25 (71%); Unknown 0; Current Smoker; No 21 (60%); Yes 14 (40%); Missing 0; Current or previous smoker; No 0; Yes 35 (100%); Missing 0; T stage; 1 24 (69%); 2a 11 (31%) | 66 Gy in 33 daily 2 Gy fractions over 6. 5 weeks or, 50 Gy in 20 daily 2. 5 Gy fractions over 4 weeks according to institutional preference | Survival:; - LTF; - OS; - LCSS; Harms:; - Dyspnea^**^; - Cough; - Fatigue **; - Chest wall pain **; - Lung infection **; - Pain **; - Cataract **; - Hypoxia **; - Weight loss **; - Pulmonary fibrosis^**^; - Dermatitis radiation **; - Nausea **; - Atelectasis **; - Pneumonitis; - Pleural effusion^**^; - Fracture **; - Anorexia **; - Dysphagia **; - Bronchopulmonary haemorrhage **; - Dizziness **; - Dry mouth^**^; - Infections and infestations **; - Superficial soft tissue fibrosis **; - Back pain^**^; - Diarrhoea **; - Non-cardiac chest pain^**^; - Pericardial effusion^**^; - Respiratory, thoracic, and mediastinal disorders^**^; - Skin and subcutaneous tissue disorders **; - Vomiting^**^; - Abdominal distension^**^; - Abdominal pain^**^; - Anxiety **; - Constipation **; - Dehydration **; - Dry skin **; - Dysgeusia **; - Erythema multiforme **; - Esophagitis; - Gastro-oesophageal reflux disease **; - Laryngeal inflammation **; - Mucosal infection **; - Musculoskeletal and connective tissue disorder^**^; - Myalgia^**^; - Oral haemorrhage^**^; - Toothache^**^; - Upper respiratory infection^**^; - Urinary tract infection^**^; Primary endpoint: Local treatment failure; Secondary endpoint: Overall survival, lung cancer-specific survival, treatment-related toxicity, and quality of life
Iyengar, 2021 ^74^; NCT01459497; LOW; Multicenter:; 9 cancer centers in Texas, USA; This study was supported by a grant from the Cancer Prevention and Research Institute of Texas (principal investigator, Dr Timmerman).; Median follow-up of 8.7 (3.6-19.9) months | Eligibility criteria: Histologically proven stage II/III or recurrent NSCLC. A Zubrod (ECOG) performance status of 2 or greater (0 indicates asymptomatic; 5, death); had greater than 10% weight loss in the previous 6 months, and/or were ineligible for concurrent chemoradiotherapy after consultation with radiation and medical oncologists. Patients were ineligible if they had a total gross tumor volume greater than 500 mL, had undergone prior regional radiotherapy, received chemotherapy within 1 week of study registration, or were pregnant or lactating. | N = 50; Age N (%); 50-59: 6 (12.0); 60-69:13 (26.0); 70-79: 18 (36.0); 80-90: 13 (26.0); Female: 20 (40); Baseline performance status; 0 1 (2.0); 1 16 (32.0); 2 28 (56.0); 3 5 (10.0); T category; T0 1 (2.0); T1 12 (24.0); T2 19 (38.0); T3 10 (20.0); T4 8 (16); N category; N0 8 (16.0); N1 12 (24.0); N2 26 (52.0); N3 4 (8.0); Stage; IB 1 (2.0) 0; II 12 (24.0); III 36 (72.0); Recurrent IV 1 (2.0) | 60 Gy; 15 fractions | N = 46; Age N (%); 50-59 9 (19.6); 60-69 12 (26.1); 70-79) 17 (37.0); 80-90) 8 (17.4); Female: 13 (28.3); Baseline performance status; 0 1 (2.2); 1 13 (28.3); 2 29 (63.0); 3 3 (6.5); T category; T0 1 (2.2); T1 5 (10.9); T2 15 (32.6); T3 15 (32.6); T4 10 (21.7); N category; N0 15 (32.6); N1 3 (6.5); N2 17 (37.0); N3 11 (23.9); Stage; IB 1 0; II 10 (21.7); III 35 (76.1); Recurrent IV 1 (2.2) | 60 Gy; 30 fractions | Survival:; - OS; - MOS; - PFS; - LC; Harms:; Cardiovascular:; - Pericardial effusion^**^; - SVC syndrome^**^; Death NOS; Fatigue^**^; Gastrointestinal tract:; - Anorexia^**^; - Dysphagia^**^; - Esophagitis; - Nausea^**^; Musculoskeletal:; - Back pain^**^; - Chest wall pain^**^; Respiratory:; - ARDS^**^; - Atelectasis^**^; - Bronchitis^**^; - Cough; - DLCO decline^**^; - Dyspnea **; - FEV1 decline^**^; - Hemoptysis^**^; - Pleural effusion^**^; - Pneumonia^**^; - Pneumonitis; - Pulmonary fibrosis^**^; - Wheezing **; Skin:; - Dermatitis **; - Dryness **; - Hyperpigmentation^**^; - Pruritus^**^; Primary endpoint:; OS; Secondary endpoint: MOS, PFS, Toxicity
Nyman, 2016; SPACE trial ^72^; NCT01920789; LOW; Multicenter: 9; Scandinavian Centers; This study was supported by grants from the Nordic Cancer; Union (NCU), and King Gustav V Jubilee Clinic Cancer Foundation in Gothenburg; Median follow-up of 37 months | The inclusion criteria were patients in WHO performance status 0 to 2 with stage I (T_1-2_N0M0, AJCC 6th edition) nonsmall cell lung cancer who were medically inoperable or refused surgery. The tumors should be morphologically verified. If that was impossible due to peripheral lesion and poor lung function (intolerance for pneumothorax), there had to be an increasing tumor size in repeated CT-scans and a positive PET-scan. The main exclusion criteria were central tumor growth adjacent to trachea, main bronchus or esophagus, maximal tumor diameter >6 cm, patients with prior malignancy in the last five years and if previous radiotherapy had been delivered to the thorax. | N = 49; Age mean (range) 73 (57-86); Female: 27 (55%); Baseline performance status; 0 11 (22.5%); 1 27 (55%); 2 10 (20.5%); Missing 1 (2%); Tumor stage; T1 26(53%); T2 23(47%) | 66 Gy; 3 fractions (1 week) | N = 53; Age mean (range); 75 (62-85); Female: 34 (64%); Baseline performance status; 0 5 (9.5%); 1 33 (62%); 2 14 (26.5%); Missing 1 (2%); Tumor stage; T1 40(75%); T2 13(25%) | 70 Gy; 35 fractions (7 weeks) | Survival:; - PFS; - OS; - LC; Quality of life; Harms:; - Toxicity (acute, late); Esophagitis; Pneumonitis; Dyspnea **; Fibrosis^**^; Cough; Skin reactions^**^; Rib fractures^**^; Primary endpoint: PFS; Secondary endpoint: OS, LC, Toxicity, QoL
Roy, 2016 ^73^; Clinical Registry of India number CTRI/2013/11/004143; LOW; Single Center: All India Institute of Medical Sciences, New Delhi, India; NR; Median follow-up 15 months | Eligibility criteria included newly diagnosed patients (previously untreated) of biopsy-proven SCC of the lung with a performance status score of Eastern Co-operative Oncology Group 0-1, stages IIIA and IIB without significant haematological or other systemic (renal, hepatic or pulmonary) impairments. Patients with hypersensitivity to platinum agents or comorbidities that can adversely affect treatment and outcome or those who had prior or synchronous malignancies were excluded from the study. | Hypofractionation; N = 18; Age; Median (range): 60 (42-70); Mean±SD: 58±8.48; Female: 1; Smoker:17; Non-smoker:1; Stage; IIIA:7; IIB:11 | 48 Gy; 20 fractions (4 weeks) | Standard RT; N = 18; Age; Median (range): 55 (42-70); Mean±SD:; 56±8.08; Female: 1; Smoker:17; Non-smoker:1; Stage; IIIA:8; IIB:10 | 60 Gy; 30 fractions (6 weeks) | Survival:; - ORR; - PFS; - OS; Quality of life^**^; Harms:; Toxicity (acute); Haemotological:; - Anaemia^**^; - Neutropaenia^**^; - Thrombocytopaeni a^**^; Non-haemotological:; - Skin reaction^**^; - Anorexia^**^; - Mucositis^**^; - Laryngitis^**^; - Pharyngitis/oesop hagitis; - Pneumonitis; - Peripheral neuropathy^**^; - Hyponatraemia^**^; Toxicity (late); - Lung fibrosis^**^; - Oesophageal morbidity^**^; - Skin morbidity^**^; - Neurological toxicity^**^; Primary endpoint: ORR; Secondary endpoint: OS, PFS, Toxicity, QoL
Gronberg, 2015 ^133^; Registration NR; High; NR; Study supported by the Central Norway Regional Health Authority (RHA), the Norwegian University of Science and Technology (NTNU) and the Norwegian Cancer Society.; Median follow-up for PFS was 59 months (range 29-97); Median follow-up for OS was 81; months (range 52119) | Eligible patients were ≥18 years old (no upper limit); had SCLC ineligible for surgery and confined to 1 hemithorax and the mediastinum, contralateral hilus and supraclavicular regions; measurable disease according to RECIST v1.0; no other active cancer; no prior chest-radiotherapy; WHO performance status (PS) 0-2; leukocytes ≥3.0 × 10^9^/l, platelets ≥100×10^9^/l, bilirubin <1.5 × ULN and creatinine <125 pmol/l. One negative cytology was required if pleural effusion was present. | Hypofractionation; N = 84; Age; Median(range):; 63(40-85); Female:39 (46%); Baseline WHO performance status; 0 31 (37%); 1 42 (50%); 2 11 (13%); Stage; I 7 8%; II 7 8%; IIIA 34 40%; IIIB 30 36%; Unknown 6 7% | 42 Gy; 15 fractions (once daily) | Twice daily thoracic RT; N = 73; Age; Median(range):63(44-79); Female:37 (51%); Baseline WHO performance status; 0 20 (27%); 1 39 (53%); 2 14 (19%); Stage; Stage I 6 8%; II 9 12%; IIIA 21 29%; IIIB 28 38%; Unknown 9 12% | 45 Gy; 30 fractions (twice daily, hyperfractionation) | Survival:; - PFS; - OS; HRQoL; Harms:; Toxicity; - Esophagitis; - Pneumonitis; - Anemia^**^; - Leukopenia^**^; - Thrombocytopenia; **; - Neutropenia^**^; - Neutropenic infection^**^; - Infection without neutropenia^**^; - Dysphagia^**^; - Dyspnea^**^; Primary endpoint: PFS; Secondary endpoint: OS, Toxicity, HRQoL
Slawson, 1988 ^135^; Registration NR; High; Single Center.; Department of Radiation Oncology, University of Maryland Medical; Supported from Developmental Account, Department of Radiation Oncology, University of Maryland Medical Systems; Median follow-up NR | Eligible patients had locally advanced, nonmetastatic, measurable lung cancer. Patients were required to have a pathologically-proved, previously unirradiated lung cancer. Patients had to have measurable disease and no evidence of distant metastases to sites other than the ipsilateral supraclavicular region and/or brain. | Hypofractionation; N = 73; Baseline ECOG performance status:; 0-1 62; 2-3 38; Stage; III 96; IV 4 | 5 Gy/fraction; Total 60 Gy; 12 fractions (12 weeks) | Hyperfractionation; N = 77; Baseline ECOG performance status:; 0-1 64; 2-3 36; Stage; III 97; IV 3 | 2 Gy/fraction; Total 60 Gy; 30 fractions (6 weeks) | Survival; - Median survival; - Local failure; - Local and distant failure; - Distant failure; Harms (acute); - Weight loss; - Nausea and vomiting; Toxicity; - Esophagitis; - Skin reaction; Harms (late); - Skin fibrosis
Singh, 2019 ^136^; Registration NR; High; Multi-center, three centers in the US.; Supported by Roswell Park Alliance Foundation grant.; Median follow-up 53.8 months | Eligibility criteria included the following: patients aged 18 years or older with a Zubrod (ECOG) performance status score of 0 to 2, deemed medically inoperable or refused surgery, and with early-stage, histologically proven NSCLC defined as American Joint Committee on Cancer sixth edition T1 to T2 (≤5 cm) N0M0 after staging by computed tomography (CT) and positron emission tomography (PET) studies. Tumors had to be characterized as peripheral per Radiation Therapy Oncology Group (RTOG) 0236. | SBRT Arm 1; N = 49; Age, mean (SD) 77(8); Female 27 (55%); T stage; T1a 20 (41%); T1b 21 (43%); T2a 8 (16%); Overall Stage; 1A 39 (80%); 1B 10 (20%) | 30 Gy/fraction; Total 30 Gy; 1 fraction | SBRT Arm 2; N = 49; Age, mean (SD) 75 (8); Female 23 (47%); T stage; T1a 27 (55%); T1b 16 (33%); T2a 6 (12%); Overall stage; 1A 42 (86%); 1B 7 (14%) | 20 Gy/fraction; Total 60 Gy; 3 fractions | Survival; - LC; - PFS; - OS; QoL; Harms; Any AE; Toxicity (acute); - Pneumonia; - COPD; - Cough; - Dyspnea; - Dyspnea, exertional; - Wheezing; Primary endpoint: Toxicity; Secondary endpoint: LC, OS, PFS, QoL

Notes.

* Risk of bias differed by outcome;

** Did not extract.

Abbreviations. SCLC=small cell lung cancer; LS=limited stage4; ECOG PS=Eastern Cooperative Oncology Group performance status; AJCC=American Joint Committee on Cancer; UICC=Union for International Cancer Control; NOS=not otherwise specified; PFS=progression-free survival; OS=overall survival; LPFS=locoregional progression-free survival; DMFS=distant metastasis free survival; LC=local control; MOS=Median Overall Survival; ORR=overall response to treatment; HRQoL=health-related quality of life.

Appendix Table 13 Detailed Results for Survival Outcomes for Lung Cancer Trials Rated “Low” or “Some Concerns” Risk of Bias

Trial Name, Year Trial # Risk of Bias | Effect Measure/Definition | Hypofractionation N Events/Total N, (%) | Comparison N Events/Total N, (%) | Results
Overall Survival
Qui, 2021 ^71^; NCT02337712; LOW | Median OS months | 39.3 (31.1, 47.2) | 33.6 (30.2, 37.0) | P = 0.14
Qui, 2021 ^71^; NCT02337712; LOW | 2-year OS | 74.2% (64.0, 84.3) | 69.9% (59.9, 79.9) | NR
Qui, 2021 ^71^; NCT02337712; LOW | 3-year OS | 56.2% (43.2, 69.1) | 41.5% (29.0, 54.0) | NR
Qui, 2021 ^71^; NCT02337712; LOW | 5-year OS | 56/88* | 48/94* | NR
Qui, 2021 ^71^; NCT02337712; LOW | Median OS (95% CI) | SABR: 5 years (3.4 to not estimable) | Standard RT: 3 years (1.9 to not estimable) | HR = 0.53 (95% CI [0.30, 0.94]) (P = 0.027)
Qui, 2021 ^71^; NCT02337712; LOW | Kaplan Meier; 2-year overall survival % (95% CI)/time (years) from randomization until death from any cause | SABR: 77% (67, 88) | Standard RT: 59% (44, 78) | NR
Iyengar, 2021 ^74^; NCT01459497; LOW | 1 year overall survival median rate (95% CI)/time from randomization until death from any cause | 37.7%; (95% CI [24.2%, 51.0%]) | 44.6%; (95% CI [29.9%, 58.3%]) | P = 0.29
Iyengar, 2021 ^74^; NCT01459497; LOW | Median overall survival rate (95% CI)]/ time from randomization until death from any cause | 8.2 months; (95% CI [5.4,12.4]) | 10.6 months; (95% CI [8.4, 15.3]) | P = 0.17
Nyman, 2016 ^72^; NCT01920789; LOW | Kaplan Meier [median rate (95% CI)]/date of randomization to death; 1 year | 81% | 89% | HR = 0.75 (95% CI [0.43,1.30])
Nyman, 2016 ^72^; NCT01920789; LOW | 2 years | 68% | 72% | HR = 0.75 (95% CI [0.43,1.30])
Nyman, 2016 ^72^; NCT01920789; LOW | 3 years | 54% | 59% | HR = 0.75 (95% CI [0.43,1.30])
Roy, 2016 ^73^; CTRI/2013/11/004143; LOW | Kaplan Meier; (log-rank test)/period from date of diagnosis to death or last follow-up | 75%; Median OS: 24.7 months | 52%; Median OS: 12.3 months | P = 0.007 (log-rank test)
Progression-free Survival
Qui, 2021 ^71^; NCT02337712; LOW | Median PFS months | 17.2 (11.8, 22.6) | 13.4 (10.8, 16.0) | P = 0.03
Qui, 2021 ^71^; NCT02337712; LOW | 2-year PFS | 42.3% (31.1, 53.5) | 28.4% (18.2, 38.6) | NR
Qui, 2021 ^71^; NCT02337712; LOW | 3-year PFS | 37.2% (26.0, 48.3) | 19.9% (9.7, 30.1) | NR
Iyengar, 2021 ^74^; NCT01459497; LOW | Rate (95% CI)/time from randomization until progression of disease | 6.4 months; (95% CI [4.1, 7.8]) | 7.3 months; (95% CI [5.0, 10.6]) | P = 0.77
Nyman, 2016 ^72^; NCT01920789; LOW | Kaplan Meier [median rate (95% CI)]/ date of randomization to progression; 1 year | 76% | 87% | HR = 0.85 (95% CI) [0.52, 1.36])
Nyman, 2016 ^72^; NCT01920789; LOW | 2 years | 53% | 54%
Nyman, 2016 ^72^; NCT01920789; LOW | 3 years | 42% | 42%
Roy, 2016 ^73^; CTRI/2013/11/004143; LOW | Kaplan Meier (log-rank test)/period from date of diagnosis to the date of locoregional failure, distant metastasis, or last follow-up | Median PFS: 17 months | Median PFS: 5.4months | P = 0.053
Local Progression-free Survival
Qui, 2021 ^71^; NCT02337712; LOW | Kaplan Meier [median rate (95% CI)]/time from randomization until first confirmation of loco-regional progression | 22/88 | 37/94 | NR
Qui, 2021 ^71^; NCT02337712; LOW | Median LPFS months | NA | 23.9 (17.3, 29.1) | P = 0.017
Qui, 2021 ^71^; NCT02337712; LOW | 2-year LPFS months | 68.5 (56.3, 80.7) | 49.8 (37.1, 62.5) | NR
Qui, 2021 ^71^; NCT02337712; LOW | 3-year LPFS months | 60.8 (47.2, 74.3) | 39.7 (24.6, 54.8) | NR
Distant Metastasis-free Survival
Qui, 2021 ^71^; NCT02337712; LOW | Kaplan Meier [median rate (95% CI)]/time from randomization until first confirmation of distant metastasis | 35/88 | 44/94 | NR
Qui, 2021 ^71^; NCT02337712; LOW | Median DMFS months | 31.2 (NA) | 19.5 (14.9, 24.2) | P = 0.124
Qui, 2021 ^71^; NCT02337712; LOW | 2-year DMFS months | 57.2 (45.4, 69.0) | 43.5 (31.0, 56.0) | NR
Qui, 2021 ^71^; NCT02337712; LOW | 3-year DMFS months | 47.9 (35.0, 60.8) | 35.8 (22.9, 48.7) | NR
Lung-cancer-specific Survival
Ball, 2019 ^10^; NCT01014130; LOW | Kaplan Meier [median rate (95% CI)]/time (years) randomization until death from lung cancer | 7/66 | 10/35 | HR = 0.49 (95% CI [0.21, 1.14]), P = 0.092
Mortality
Qui, 2021 ^71^; NCT02337712; LOW | Total deaths | 32/88 (36.4) | 46/94 (48.9) | NR
Qui, 2021 ^71^; NCT02337712; LOW | Treatment-related deaths | 1/85 (1.2) | 2/92 (2.2) | NR
Ball, 2019 ^10^; NCT01014130; LOW | Total deaths | 26/66 (33) | 22/35 (63) | NR
Ball, 2019 ^10^; NCT01014130; LOW | Death from cancer | 7/66 (10.6) | 10/35 (28.5) | NR
Ball, 2019 ^10^; NCT01014130; LOW | Death from lung cancer and other causes | 4/66 (6) | 0/35 (0) | NR
Ball, 2019 ^10^; NCT01014130; LOW | Death from other causes | 13/66 (19.7) | 11/35 (31) | NR
Ball, 2019 ^10^; NCT01014130; LOW | Death from other malignancy | 2/66 (3) | 1/35 (3) | NR
Ball, 2019 ^10^; NCT01014130; LOW | Death from unknown cause | 1/66 (1.5) | 0/35 (0) | NR
Iyengar, 2021 ^74^; NCT01459497; LOW | Median follow-up was 8.7 (3.6–19.9) months.; Total treatment period deaths | 5/50 (10) | NR | NR
Iyengar, 2021 ^74^; NCT01459497; LOW | 24-month exploratory analysis NSCLC deaths | 11/38 (28.9) | 19/39 (48.7) | P = .10
Nyman, 2016 ^72^; NCT01920789; LOW | Total deaths during follow-up | 18/49 (37) | 21/53 (39.6) | NR
Nyman, 2016 ^72^; NCT01920789; LOW | Death from lung cancer | 5/49 (10) | 8/53 (15) | NR
Roy, 2016 ^73^; CTRI/2013/11/004143; LOW | Median follow-up 15 months Death due to toxicity | 1/18 (5.5) | 1/18 (5.5) | NR

Appendix Table 14 Detailed Results for Toxicity Outcomes for Lung Cancer Trials Rated “Low” or “Some Concerns” Risk of Bias

Trial Name, Year Trial # Risk of Bias | Effect Measure/Definition | Hypofractionation N Events/Total N, (%) | Comparison N Events/Total N, (%) | Results
Acute Cough
Qui, 2021 ^71^; NCT02337712; LOW | ≥ Grade 3 (first 90 days post treatment)/CTCAE | 0/85 (0) | 0/92 (0) | NR
Late Cough
Qui, 2021 ^71^; NCT02337712; LOW | ≥ Grade 3 (greater than 90 days post treatment)/CTCAE | 0/85 (0) | 0/92 (0) | NR
Acute and Late Cough
Ball, 2019 ^10^; NCT01014130; LOW | ≥ Grade 3 (worst toxicity per patient per toxicity type)/CTCAE | 2/66 (3.0) | 0/35 (0) | NR
Iyengar, 2021 ^74^; NCT01459497; LOW | ≥ Grade 2/CTCAE | 1/50 (2.0) | 3/46 (6.5) | NR
Nyman, 2016 ^72^; NCT01920789; LOW | ≥ Grade 2 (maximal toxicity)/CTCAE 3.0 | 6/48 (12.5) | 3/53 (5.7) | P = 0.22
Acute Pneumonitis
Qui, 2021 ^71^; NCT02337712; LOW | ≥ Grade 3 (first 90 days post treatment)/CTCAE | 2/85 (2.4) | 3/92 (3.3) | NR
Roy, 2016 ^73^; CTRI/2013/11/004143; LOW | ≥ Grade 3)/CTCAE | 0/18 (0) | 1/18 (5.5) | P = 0.99
Late Pneumonitis
Qui, 2021 ^71^; NCT02337712; LOW | ≥ Grade 3 (greater than 90 days post treatment)/CTCAE | 0/85 (0) | 0/92 (0) | NR
Acute and Late Pneumonitis
Ball, 2019 ^10^; NCT01014130; LOW | ≥ Grade 3) (worst toxicity/patient/toxicity type)/CTCAE | 0/66 (0) | 0/35 (0) | NR
Iyengar, 2021 ^74^; NCT01459497; LOW | ≥ Grade 2/CTCAE | 4/50 (8.0) | 3/46 (6.5) | NR
Nyman, 2016 ^72^; NCT01920789; LOW | CTCAE 3.0 (maximal toxicity) | 2/48 (4.2) | 5/53 (9.4) | P = 0.085
Acute Esophagitis
Qui, 2021 ^71^; NCT02337712; LOW | ≥ Grade 3 (first 90 days post treatment)/ CTCAE | 13/85 (15.3) | 16/92 (17.4) | NR
Acute Pharyngitis/Esophagitis
Roy, 2016 ^73^; CTRI/2013/11/004143; LOW | ≥ Grade 3/ CTCAE | 1/18 (5.5) | 3/18 (16.7) | P = 0.05
Acute and Late Esophagitis
Iyengar, 2021 ^74^; NCT01459497; LOW | ≥ Grade 2/ CTCAE | 12/50 (24.0) | 5/46 (10.9) | NR
Nyman, 2016 ^72^; NCT01920789; LOW | CTCAE 3.0 (maximal toxicity) | 0/48 (0) | 1/53 (1.9) | P = 0.006
Ball, 2019 ^10^; NCT01014130; LOW | ≥ Grade 3 (worst toxicity/patient/toxicity type)/CTCAE | 0/66 (0) | 0/35 (0) | NR
All Adverse Events
Iyengar, 2021 ^74^; NCT01459497; LOW | Rate/CTCAE (≥ grade 2) | 65/50 (130.0) | 36/46 (78.3) | NR

Abbreviations. CTCAE=Common Terminology Criteria for Adverse Events (version 4.0); EORTC=European Organization for Research and Treatment for Cancer; CFRT=Conventionally Fractionated Radiotherapy.

Appendix Table 15 Detailed Results for Global Quality of Life for Lung Cancer Studies Rated “Low” or “Some Concerns” Risk of Bias

Trial Name, Year Trial # Risk of Bias | Effect Measure/Definition | Hypofractionation N events/Total N | Standard Care N Events/Total N | Results
Ball, 2019 ^10^; NCT01014130; LOW | EORTC QLQ-C30; Mean AUC (95% CI) for the difference in quality of life between arms/Global Health Status | NR | NR | AUC for the difference in quality of life between arms; Overall AUC (95% CI): 5.19 (−3.9, 14); 3 months AUC (95% CI): −1.0 (−12.9, 10.2); 6 months AUC (95% CI): 5.0 (−6.37, 16.8)
Roy, 2016 ^73^; CTRI/2013/11/004143; LOW | Global Health Status median (range): European Organisation for Research and Treatment of Cancer QOL questionnaire C30 and LC13/ 2-sample Wilcoxon rank-sum test was used to compare the QOL parameters among the 2 arms | Pre; 50 (8.3, 66.7) | Pre; 41.7 (0–58.3) | P = 0.24
Roy, 2016 ^73^; CTRI/2013/11/004143; LOW | | Post; 66.7 (41.7, 100) | Post; 58.3 (8.3, 100) | P = 0.44

Abbreviations. QLQ=Quality of Life Questionnaire; HRQL=health related quality of life.