# APPENDIX E PROSTATE CANCER TABLES

Appendix Table 6 Risk of Bias Ratings for All Eligible Prostate Cancer Trials

Trial | Outcome | Domain 1: Risk of Bias Arising from the Randomization Process | Domain 2a: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Assignment to Intervention) | Domain 2b: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Adherence to Intervention) | Domain 3: Risk of Bias Due to Missing Outcome Data | Domain 4: Risk of Bias in Measurement of the Outcome | Domain 5: Risk of Bias in Selection of the Reported Result | Overall Risk of Bias
Alexidis^123,124^ | Harms | Low | Low | High | Low | Low | Some concerns^123^; Low^124^ | High
Alexidis^123,124^ | QoL | Low | Low | High | Low | Some concerns^123^; Low^124^ | Some concerns | High
Arcangelli | Harms^49,60,65^ | Low | Low | Some concerns | Low | Low | Low | Some concerns
Arcangelli | Survival^49,60,61^ | Low | Low | Some concerns | Low | Low | Low | Some concerns
Catton^43^ | Harms | Low | Low | Low | Low | Low | Low | Low
CHHiP | Harms^40,70,125^ | Low | Low | Some concerns | Low | Low | Low | Some concerns
CHHiP | Survival^40^ | Low | Low | Some concerns | Low | Low | Low | Some concerns
CHHiP | QoL^69^ | Low | Low | Some concerns | Low | Low | Low | Some concerns
CHIRP^55^ | Harms | Low | Low | Some concerns | Low | Low | Low | Some concerns
CHIRP^55^ | Survival | Low | Low | Some concerns | Low | Some concerns | Low | Some concerns
Fonteyne^44^ | Harms | Low | Low | Some concerns | Low | Low | Low | Some concerns
Hoffman | Harms^53,66^ | Low | Low | Low | Low | Low | Low | Low
Hoffman | Survival^53^ | Low | Low | Low | Low | Low | Low | Low
Houshyari^45^ | Harms | Low | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
HYPO-RTPC | Harms^39^ | Some concerns | Some concerns | Low | Low | Low | Low | Some concerns
HYPO-RTPC | Survival^39^ | Some concerns | Some concerns | Low | Some concerns | Low | Low | Some concerns
HYPO-RTPC | QoL^58^ | Some concerns | Some concerns | Low | Some concerns | Some concerns | Low | Some concerns
HYPRO | Harms^64^ | Low | Low | Low | Low | Low | Low | Low
HYPRO | Survival^48,59^ | Low | Low | Low | Low | Low | Low | Low
HYPRO | QoL^126^ | Low | Low | Low | High | Low | Low | High
Lukka 05^54^ | Harms | Low | Low | Low | Low | Low | Low | Low
Lukka 05^54^ | Survival | Low | Low | Low | Low | Low | Low | Low
Marzi^127^ | Harms | Low | High | High | Some concerns | Low | Low | High
Norkus 09 | Harms^51^ | Low | Some concerns | Low | Low | Low | Low | Some concerns
Norkus 13^50,128^ | Harms | Low | Low | Low | Low | Low | Low | Low
PACE-B^47^ | Harms | Low | Low | Some concerns | Low | Low | Low | Some concerns
PACE-B^47^ | QoL | Low | Low | Some concerns | Low | Low | Low | Some concerns
Pollack | Harms^52^ | Low | Low | Low | Low | Low | Low | Low
Pollack | Survival^63^ | Low | Low | Low | Low | Low | Low | Low
Pollack | QoL^68^ | Low | Low | Low | Low | Low | Low | Low
Poon^46^ | Harms | Low | Some concerns | Low | Low | Low | Some concerns | Some concerns
Poon^46^ | Survival | Low | Some concerns | Low | Low | Low | Some concerns | Some concerns
RTOG 0415 | Survival^41^ | Low | Low | Low | Low | Low | Low | Low
RTOG 0415 | QoL^67^ | Low | Low | Low | Low | Low | Low | Low
Yeoh^57,62,129^ | Survival | Low | Some concerns | Low | Low | Low | Low | Some concerns
Zhong^56^ | Harms | Some concerns | Some concerns | Low | Low | Some concerns | Low | Some concerns
Zhong^56^ | Survival | Some concerns | Some concerns | Low | Low | Low | Low | Some concerns

Appendix Table 7 Study Characteristics for All Eligible Prostate Cancer Trials

Trial Name, Year Trial # Risk of Bias Country Funding Follow-up | Inclusion/Exclusion Criteria Other Treatments | Intervention (Hypofractionation) Characteristics | | Comparator (Conventional) Characteristics | Outcomes Reported (Risk of Bias If Different by Outcome); *Primary
Trial Name, Year Trial # Risk of Bias Country Funding Follow-up | Inclusion/Exclusion Criteria Other Treatments | Dose/Fraction; Total Dose; Time; N; Baseline Characteristics (n, %) | | Dose/Fraction; Total Dose; Time; N; Baseline Characteristics (n, %) | Outcomes Reported (Risk of Bias If Different by Outcome); *Primary
Alexidis, 2019 ^123^ ^,^ ^124^; Trial # NR; High; Greece; Funding NR; Follow-up 19 weeks | Patients between 40 and 85 years old with histologically proven localized prostate cancer (cT1c-cT3bN0M0), PSA ≤ 40 ng/mL and WHO performance status of 0–2. Patients were excluded if they had received past pelvic irradiation, any type of prostatectomy (suprapubic or transurethral), suffered from inflammatory bowel disease, a history of bladder cancer or transurethral resection of bladder tumor or impaired urinary function; a calculated risk of lymph node involvement ≥ 5%, T3 disease and GS ≥ 8, T3 disease and PSA > 10 ng/ml, GS 8–9 and stage T3 or T4 or PSA > 10 ng/ml.; Other treatments: ADT was given 2 months prior | 2.25 Gy/fraction; 72 Gy; 32 fractions; Weeks NR; N=72; Mn age (range): 69.8 (NR); Race: NR; PSA ng/mL:; < 10=45 (62.5); ≥ 10=36 (37.5); Gleason score:; < 6: 31 (43.1); 7: 30 (41.7); 8–9: 11 (15.3); Tumor stage:; T1: 32 (44.4); T2: 34 (47.2); T3: 6 (8.3); Risk Category: NR | | 2 Gy/fraction; 74 Gy; 37 fractions; Weeks NR; N=67; Md age (range): 70.9 (NR); Race: NR; PSA ng/mL:; < 10=39 (58.2); ≥ 10=28 (41.8); Gleason score:; < 6: 29 (43.3); 7: 31 (46.3); 8–9: 7 (10.4); Tumor stage:; T1: 28 (41.8); T2: 36 (53.7); T3: 3 (4.5); Risk Category: NR | Harms*; - GU/GI toxicity; Quality of life
Aluwini, 2015^48,59,64,126,130^ HYPRO; ISRCTN85138529; Low; 7 centers in the Netherlands; The Dutch Cancer Society; Median follow-up 89 months | Intermediate-risk and high-risk patients with prostate cancer between 44–85 years with histologically confirmed stage T1b–T4 NX–0 MX–0, prostate-specific antigen of ≤ 60 ng/mL and a WHO performance status of 0–2. We Patients were excluded if previous pelvis irradiation, radical prostatectomy, evidence of pelvic nodal disease (determined by CT of pelvis), presence of distant metastases (determined by bone scintigraphy), and low-risk patients (stage T1b–T2a, Gleason score ≤ 6, prostate-specific antigen ≤ 10 ng/mL).; Other treatments:; 67% of patients received concomitant ADT for median 32 months | 5.6 Gy/fraction; 3.4 Gy; 19 fractions; 6.5 weeks; N=403; Mn age (range):; 70 (66–74); Race: NR; PSA ng/mL:; ≤ 10: 124 (31); 10–20: 159 (39); > 20: 120 (30); Gleason score:; ≤ 6:122 (30); 7: 181 (45); 8: 60 (15); 9: 7 (9); 10: 3 (1); Tumor stage:; T1a: 0; T1b: 3 (1); T1c: 55 (14); T2a: 50 (12); T2b: 35 (9); T2c: 49 (12); T3a: 157 (39); T3b: 47 (12); T4: 7 (2); Risk category NR | | 2.0 Gy/fraction; 78 Gy; 39 fractions; 8 weeks; N=391; Mn age (range):; 71 (67–75); Race: NR; PSA ng/mL:; ≤ 10: 103 (26); 10–20: 157 (40); > 20: 131 (34); Gleason score:; ≤ 6:119 (31); 7: 178 (46); 8: 57 (15); 9: 33 (8); 10: 4 (1); Tumor stage:; T1a: 1 (0); T1b: 3 (1); T1c: 55 (14); T2a: 45 (12); T2b: 38 (10); T2c: 48 (12); T3a: 160 (41); T3b: 38 (10); T4: 3 (1); Risk category NR | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity*; Survival*; - Overall; - Prostate-specific; Quality of life (high)
Arcangelli, 2010 ^49^ ^,^ ^60^ ^,^ ^61^ ^,^ ^65^; Trial # NR; Some concerns; Italy; Funding NR; Median follow-up 9 years | Inclusion criteria: (1) histological proof of prostate adenocarcinoma of not more than 6 months; (2) high-risk features; (3) total PSA level ≤ 100 ng/mL; (4) no evidence of distant metastases; (5) no contraindications for 9-month total androgen deprivation; (6) no previous pelvic radiotherapy; (7) no previous hormonal therapy; (8) no previous major pelvic surgery; (9) no previous prostate surgery other than transurethral resection of the prostate; (10) no evidence of ulcerative colitis; (11) WHO performance status #2; (12) no pelvic node > 1 cm at the CT or MR evaluation; (13) no previous malignant tumors, with the exception of adequately treated cutaneous carcinomas; (14) no evidence of; infectious or psychotic disease; Other treatments:; All participants received 9-month ADT | 3.1 Gy/fraction; 62 Gy; 20 fractions; 5 weeks; N=83; Md age (range):; 75 (61–82); Race NR; PSA ng/mL:; ≤ 20: 35 (42); > 20: 48 (58); Gleason score:; ≤ 7: 22 (27); > 7: 61 (73); Tumor stage:; < T2c: 54 (65); ≥ T2c: 29 (35); Risk category NR | | 2.0 Gy/fraction; 80 Gy; 40 fractions; 8 weeks; N=85; Md age (range):; 75 (54–83); Race NR; PSA ng/mL:; ≤ 20: 27 (32); > 20: 58 (68); Gleason score:; ≤ 7: 20 (24); > 7: 65 (76); Tumor stage:; < T2c: 48 (56); ≥ T2c: 37 (44); Risk category NR | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity*; Survival; - Biochemical recurrence-free; - Local recurrence; - Metastases; - Overall; - Prostate-specific
Brand, 2019^47^ PACE-B; NCT01584258; Some concerns; 37 centers in the United Kingdom, Ireland and Canada; Accuray and National Institute of Health Research; Median follow-up 12 weeks | Only patients suitable for radical radiotherapy, but not willing to have or not suitable for radical prostatectomy were recruited. Eligible patients were men aged at least 18 years, with WHO performance status of 0–2, life expectancy of at least 5 years, and histologically confirmed prostate adenocarcinoma. All patients had NCCN low-risk or intermediate-risk disease.; Other treatments:; ADT not permitted | 3.1 Gy/fraction; 62 Gy; 20 fractions; 4 weeks; Or; Conventionally fractionated; RT; 2.0 Gy/fraction; 78 Gy; 39 fractions; 7–8 weeks; N=441; Mean age (range): 70 (66–74); Ethnicity:; Black 25 (6); East Asian 3 (1); Mixed heritage 2 (<1); South Asian 9 (2); White 386 (89); Other 7 (2); PSA ng/mL:; < 10: 299 (69); 10–20: 133 (31); Gleason score:; 3+3: 84 (19); 3+4: 348 (81); Tumor stage:; T1c: 78 (18); T2a: 130 (30); T2b: 57 (13); T2c: 167 (39); Risk category (NCCN); Low: 38 (9); Intermediate: 394 (91) | | 2.0 Gy/fraction; 36.25 Gy; 5 fractions; 1–2 weeks; N=433; Mean age (range): 70 (65–74); Ethnicity:; Black 25 (6); East Asian 3 (1); Mixed heritage 2 (<1); South Asian 9 (2); White 386 (89); Other 7 (2); PSA ng/mL:; < 10: 283 (68); 10–20: 132 (32); Gleason score:; 3+3: 61 (15); 3+4: 354 (85); Tumor stage:; T1c: 76 (18); T2a: 105 (25); T2b: 81 (20); T2c: 153 (37); Risk category (NCCN); Low: 30 (7); Intermediate: 385 (93) | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity; Quality of life
Catton, 2017 ^43^; NCT00304759; Low; 27 Centers: Canada (14), Australia (12), France (1); Canadian Institutes for Health Research; Median follow-up 6 years | Eligible patients had a histologic diagnosis of intermediate risk carcinoma of the prostate (T1-2a, Gleason score ≤ 6, and PSA=10.1-20 ng/mL; T2b-2c, Gleason ≤ 6, and PSA ≤ 20 ng/mL; or T1-2, Gleason = 7, and PSA ≤ 20 ng/mL) without evidence of disease spread to the lymph nodes or bone. Exclusion criteria were prostate cancer diagnosis > 6 months before study entry, previous therapy for prostate cancer other than biopsy or transurethral resection, > 12 weeks of hormone therapy for treatment of prostate cancer, any malignancy diagnosed within 5 years of entry except for nonmelanoma skin cancer, radiation treatment plan that did not meet dose constraints for the hypofractionation arm of the trial, and previous pelvic RT or inflammatory bowel disease. | 3 Gy/fraction; 60 Gy; 20 fractions; 4 weeks; N=608; Md age (range): 72 (68–75); Race: NR; PSA ng/mL:; < 10=405 (67); ≥ 10=203 (33); Gleason score:; 3+3: 57 (9); 3+4: 382 (63); 4+3: 169 (28); Tumor stage:; T1a, T1b: 4 (<1); T1c: 328 (54); T2a: 163 (27); T2b: 73 (12); T2c: 40 (7); Other treatments: Androgen deprivation therapy was not permitted.; Risk category: NR | | 2 Gy/fraction; 78 Gy; 39 fractions; 8 weeks; N=598; Md age (range): 71 (67–75); Race: NR; PSA ng/mL:; < 10=419 (49); ≥ 10=179 (30); Gleason score:; 3+3: 56 (9); 3+4: 380 (64); 4+3: 162 (27); Tumor stage:; T1a, T1b: 3 (<1); T1c: 308 (52); T2a: 159 (27); T2b: 91 (15); T2c: 37 (6); Other treatments: Androgen deprivation therapy was not permitted.; Risk category: NR | Harms; - GU/GI toxicity
Dearnaley, 2012^40,69,70,125^ CHHiP; SRCTN97182923; Some concerns; 71 centers in the UK, Ireland, Switzerland and New Zealand; Cancer Research UK, Department of Health, National Institute for Health Research Cancer Research Network, and NHS funding to the National Institute of Health Research Biomedical Research Centre at the Royal Marsden NHS Foundation Trust and The Institute of Cancer Research, London.; Median follow-up 62.4 months | Men older than 16 years who had histologically confirmed T1b–T3aN0M0 prostate cancer and a WHO performance status of 0 or 1, were eligible. A PSA concentration less than 30 ng/mL and a risk of seminal vesicle involvement less than 30% were needed. Patients were ineligible if they had both T3 tumors and a Gleason score of 8 or higher, or a life expectancy of less than 10 years. Other exclusion criteria included previous pelvic radiotherapy or radical prostatectomy, previous androgen suppression, another active malignancy in the past 5 years (other than cutaneous basal-cell carcinoma), comorbid conditions precluding radical radiotherapy, hip prosthesis, and full anticoagulation treatment.; Other treatments: Men with NCCN intermediate-risk or high-risk disease received short-course androgen suppression for 3–6 months before and during RT; this was optional for patients with low-risk disease. | 3 Gy/fraction; 60 Gy; 20 fractions; 4 weeks; N=1074; Mean age (range):; 69 (48–84); Race NR; PSA ng/mL:; < 10: 518 (48); ≤ 10: 551 (52); Gleason score:; ≤ 6: 387 (36); 7: 658 (61); 8: 29 (3); Tumor stage:; T1a-b-c-x: 422 (39); T2a-b-c-x: 561 (52); T3a-T3x: 90 (8); Unknown: 1 (<1); Risk category (NCCN); Low: 164 (15); Intermediate: 784 (73); High: 126 (12) | 3 Gy/fraction; 57 Gy; 19 fract; 3.8 weeks; N=1077; Mean age (range):; 69 (44–83); Race NR; PSA ng/mL:; < 10: 539 (50); ≥ 10: 528 (50); Gleason score:; ≤ 6: 364 (34); 7: 681 (63); 8: 32 (3); Tumor stage:; T1a-b-c-x: 392 (36); T2a-b-c-x: 582 (54); T3a-T3x: 102 (9); Unknown: 1 (<1); Risk category (NCCN); Low: 163 (15); Intermediate: 784 (73); High: 130 (12) | 2 Gy/fraction; 74 Gy; 37 fractions; 7.4 weeks; N=1065; Mean age (range):; 69 (48–85); Race NR; PSA ng/mL:; < 10: 510 (48); ≥ 10: 544 (52); Gleason score:; ≤ 6: 371 (35); 7: 656 (62); 8: 38 (4); Tumor stage:; T1a-b-c-x: 356 (33); T2a-b-c-x: 623 (58); T3a-x: 85 (8); Unknown: 1 (<1); Risk category (NCCN); Low: 157 (15); Intermediate: 779 (73); High: 129 (12) | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity; Survival; - Overall
Fonteyne, 2018 ^44^; Trial #NCT01921803; Some concerns; Belgium; Stichting tegen kanker (non-profit); Follow-up 3 months | Patients with histologically confirmed stage T1-T4N0M0 prostate cancer and WHO performance status of 0 t | 3.5 Gy/fraction; 56 Gy; 16 fractions; Weeks NR; N=77; Baseline characteristics NR | | 2.68 Gy/fraction; 67 Gy; 25 fractions; Weeks NR; N=80; Baseline characteristics NR | Harms*; - GU/GI toxicity
Hoffman, 2014 ^53^ ^,^ ^66^; NCT00667888; Low; United States; Funding NR; Median follow-up 8.5 years | Eligible patients had biopsy-proven prostate adenocarcinoma, good performance status (Zubrod <2), clinical sIe (c) T1b-T3b disease (1992 AJCC staging system), PSA ≤ 20 ng/mL, Gleason score < 10, and no clinical, radiographic, or pathologic evidence of nodal or bone metastasis.; Other treatments: ADT similar across groups | 2.4 Gy/fraction; 72 Gy; 30 fractions; 6 weeks; N=101; Median age (range):; 69 (41–83); Race: NR; PSA ng/mL:; < 10: 93 (91); ≥ 10: 9 (9); Gleason score:; 6: 33 (32); 7: 68 (67); 8: 1 (1); Tumor stage:; T1: 70 (69); T2: 32 (31); Risk category (NCCN); Low: 28 (27); Intermediate: 73 (72); High: 1 (1) | | 1.8 Gy/fraction; 75.6 Gy; 42 fractions; 8.4 weeks; N=102; Median age (range):; 67 (48–84); Race: NR; PSA ng/mL:; < 10: 88 (87); ≥ 10: 13 (13); Gleason score: 6: 37 (37); 7: 63 (62); 8: 1 (1); Tumor stage:; T1: 76 (75); T2: 25 (25); Risk category (NCCN); Low: 29 (29); Intermediate: 71 (70); High: 1 (1) | Harms; - Late GU/GI toxicity*; Survival; - Overall; - Prostate-specific
Houshyari, 2021 ^45^; Trial # NR; Some concerns; Iran; Funding NR; Follow-up 3 months | Eligible patients had histologically confirmed stage T1-T3aN0M0 PCa (according to the 7th edition of AJCC), PSA ≤ 40 and ECOG performance status of 0–2. Exclusion criteria included lymph node involvement, distant metastasis, co-existing malignancy (except for basal cell skin cancer), and previous RT to the pelvis.; Other treatments:; Patients with intermediate and high-risk disease received ADT for 3 months before and during RT, and continued up to 6 and 36 months, respectivetly. | 3.5 Gy/fraction; 56 Gy; 16 fractions; 4 weeks; N=20; Median age (SD):; 72 (6.0); Range 56–80; Race: NR; PSA ng/mL:; < 10: 11 (55); ≥ 10: 9 (45); Gleason score:; ≤ 6: 4 (20) 7: 10 (50); ≥ 8: 6 (30); Tumor stage:; T1-T2a: 7 (35); T2b-T2c: 8 (40); T3: 5 (25); Risk category (D’Amico):; Low: 2 (10); Int. 13 (65); High: 5 (25) | | 2.7 Gy/fraction; 70.2 Gy; 26 fractions; 5 weeks; N=20; Median age (SD):; 68.5 (8.9); Range 55–86; Race: NR; PSA ng/mL:; < 10: 5 (25); ≥ 10: 15 (75); Gleason score:; ≤ 6: 5 (25) 7: 7 (35); ≥ 8: 8 (40); Tumor stage:; T1-T2a: 4 (20); T2b-T2c: 7 (35) T3: 9 (45); Risk category (D’Amico):; Low: 1 (5); Int. 11 (55); High: 8 (40) | Harms*; - Acute GU/GI toxicity
Lee, 2016^41,67^ RTOG-0415; Trial# NR; Low; United States; National Cancer Institute; Median follow-up 5.8 years | Men age ≥ 18 years with prostate adenocarcinoma were eligible if they met the following criteria: a clinical classification of T1b to T2c (according to AJCC staging system, 6^th^ edition), a Gleason score of 2 to 6, and PSA < 10. Additional criteria were no nodal or distant metastatic disease, Zubrod performance status < 2, and no prior bilateral orchiectomy, chemotherapy, RT, cryosurgery, or definitive surgery for prostate cancer. Patients with another invasive cancer, other than localized basal or squamous cell skin carcinoma, were not eligible unless continually free of that cancer for a minimum of 5 years.; Other treatments:; NR | 2.5 Gy/fraction 70 Gy; 28 fractions; 5.6 weeks; N=550; Age:; ≤ 59: 95 (17.3); 60–69: 251 (45.6); ≥ 70: 204 (37.1); Race:; American Indian/AK Native: 1 (0.2); Asian: 8 (1.5); Black: 99 (18); Native Hawaiian or other Pacific Islander: 1 (0.2); White: 436 (79.3); NR: 5 (0.9); PSA ng/mL:; < 4: 112 (20.4); 4 to < 10: 43.8 (79.6); Gleason score:; 2–4: 0; 5–6: 550 (100); Tumor stage:; T1: 442 (80.4); T2: 408 (19.6); Risk category NR | | 1.8 Gy/fraction 73.8 Gy; 41 fractions; 8.2 weeks; N=542; Age:; ≤ 59: 87 (16.1); 60–69: 239 (44.1); ≥ 70: 216 (39.9); Race:; American Indian/AK Native: 5 (0.9); Asian: 7 (1.3); Black: 91 (16.8); Native Hawaiian or other Pacific Islander: 1 (0.2); White: 430 (79.3) NR: 8 (1.5); PSA ng/mL:; < 4: 106 (93.5); 4 to <10: 436 (80.4); Gleason score:; 2–4: 2 (0.4); 5–6: 540 (99.6); Tumor stage:; T1: 411 (75.8); T2: 131 (24.2); Risk category NR | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity; Survival; - Overall; Quality of life
Lukka, 2005 ^54^; Trial # NR; Low; Canada; Funding NR; Median follow-up 5.7 years | Men with early-stage adenocarcinoma of the prostate (T1-2 according to International Union Against Cancer TNM classification) were eligible for the trial. Patient exclusion criteria were as follows: PSA > 40 ng/L; previous therapy for PCa (other than biopsy or transurethral resection of the prostate); previous hormone therapy; prior or active malignancy other than nonmelanoma skin cancer, colon cancer, or thyroid cancer treated a minimum of 5 years before the trial and presumed cured; a simulated volume exceeding 1,000 mL; previous pelvic radiotherapy; presence of inflammatory bowel disease; diagnosis of serious nonmalignant disease that would preclude radiotherapy or surgical biopsy; geographically inaccessible for follow-up; a psychiatric or addictive disorder that would preclude obtaining informed consent or adherence to protocol; inability to commence radiotherapy within 26 weeks of the date of last prostatic biopsy.; Other treatments: NR | 2.63 Gy/fraction; 52.5 Gy; 20 fractions; 28 days; N=466; Mean age (range):; 70 (53–84); Race: NR; PSA ng/mL:; Mean (range): 10.6 (0.3–39); Gleason score:; 2–4: 35 (8); 5: 67 (14); 6: 181 (39); 7: 134 (29); 8–9: 49 (11); Tumor stage:; T1a: 0; T1b: 9 (2); T1c: 114 (25); T2a: 135 (29); T2b: 130 (28); T2c: 78 (17); Risk category NR | | 2.0 Gy/fraction; 66 Gy; 33 fractions; 45 days; N=470; Mean age (range):; 70.3 (53–84) Race: NR; PSA ng/mL:; Mean (range): 10.4 (0.4–40); Gleason score:; 2–4: 35 (8); 5: 67 (14); 6: 181 (39); 7: 134 (29); 8–9: 49 (11); Tumor stage; T1a: 3 (1); T1b: 13 (3); T1c: 116 (25); T2a: 122 (26); T2b: 123 (26); T2c: 93 (20); Risk category NR | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity*; Survival; - Biochemical recurrence-free; - Local recurrence; - Metastases; - Overall; - Prostate-specific
Marzi, 2009 ^127^; Trial # NR; High; Italy; Funding NR; Median follow-up 30 months | Eligible participants were < 85 with at least two of the following risk factors present: T2c-T4, PSA > 10 ng/ml, Gleason score 7–10. Other eligibility criteria were no nodes involvement present at CT or MRI, no other previous RT or prostatectomy, no other malignant disease except for Basal cell carcinoma or other tumors in the past 5 years. | 3.1 Gy/fraction; 62 Gy; 20 fractions; 5 weeks; N=57; Age:; ≤ 75: 31; > 75: 26; Race: NR; PSA ng/mL:; ≤ 10:18 (32); > 10:39 (68); Gleason score:; ≤ 6: 9 (16); > 6: 48 (84); Tumor stage:; < T2c: 27 (47); ≥ T2c: 30 (53); Other treatments:; Hormonal treatment was given 2 months prior; Risk category:; NR | | 2 Gy/fraction; 80 Gy; 40 fractions; 8 weeks; N=57; Age:; ≤ 75: 29; > 75: 28; Race: NR; PSA ng/mL:; ≤ 10: 14 (25); > 10: 43 (75); Gleason score:; ≤ 6: 5 (9); > 6: 52 (91); Tumor stage:; < T2c: 26 (46); ≥ T2c: 31 (54); Other treatments:; Hormonal treatment was given 2 months prior; Risk category:; NR | Harms*; - Late rectal toxicity
Norkus, 2009 ^51^ ^,^ ^131^; Trial # NR; Some concerns; Lithuania; Funding NR; Follow-up 12 months | Inclusion criteria were as follows: prostate adenocarcinoma of low- and intermediate-risk group, with risk of seminal vesicle and/or pelvic lymph node involvement of < 15% regarding Partin’s nomograms and Roach formula, no hormonal therapy or surgical castration before radiotherapy; Other treatments:; NR | 57 Gy; 17 frons; 3.5 weeks; Given as 13 fractions of 3 Gy plus 4 fractions of 4.5 Gy; N=47; Median age (range): 63 (53–75); Race: NR; PSA ng/mL:; ≥ 10: 47; > 10: 0; Gleason score:; ≤ 6: 42; 7: 2; ≥ 8: 0; Tumor stage:; T1: 20; T2: 26; T3: 1; Risk category NR | | 2 Gy/fraction; 74 Gy; 37 fractions; 7.5 weeks; N=44; Median age (range): 65 (50–78); Race: NR; PSA ng/mL:; ≥ 10: 44; > 10: 0; Gleason score:; ≤ 6: 44; 7: 0; ≥ 8: 0; Tumor stage:; T1: 16; T2: 26; T3: 2; Risk category NR | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity*
Norkus, 2013 ^50^ ^,^ ^128^; Trial # NR; Low; Lithuania; Funding NR; Follow-up 12 weeks | The inclusion criteria were as follows: histologically proven prostate adenocarcinoma; PSA ≤ 100 ng/ml; ECOG performance status < 2; no evidence of distant metastases; no other malignancy except basal cell skin cancer; no contraindications for ADT; no previous prostate surgery including transurethral resection; and most importantly, high risk features according to NCCN criteria: stage T3a-T3b, biopsy Gleason score of 8–10; pretreatment PSA level > 20 ng/mL, or the presence of at least 2 of the following clinical characteristics: pretreatment PSA of 11–20 ng/ mL, T ≥ 2c, GS = 7. Exclusion criteria included lymph node involvement and previous RT to the pelvis.; Other treatments:; All patients received ADT ~3–4 month prior to RT and continued for a total duration of ≥ 6 months. | 3.15 Gy/fraction; 63 Gy; 20 fractions; 4–5 weeks (4 fractions/week); N=115; Mean age (SD):; 65 (6); Race: NR; PSA ng/mL:; ≤ 20: 92 (80); > 20: 23 (20); Gleason score:; ≤ 7: 107 (93); > 7: 8 (7); Tumor stage:; ≤ T2c: 17 (15); > T2c: 98 (85); Risk category NR | | 2.0 Gy/fraction; 76 Gy; 38 fractions; Weeks NR (5 fractions/week); N=106; Mean age (SD):; 65 (7); Race: NR; PSA ng/mL:; ≤ 20: 76 (72); > 20: 30 (28); Gleason score:; ≤ 7: 90 (85); > 7: 16 (15); Tumor stage:; ≤ T2c: 20 (19); > T2c: 86 (81); Risk category NR | Harms*; - Acute GU/GI toxicity
Pollack, 2006 ^52^ ^,^ ^63^ ^,^ ^68^ ^,^ ^132^; NCT00062309; Low; United States; National Cancer Institute & Florida Biomed Bankhead Coley; Median follow-up 122.9 months | Men with stage T1-3 adenocarcinoma of the prostate and Gleason score ≥ 5 were eligible if they had intermediate to high-risk features. Intermediate risk was defined as Gleason score 7, pretreatment initial PSA > 10.20 ng/mL, or ≥ 3 biopsy cores of Gleason score ≥ 5, as long as no high-risk features were present. High risk was defined as Gleason score 8–10, Gleason score 7 in ≥ 4 cores, cT3 disease, or an initial PSA > 20 ng/mL; Other treatments: Long-term ADT planned for 24 months in those with high risk; for those with less than high risk, ADT planned for up to 4 months | 2.7 Gy/fraction; 70.2 Gy; 26 fractions; Weeks NR; N=151; Mean age (SD):; 66.7 (7.6); Race: NR; PSA ng/mL:; < 10: 95 (62.9); ≤ 10–20: 41 (27.2); > 20: 15 (9.9); Gleason score:; 6: 53 (35.1); 7: 70 (46.4); 8–10: 28 (18.5); Tumor stage:; T1: 61 (40.4); T2: 71 (47.0); T3: 19 (12.6); Risk category NR | | 2.0 Gy/fraction; 76 Gy; 38 fractions; Weeks NR; N=152; Mean age (SD):; 66.9 (8.4); Race: NR; PSA ng/mL:; < 10: 99 (65.1); ≤ 10–20: 40 (26.3); > 20: 13 (8.6); Gleason score:; 6: 51 (38.8); 7: 72 (47.4); 8–10: 29 (19.1); Tumor stage:; T1: 59 (383.8); T2: 77 (50.7); T3: 16 (10.5); Risk category NR | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity; Survival; - Biochemical recurrence-free; - Local recurrence; - Metastases; - Prostate-specific
Poon, 2022 ^46^; NCT02339701; Some concerns; China; “This study did not receive any specific grants from funding agencies in the public, commercial, or not-for-profit sectors.”; Median follow-up 2.3 years | Men aged ≥ 18 years with a histologic diagnosis of prostate adenocarcinoma and NCCN low- or intermediate-risk (T1-2, Gleason score ≤ 7 and PSA < 20 ng/mL) localized disease were eligible. Additional criteria were Zubrod performance status < 2, no nodal or distant metastasis, and no prior bilateral orchiectomy, chemotherapy, RT, cryosurgery, or definitive surgery for PCa. Patients with another invasive cancer, other than localized basal or squamous cell skin carcinoma, were ineligible.; Other treatments:; Neoadjuvant ADT was given in 10 patients (SBRT: 4; CFRT: 6). Total of 6 months of ADT prescribed 3 months prior to RT. | SBRT; 7.25 Gy/fraction; 36.25 Gy; 5 fractions; 2 weeks; N=31; Median age (range):; 68 (53–78); Race NR; PSA ng/mL:; Mean (SD): 9.2 (5.0); Gleason score:; 5: 3 (9); 6: 16 (51); 7: 12 (38); Tumor stage:; T1a: 1 (3); T1c: 16 (51); T2a: 7 (22); T2b: 5 (16); T2c: 2 (6); Risk category (NCCN); Low: 16 (51); Intermediate: 15 (48) | | CFRT; 2.0 Gy/fraction; 76 Gy; 38 fractions; 7.5 weeks; N=33; Median age (range):; 70 (55–81); Race NR; PSA ng/mL:; Mean (SD): 8.6 (5.4); Gleason score:; 5: 0; 6: 22 (66); 7: 11 (33); Tumor stage:; T1a: 0; T1c: 15 (45); T2a: 10 (30); T2b: 3 (9); T2c: 5 (15); Risk category (NCCN); Low: 16 (48); Intermediate: 17 (51) | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity; Survival; - Overall
Wang, 2021^55^ CHIRP; NCT01488968; Some concerns; Canada; Alberta Cancer Foundations, Alberta Innovates-Health Solutions; Median follow-up 38 months | Patients were eligible if they had newly diagnosed, histologically proven PCa, classified as high-risk disease (1 or more of: clinical stage ≥T3, Gleason ≥ 8, or PSA ≥ 20 ng/mL). Patients were excluded if they had any of the following: clinical or radiologic evidence of distant metastasis, previous prostatectomy or more than 1 transurethral resection of prostate, previous pelvic radiation therapy (RT), history of inflammatory bowel disease, anal stenosis, colorectal surgery, repeated endoscopic examinations, interventions related to anorectal diseases, hip prostheses, or ≥ 4 month history of AST.; Other treatments:; AST was offered for 18 months | 2.72 Gy/fraction; 68 Gy; 25 fractions; Weeks NR; N=55; Md age (range):; 67 (49–79); Race: NR; PSA ng/mL:; < 10: 12 (22); ≥ 10: 42 (78); Gleason score:; 6: 2 (4); 7: 26 (48); 8: 15 (28); 9: 11 (20); Tumor stage:; Tx: 0; T1: 5 (9); T2: 24 (44); T3: 23 (43); T4: 2 (4); Risk category (IPSS):; Mild (0–7): 16 (30); Moderate (8–19): 24 (44); Severe (20–35):12 (22); Not done: 2 (4) | | 2.0 Gy/fraction; 78 Gy; 39 fractions; Weeks NR; N=56; Md age (range):; 70 (49–80); Race: NR; PSA ng/mL:; < 10: 13 (24); ≥ 10: 42 (76); Gleason score:; 6: 2 (4); 7: 15 (27); 8: 19 (35); 9: 19 (35); Tumor stage:; Tx: 1 (2); T1: 6 (11); T2: 29; (53) T3: 19 (35); T4: 0; Risk category (IPSS):; Mild (0–7): 21 (38); Moderate (8–19): 20 (36); Severe (20–35):9 (16); Not done: 5 (9) | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity*; Survival; - Biochemical recurrence-free; - Overall; - Prostate-specific
Widmark, 2019 ^39^ ^,^ ^58^; HYPO-RT-PC; ISRCTN45905321; Some concerns; 12 centers in Sweden and Denmark; The Nordic Cancer Union, Swedish Cancer Society and the Swedish Research Council; Median follow-up 5 years | Participants were men up to 75 years of age with histologically verified intermediate-to-high-risk prostate cancer and WHO performance status between 0 and 2. Intermediate-to-high-risk prostate cancer was categorized according to the TNM classification system as T1c−T3a with no evidence of lymph node involvement or distant metastases with one or two of the following risk factors: stage T3a, Gleason score of at least 7, or PSA of at least 10 ng/mL. The maximum PSA allowed was 20 ng/mL and no ADT was permitted. | 6.1 Gy/fraction; 42.7 Gy; 7 fractions; 2.5 weeks; N=589 (598 randomized); Mean age (range): 68 (64–72); Race: NR; PSA ng/mL:; ≤ 10: 357 (61); > 10: 232 (39); Gleason score:; 5: 5 (1); 6: 99 (17); 7: 447 (76); 8: 33 (6); 9: 5 (1); Tumor stage:; T1c: 313 (53); T2: 252 (43); T3a: 24 (4); Risk category NR | | 2.0 Gy/fraction; 78 Gy; 39 fractions; 8 weeks; N=591 (602 randomized); Mean age (range): 69 (65–72); Race: NR; PSA ng/mL:; ≤ 10: 356 (60); > 10: 235 (40); Gleason score:; 5: 2 (< 1); 6: 106 (18) 7: 444 (75); 8: 37 (6); 9: 2 (< 1); Tumor stage:; T1c: 289 (49); T2: 275 (47); T3a: 27 (5); Risk category NR | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity; Survival; - Overall; - Prostate-specific
Yeoh, 2006 ^57^ ^,^ ^62^ ^,^ ^129^; Trial # NR; Some concerns; Australia; Funding NR; Median follow-up 90 months | Inclusion criteria NR; Other treatments:; Androgen deprivation therapy, which was not standard practice for T2b disease at the time, was one of the exclusion criteria for the study | 2.75 Gy/fraction; 55 Gy; 20 fractions; 4 weeks; N=108; Median age (range) for entire study:; 69 (44–82); Race: NR; PSA ng/mL:; NR; Gleason score:; NR; Tumor stage:; NR; Risk category; NR | | 2 Gy/fraction; 64 Gy; 32 fractions; 6.5 weeks; N=109; Median age (range) for entire study:; 69 (44–82); Race: NR; PSA ng/mL:; NR; Gleason score:; NR; Tumor stage:; NR; Risk category; NR | Survival; - Biochemical recurrence free; - Overall; - Prostate-specific
Zhong, 2021 ^56^; NCT02934685; Some concerns; China; National Natural Science Foundation of China & VARIAN Research Foundation; Median follow-up 26 months | Male patients were eligible if 1) they were aged ≥ 50 years, 2) had histologically confirmed prostate adenocarcinoma, 3) had good performance status (ECOG score 0–1), and 4) had clinical stage T1-3 disease by the 2009 AJCC criteria. Exclusion criteria were 1) clinical stage T4, 2) evidence of nodal or distant metastases, 3) previous pelvic radiation therapy, or 4) previous malignancies.; Other treatments:; Per NCCN guidelines, intermediate-risk and high-risk patients received, respectively, 4–6 months and 24 months of neoadjuvant/concurrent androgen deprivation therapy. | 2.5 Gy/fraction; 70 Gy; 28 fractions; 5.6 weeks; N=46; Age (range):; (54–84); ≤ 70: 4 (8.7); > 70: 42 (91.3); Race: NR; PSA ng/mL:; < 10: 12 (26.1); ≥ 10: 34 (73.9); Gleason score:; ≤ 6: 17 (37.0); 7: 19 (41.3); ≥ 8: 10 (21.7); Tumor stage:; T1: 7 (15.2); T2: 25 (54.3); T3: 14 (30.4); Risk category (NCCN):; Low: 16 (34.8); Int. 19 (41.3); High: 11 (23.9) | | 2 Gy/fraction; 80 Gy; 40 fractions; 8 weeks; N=46; Age (range):; (61–86); ≤ 70: 9 (19.6); > 70: 37 (80.4); Race: NR; PSA ng/mL:; < 10: 14 (30.4); ≥ 10: 32 (69.6); Gleason score:; ≤ 6: 16 (34.8); 7: 16 (34.8); ≥ 8: 14 (30.4); Tumor stage:; T1: 8 (17.4); T2: 26 (56.5); T3: 12 (26.1); Risk category (NCCN):; Low: 15 (32.6); Int. 17 (37.0); High: 14 (30.4) | Harms; - Acute GU/GI toxicity; - Late GU/GI toxicity*; Survival; - Biochemical recurrence free

Abbreviations. ADT=androgen deprivation therapy; AJCC=American Joint Committee on Cancer; AST=androgen suppression treatment; CFRT=conventional fractionated radiotherapy; CHHiP=Conventional or Hypofractionated High Dose Intensity Modulated Radiotherapy in Prostate Cancer trial; CHRIP=Conventional versus Hypofractionated Radiation in High Risk Prostate Patients trial; CT=computed tomography; ECOG=Eastern Cooperative Oncology Group; GI=gastrointestinal; GS=Gleason score; GU=genitourinary; Gy=gray; HYPO-RT-PC=Hypofractionated Radiotherapy for Prostate Cancer trial; HYPRO=Hypofractionated versus Conventionally Fractionated Radiotherapy for Patients with Prostate Cancer trial; IPSS=International Prostate Symptom Score; Md=median; Mn=mean; MR=magnetic resonance; MRI=magnetic resonance imaging; NCCN=National Comprehensive Cancer Network; NHS=National Health Service (UK); ng/mL=nanograms per millimeter; NR=not reported; PACE-B=Prostate Advances in Comparative Evidence trial; PCa=prostate cancer; PSA=prostate-specific antigen; PTV=planning target volume; RT=radiotherapy; SBRT=stereotactic body radiotherapy; SD=standard deviation; UK=United Kingdom; WHO=World Health Organization.

Appendix Table 8 Detailed Results for Survival Outcomes for Prostate Cancer Trials Rated “Low” or “Some Concerns” Risk of Bias

Outcome | Trial Name, Year; Trial #; Risk of Bias | Effect Measure/Definition | Hypofractionation N Events/total N; % | Comparison N Events/Total N; % | Results
Biochemical recurrence-free | Arcangelli, 2010 ^49^; Arcangelli, 2012 ^61^; Arcangelli, 2017 ^60^; Some concerns | 3-year; Time from first day of radiotherapy to biochemical relapse according to the most recent Phoenix definition of nadir PSA +2 ng/mL | 87% | 79% | P = 0.04
Biochemical recurrence-free | Arcangelli, 2010 ^49^; Arcangelli, 2012 ^61^; Arcangelli, 2017 ^60^; Some concerns | 4-year | 82% | 60% | P = 0.004
Biochemical recurrence-free | Arcangelli, 2010 ^49^; Arcangelli, 2012 ^61^; Arcangelli, 2017 ^60^; Some concerns | 5-year | 85% | 79% | P = 0.65
Biochemical recurrence-free | Arcangelli, 2010 ^49^; Arcangelli, 2012 ^61^; Arcangelli, 2017 ^60^; Some concerns | 10-year | 72% | 65% | HR = 1.62 (0.88-2.97); P = 0.15
Biochemical recurrence-free | Avkshtol, 2020 ^63^; NCT00062309; Low | 10-year; Phoenix definition | 74.6%^*^ (66.1 to 83.7) | 78.9%^*^ (71.3 to 87.3) | P = 0.49
Biochemical recurrence-free | Lukka, 2005 ^54^; Low | 5-year; Houston definition | 249/466 (53.4%)^*^ | 271/470 (57.7%)^*^ | NR
Biochemical recurrence-free | Wang, 2021 ^55^; CHIRP; NCT01488968; Some concerns | 3-year; Phoenix criteria | 97.3% (92% to 102.6%) | 91% (81.0% to 100.8%) | P = 0.61
Biochemical recurrence-free | Yeoh, 2011 ^57^; Some concerns | 7.5-year; Phoenix and ASTRO criteria | ASTRO 44%; Phoenix 53% | ASTRO 44%; Phoenix 34% | P = NS; HR = 0.65 (0.42-0.99); P < 0.05
Biochemical recurrence-free | Zhong, 2021 ^56^; NCT02934685; Some concerns | 2-year | 94.6% | 95% | P = 0.70
Local recurrence | Arcangelli, 2010 ^49^; Arcangelli, 2012 ^61^; Some concerns | 3-year | 3/83 (3.6%) | 1/85 (1.2%) | P = 0.06
Local recurrence | Arcangelli, 2010 ^49^; Arcangelli, 2012 ^61^; Some concerns | 5.8 years | 7/83 (8.4%) | 10/85 (11.8%) | NR
Local recurrence | Avkshtol, 2020 ^63^; NCT00062309; Low | 10-year | 4.7% | 4% | P = 0.82
Local recurrence | Lukka, 2005 ^54^; NCT01488968; Low | 5-year; Based on the prostate clinical evaluation at time of digital rectal examination. Signs or symptoms of local recurrence were confirmed through prostate biopsy. | 2/466 (0.4%) | 1/470 (0.2%) | NR
Metastases | Arcangelli, 2010 ^49^; Arcangelli, 2012 ^61^; Some concerns | 3-year | 6/83; 7.2% | 10/85; 11.8% | P = 0.46
Metastases | Arcangelli, 2010 ^49^; Arcangelli, 2012 ^61^; Some concerns | 5-year | 90% | 86% | NS
Metastases | Avkshtol, 2020 ^63^; NCT00062309; Low | 5-year | 7.5% (3.4 to 12.0) | 4.0% (1.3 to 7.3) | ARD = 3.5% (−1.8 to 8.8)
Metastases | Avkshtol, 2020 ^63^; NCT00062309; Low | 10-year | 14.3% (8.5 to 20.5) | 6.4% (2.8 to 10.08) | ARD = 7.8% (0.7 to 15.1); HR = 1.93 (0.93 to 4.0); P = 0.08
Metastases | Lukka, 2005 ^54^; Low | 5-year; Distant disease recurrence of metastases outside the prostate included recurrent tumor found in regional pelvic lymph nodes, bone (abnormal bone x-rays or bone scan), liver (abnormal liver scan, ultrasound, or CT scan), and lung (abnormal chest x-ray consistent with metastases). | 10/466; 2% | 4/470; 1% | NR
Overall survival | Arcangelli, 2012 ^61^; Arcangelli, 2017 ^60^; Some concerns | 5-year | 92% | 82% | NS
Overall survival | Arcangelli, 2012 ^61^; Arcangelli, 2017 ^60^; Some concerns | 10-year | 75% | 64% | HR = 1.45 (0.80 to 2.59); P = 0.22
Overall survival | NDearnaley, 2012 ^40^; CHHiP; SRCTN97182923; Some concerns | 5-year; Time from randomization to death from any cause. | 60 Gy; 93% | 57 Gy; 92% | 74 Gy; 91%
Overall survival | de Vries, 2020 ^59^; Incrocci, 2016 ^48^; HYPRO; ISRCTN85138529; Low | 7-year | 80.8% (76.5 to 84.4) | 77.6% (73.0 to 81.5) | HR = 0.82 (0.61 to 1.09); P = 0.17
Overall survival | de Vries, 2020 ^59^; Incrocci, 2016 ^48^; HYPRO; ISRCTN85138529; Low | 5-year | 86.2% (82.3 to 89.4) | 85.9% (81.8 to 89.2) | HR = 1.02 (0.71 to 1.46); P = 0.92
Overall survival | Lee, 2016 ^41^; RTOG-0415; Low | 5-year | 92.5% (89.9 to 94.5) | 93.2% (90.7 to 95.1) | HR = 0.95 (0.64 to 1.41)
Overall survival | Hoffman, 2018 ^53^; Low; NCT00667888 | 8-year | 90% (82.2 to 94.5) | 85.2% (76.2 to 91.0) | NS
Overall survival | Hoffman, 2018 ^53^; Low; NCT00667888 | 10-year | 82.8% (72.0 to 89.8) | 76.1% (64.3 to 84.4) | NS
Overall survival | Lukka, 2005 ^54^; Low | 5-year; Time from randomization to death from any cause or date of last visit for patients still alive | 87.6% | 85.2% | HR = 0.85 (0.63 to 1.15)
Overall survival | Poon, 2022 ^46^; NCT02339701; Some concerns | 1 year | 100% | 97% | P = 0.08
Overall survival | Wang, 2021 ^55^; CHIRP; NCT01488968; Some concerns | 3-year | 94.8% (87.5 to 102.1) | 100% | P = 0.12
Overall survival | Widmark, 2019 ^39^; HYPO-RT-PC; ISRCTN45905321; Some concerns | 5-year | 94% (92 to 96) | 96% (95 to 98) | HR = 1.11 (0.73 to 1.69)
Overall survival | Yeoh, 2006 ^62^; Yeoh, 2011 ^57^; Some concerns | 5-year | 86.4% | 84.1% | P = NS
Overall survival | Yeoh, 2006 ^62^; Yeoh, 2011 ^57^; Some concerns | 7-year | 71% | 69% | P = NS
Prostate-specific survival | Arcangelli, 2012 ^61^; Arcangelli, 2017 ^60^; Some concerns | 5-year | 98% | 92% | NS
Prostate-specific survival | Arcangelli, 2012 ^61^; Arcangelli, 2017 ^60^; Some concerns | 10-year | 95% | 88% | HR = 2.40 (0.77 to 6.84); P = 0.07
Prostate-specific survival | Avkshtol, 2020 ^63^; NCT00062309; Low | 10-year | 95.6% (92.6 to 99.5)^*^ | 95.6% (92.7 to 99.5)^*^ | NR
Prostate-specific survival | Incrocci, 2016 ^48^; de Vries, 2020 ^59^; HYPRO; ISRCTN85138529; Low | 5-year | 45/61 (73.7%)^*^ | 44/59 (74.6%)^*^ | NR
Prostate-specific survival | Incrocci, 2016 ^48^; de Vries, 2020 ^59^; HYPRO; ISRCTN85138529; Low | 7-year | 64/82 (78.0%)^*^ | 79/98 (80.1%)^*^ | NR
Prostate-specific survival | Hoffman, 2018 ^53^; Low | 10-year | 100% | 100% | --
Prostate-specific survival | Lukka, 2005 ^54^; Low | 5-year; Time from randomization to death from any cause or date of last visit for patients still alive | 453/466 (97.2%)^*^ | 452/470 (96.2%)^*^ | NR
Prostate-specific survival | Wang, 2021 ^55^; CHIRP; NCT01488968; Some concerns | 3-year | 54/54 (100%) | 55/55 (100%) | --
Prostate-specific survival | Widmark, 2019 ^39^; HYPO-RT-PC; ISRCTN45905321; Some concerns | 5-year; Cumulative incidence of prostate cancer death analyzed with non-prostate cancer death as competing risk | 98% (97 to 100)^*^ | > 99% (99 to 100)^*^ | P = 0.46
Prostate-specific survival | Yeoh, 2006 ^62^; Yeoh, 2011 ^57^; Some concerns | 5-year | 107/108 (99.1%)^*^ | 106/109 (97.2%)^*^ | NR
Prostate-specific survival | Yeoh, 2006 ^62^; Yeoh, 2011 ^57^; Some concerns | 7-year | 106/108 (98.2%)^*^ | 105/109 (96.3%)^*^ | NR

Notes.

* Calculated by review authors.

Abbreviations. ARD=absolute rate difference; ASTRO=American Society for Radiation Oncology; CHHiP=Conventional or Hypofractionated High Dose Intensity Modulated Radiotherapy in Prostate Cancer trial; CHRIP=Conventional versus Hypofractionated Radiation in High-Risk Prostate Patients trial; CT=computed tomography; HR=hazard ratio; HYPO-RT-PC=Hypofractionated Radiotherapy for Prostate Cancer trial; HYPRO=Hypofractionated versus Conventionally Fractionated Radiotherapy for Patients with Prostate Cancer trial; NR=not reported; NS=non-significant.

Appendix Table 9 Detailed Results for Toxicity Outcomes for Prostate Cancer Trials Rated “Low” or “Some Concerns” Risk of Bias

Outcome | Trial Name, Year; Trial #; Risk of Bias | Effect Measure/Definition | Hypofractionation N Events/Total N, % | | Comparison N Events/Total N, % | Results
Acute genitourinary (GU) toxicity | Aluwini, 2015 ^130^; HYPRO; ISRCTN85138529; Low | 4-week grade ≥2; RTOG | 191/401; 47.6% | | 171/385; 44.4% | P = 0.37
Acute genitourinary (GU) toxicity | Aluwini, 2015 ^130^; HYPRO; ISRCTN85138529; Low | 3-month grade ≥2; RTOG | 75/327; 22.9% | | 73/325; 22.4% | P = 0.89
Acute genitourinary (GU) toxicity | Arcangelli, 2011 ^65^; Some concerns | Acute (1 month after the end of treatment) grade ≥2; RTOG/EORTC | 39/83; 47.0% | | 34/85; 40.0% | P = 0.45
Acute genitourinary (GU) toxicity | Brand, 2019 ^47^; PACE-B; NCT01584258; Some concerns | Any point <12 weeks after radiotherapy; grade ≥2; RTOG | 118/432; 27.3% | | 96/415; 23.1% | Grade 2 only (92% of events); ARD = −4.2 (−10.0 to 1.7); P = 0.16
Acute genitourinary (GU) toxicity | Catton, 2017 ^43^; NCT00304759; Low | During first 14 weeks; -grade ≥2; RTOG | 185/608; 30.4% | | 183/598; 30.6% | NR
Acute genitourinary (GU) toxicity | Dearnaley, 2012 ^125^; Wilson, 2018 ^70^; CHHiP; SRCTN97182923; Some concerns | < 18 weeks; grade ≥2; RTOG | 60 Gy; 356/720; 49.4% | 57 GY; 327/720; 45.8% | 74 Gy; 331/715 | 60 Gy vs 74 Gy: P = 0.34; 57 Gy vs 74 Gy: P < = 0.90
Acute genitourinary (GU) toxicity | Dearnaley, 2012 ^125^; Wilson, 2018 ^70^; CHHiP; SRCTN97182923; Some concerns | < 18 weeks; grade ≥3; RTOG | NR | | NR | 60 Gy vs 74 Gy: <75 years P = 0.97; 74 Gy vs 60 Gy: ≥ 75 years P = 0.004; 57 Gy vs 74 Gy <75 years P = 0.57; ≥ 75 years P = 0.08
Acute genitourinary (GU) toxicity | Fonteyne, 2018 ^44^; NCT01921803; Some concerns | Grade ≥2 occurring within 2 months after HFRT; CTCAE v4.0 or RTOG | 47/77; 61.0% | | 47/80; 58.8% | NR
Acute genitourinary (GU) toxicity | Houshyari, 2021 ^45^; Trial # NR; Some concerns | Grade ≥2 occurring ≤5 months after randomization; RTOG | 1/20; 5.0% | | 1/20; 5.0% | NS
Acute genitourinary (GU) toxicity | Lee, 2016 ^41^; RTOG-0415; Low | Grade ≥2 within 90 days of RT completion; CTCAE | 147/545; 27.0% | | 145/534; 27.2% | NS
Acute genitourinary (GU) toxicity | Lukka, 2005 ^54^; Low | ≤ 5 months; grade 3 & 4, standardized National Cancer Institute of Canada toxicity scale | 40/466; 8.6% | | 23/470; 7.4% | ARD −3.7 (−7.0 to −0.5)
Acute genitourinary (GU) toxicity | Norkus, 2009 ^51^; Some concerns | 12 weeks; grade 2;; RTOG/EORTC (no grade ≥3 observed) | 9/47; 19.1% | | 21/44; 14.6% | P = 0.003
Acute genitourinary (GU) toxicity | Norkus, 2013 ^50^; Low | 12 weeks; grade 2; RTOG/EORTC; (no grade ≥ 3 observed) | 1/115; 0.9% | | 5/106; 4.7% | P = 0.18
Acute genitourinary (GU) toxicity | Poon, 2022 ^46^; NCT02339701; Some concerns | First occurrence of worst severity of adverse event from beginning of RT until ≤30 days after RT completion); CTCAE (no grade ≥3 observed) | 1/31; 3.2% | | 8/33; 24% | P = 0.04
Acute genitourinary (GU) toxicity | Wang, 2021 ^55^; CHIRP; NCT01488968; Some concerns | Grade ≥2; CTCAE v4.0 (deemed related to treatment during or within 12 weeks after completion of RT) | 16/53; 30.2% (17.8 to 42.5) | | 16/55; 30.9% (18.7 to 43.1) | P = 1.0
Acute genitourinary (GU) toxicity | Widmark, 2019 ^39^; HYPO-RT-PC; ISRCTN45905321; Some concerns | Grade ≥2 at treatment end; RTOG | 158/569; 27.8% | | 132/578; 22.8% | P = 0.06
Acute genitourinary (GU) toxicity | Zhong, 2021 ^56^; NCT02934685; Some concerns | Grade ≥2; CTCAE v3.0 (no Grade ≥3 observed) | 8/46; 17.4% | | 6/46; 13.0% | P = 0.13
Acute gastrointestinal (GI) toxicity | Aluwini, 2015 ^130^; HYPRO; ISRCTN85138529; Low | 4-week grade ≥2; RTOG | 108/400; 27.0% | | 70/385; 18.2% | P = 0.003
Acute gastrointestinal (GI) toxicity | Aluwini, 2015 ^130^; HYPRO; ISRCTN85138529; Low | 3-month grade ≥2; RTOG | 42/327; 12.8% | | 43/326; 13.2% | P = 0.90
Acute gastrointestinal (GI) toxicity | Arcangelli, 2011 ^65^; Some concerns | Acute (1 month after the end of treatment) grade ≥2; RTOG/EORTC | 29/83; 35% | | 18/85; 21% | P = 0.07
Acute gastrointestinal (GI) toxicity | Brand, 2019 ^47^; PACE-B; NCT01584258; Some concerns | Any point <12 weeks after radiotherapy; grade ≥2; RTOG | 53/432; 12.3% | | 43/415; 10.4% | Grade 2 only (95% of events); RD −1.9 (−6.2 to 2.4; P = 0.38)
Acute gastrointestinal (GI) toxicity | Catton, 2017 ^43^; NCT00304759; Low | During first 14 weeks; -grade ≥2 RTOG | 99/608; 16.3% | | 62/598; 10.4% | P = .003
Acute gastrointestinal (GI) toxicity | Dearnaley, 2012 ^125^; Wilson, 2018 ^70^; CHHiP; SRCTN97182923; Some concerns | <18 weeks; grade ≥2; RTOG | 60 Gy; 277/720; 38.5% | 57 Gy; 270/713; 37.9% | 74 Gy; 176/715; 24.6% | 60 Gy vs 74 Gy: P <0.0001; 57 Gy vs 74 Gy: P <0.0001; “By 18 weeks, both bowel and bladder toxicity by RTOG assessment were similar between treatment groups”
Acute gastrointestinal (GI) toxicity | Wilson, 2018 ^70^; CHHiP; SRCTN97182923; Some concerns | < 18 weeks grade ≥3; RTOG | NR | | NR | 60 Gy vs 74 Gy: < 75 years P <0.0001; ≥ 75 years P = 0.10; 57 Gy vs 74 Gy; < 75 years P < 0.0001; ≥ 75 years P = 0.05
Acute gastrointestinal (GI) toxicity | Fonteyne, 2018 ^44^; Trial #NCT01921803; Some concerns | Grade ≥2 occurring within 2 months after HFRT; CTCAE v4.0 or RTOG | 21/77; 27.3% | | 16/80; 20.0% | NR
Acute gastrointestinal (GI) toxicity | Houshyari, 2021 ^45^; Trial # NR; Some concerns | Grade ≥2 occurring ≤ 5 months after randomization; RTOG | 10/20; 50.0% | | 12/20; 60.0% | NR
Acute gastrointestinal (GI) toxicity | Lee, 2016 ^41^; RTOG-0415; Low | Grade ≥2 within 90 days of RT completion: CTCAE | 58/545; 10.6% | | 55/534; 10.3% | NS
Acute gastrointestinal (GI) toxicity | Lukka, 2005 ^54^; Low | ≤ 5 months; grade 3 & 4, standardized National Cancer Institute of Canada toxicity scale | 19/466; 4.1% | | 12/470; 2.6% | ARD −1.5 (−4.0 to 0.8)
Acute gastrointestinal (GI) toxicity | Norkus, 2009 ^51^; Some concerns | Grade 2; RTOG/EORTC | 8/47; 17.0% | | 10/44; 22.7% | NS
Acute gastrointestinal (GI) toxicity | Norkus, 2013 ^50^; Low | 12 weeks; grade 2; RTOG/EORTC (no grade ≥3 observed) | 5/115; 4.3% | | 8/106; 7.5% | P = 0.37
Acute gastrointestinal (GI) toxicity | Poon, 2022 ^46^; NCT02339701; Some concerns | First occurrence of worst severity of adverse event from beginning of RT until <30 days after RT completion); CTCAE (no grade ≥3 observed) | 2/31; 6.4% | | 7/33; 21.2% | NR
Acute gastrointestinal (GI) toxicity | Wang, 2021 ^55^; CHIRP; NCT01488968; Some concerns | Grade ≥2; CTCAE v4.0 (deemed related to treatment during or within 12 weeks after completion of RT) | 10/53; 18.9%; (8.3 to 29.4) | | 12/55; 21.8%; (10.9 to 32.7) | P = 0.81
Acute gastrointestinal (GI) toxicity | Zhong, 2021 ^56^; NCT02934685; Some concerns | Grade ≥2; CTCAE v3.0 (no grade ≥3 observed) | 8/46; 17.4% | | 5/46; 10.9% | P = 0.19
Late genitourinary (GU) toxicity | Aluwini, 2016 ^64^; HYPRO; ISRCTN85138529; Low | 3-year cumulative incidences of grade ≥2; RTOG/EORTC | 21.9% (18.1 to 26.4) | | 17.7% (14.1 to 21.9) | HR 1.19 (0.88 to 1.59); P = 0.26
Late genitourinary (GU) toxicity | Arcangelli, 2011 ^60^ ^,^ ^65^; Some concerns | 3-year grade ≤2; modified (“clinical”) LENT-SOMA scale; occurring or persisting for ≥6 months after end of RT | 7/83 | | 5/85 | P = 0.92
Late genitourinary (GU) toxicity | Arcangelli, 2011 ^60^ ^,^ ^65^; Some concerns | 9-year grade ≥2; modified (“clinical”) LENT-SOMA scale; occurring or persisting for ≥6 months after end of RT | NR; (reported as freedom from late toxicity, 86%) | | NR; (reported as freedom from late toxicity, 79%) | P = 0.68
Late genitourinary (GU) toxicity | Catton, 2017 ^43^; NCT00304759; Low | 6 months onward; grade ≥2 RTOG | 136/608; 22.4% | | 134/598; 22.4% | NR
Late genitourinary (GU) toxicity | Dearnaley, 2012 ^125^; Wilson, 2018 ^70^; CHHiP; SRCTN97182923; Some concerns | 2-year; grade ≥2; RTOG | 60 Gy; 16/959; 1.7% | | 57 Gy; 11/962; 1.1% | 60 Gy vs 74 Gy: P = 0.71; 74 Gy vs 57 Gy: P = 0.68
Late genitourinary (GU) toxicity | Dearnaley, 2012 ^125^; Wilson, 2018 ^70^; CHHiP; SRCTN97182923; Some concerns | 5-year; grade ≥2; RTOG | 60 Gy; 88/NR | | 57 Gy; 57/NR | 60 Gy vs 74 Gy: HR = 1.34 (0.98 to 1.85); P = 0.07; 57 Gy vs 74 Gy: HR = 0.85 (0.60 to 1.12); P = 0.37
Late genitourinary (GU) toxicity | Dearnaley, 2012 ^125^; Wilson, 2018 ^70^; CHHiP; SRCTN97182923; Some concerns | 5-year grade ≥2; RTOG/RMH/LENT-SOM | NR | | NR | 60 Gy vs 74 Gy:; < 75 years P = 0.012; ≥ 75 years P = NS; 57 Gy vs 74 Gy; < 75 years P = NS; ≥ 75 years P = NS
Late genitourinary (GU) toxicity | Hoffman, 2014 ^53^ ^,^ ^66^; Low; NCT00667888 | 5-year (> 90 days after RT completion); grade ≥2 RTOG | 15/101; 15.8%; (9.8 to 24.9) | | 15/102; 16.5%; (10.2 to 26.1) | P = 0.97
Late genitourinary (GU) toxicity | Hoffman, 2014 ^53^ ^,^ ^66^; Low; NCT00667888 | 5-year (> 90 days after RT completion); grade ≥2 RTOG | Intermediate/high vs low NCCN; 0.63 (0.22 to 1.77); P = .38 | | Intermediate/high vs low NCCN; 0.90 (0.31 to 2.64); P = .85 | --
Late genitourinary (GU) toxicity | Hoffman, 2014 ^53^ ^,^ ^66^; Low; NCT00667888 | 8-year (> 90 days after RT completion) grade ≥2; RTOG | 15/104; 15.1%; (9.4 to 23.8) | | 16/102; 16.4%; (10.4 to 25.4) | P = 0.84
Late genitourinary (GU) toxicity | Lee, 2016 ^41^; RTOG-0415; Low | > 90 days after RT completion; grade ≥2; CTCAE | 161/545; 29.5% | | 121/534; 22.6% | Grade 2: RR = 1.31 (1.07 to 1.61); P = 0.009; Grade 3:; RR = 1.56 (0.76 to 3.18); P = 0.22
Late genitourinary (GU) toxicity | Lukka, 2005 ^54^; NCT01488968; Low | > 5 months; grade 3 & 4, standardized National Cancer Institute of Canada toxicity scale | 9/466; 1.9% | | 9/470; 1.9% | ARD = 0.0 (−1.9 to 1.9)
Late genitourinary (GU) toxicity | Pollack, 2013 ^52^; NCT00062309; Low | 5-year cumulative risk; modified LENT/RTOG criteria | 21.5% (14.4% to 29.6%) | | 13.4% (8.0% to 20.1%) | P = 0.16
Late genitourinary (GU) toxicity | Poon, 2022 ^46^; NCT02339701; Some concerns | 1-year grade ≥2; CTCAE | 6/31; 19.4% | | 8/33; 24.2% | NR
Late genitourinary (GU) toxicity | Wang, 2021 ^55^; CHIRP; NCT01488968; Some concerns | Cumulative grade ≥2; CTCAE v4.0 (related to treatment that occurred ≥3 months after RT completion) | 8/50; 16.0% (5.8 to 26.2) | | 3/50; 6.0% (0 to 12.6) | P = 0.20
Late genitourinary (GU) toxicity | Widmark, 2019 ^39^; HYPO-RT-PC; ISRCTN45905321; Some concerns | 1-year grade ≥2; RTOG | 32/528; 6.1% | | 13/529; 2.4% | P = 0.004
Late genitourinary (GU) toxicity | Widmark, 2019 ^39^; HYPO-RT-PC; ISRCTN45905321; Some concerns | 5-year grade ≥2; RTOG | 11/243; 4.5% | | 12/249; 4.8% | P = 1.00
Late genitourinary (GU) toxicity | Zhong, 2021 ^56^; NCT02934685; Some concerns | 2-year grade ≥2; RTOG/EORTC | 0/46; 0% | | 2/46; 4.4% | P = 0.50
Late gastrointestinal (GI) toxicity | Aluwini, 2016 ^64^; HYPRO; ISRCTN85138529; Low | 3-year cumulative incidences; grade ≥2; RTOG/EORTC | 41.3% (36.6 to 46.4) | | 39.0% (34.2 to 44.1) | HR = 1.16 (0.94-1.43); P = 0.16
Late gastrointestinal (GI) toxicity | Arcangelli, 2011 ^60^ ^,^ ^65^; Some concerns | 3-year grade ≥2; modified (“clinical”) LENT-SOMA scale; occurring or persisting for ≥6 months after end of RT | 12/83; 14.4% | | 10/85; 11.8% | P = 0.55
Late gastrointestinal (GI) toxicity | Arcangelli, 2011 ^60^ ^,^ ^65^; Some concerns | 9-year grade ≥2; modified (“clinical”) LENT-SOMA scale; occurring or persisting for ≥6 months after end of RT | NR; (reported as freedom from late toxicity, 86.5%) | | NR; (reported as freedom from late toxicity, 84.6%) | P = 0.57
Late gastrointestinal (GI) toxicity | Catton, 2017 ^43^; NCT00304759; Low | 6 months onward; grade ≥2 RTOG | 54/608; 8.9% | | 83/598; 13.9% | P = .006
Late gastrointestinal (GI) toxicity | Dearnaley, 2012 ^40^; Wilson, 2018 ^70^; CHHiP; SRCTN97182923; Some concerns | 2-year; grade ≥2; RTOG | 60 Gy; 28/959; 2.9% | 57 GY; 17/963; 2.8% | 74 Gy; 35/922; 3.8% | 60 Gy vs 74 Gy: P = 0.31; 74 Gy vs 57 Gy: P = 0.0075
Late gastrointestinal (GI) toxicity | Dearnaley, 2012 ^40^; Wilson, 2018 ^70^; CHHiP; SRCTN97182923; Some concerns | 5-year grade ≥2; RTOG | 60 Gy; 105/NR | 57 GY; 95/NR | 74 Gy; 111/NR | 60 Gy vs 74 Gy: HR = 0.94 (0.72 to 1.23); P = 0.65; 57 Gy vs 74 Gy: HR = 0.84 (0.64 to 1.11); P = 0.22
Late gastrointestinal (GI) toxicity | Dearnaley, 2012 ^40^; Wilson, 2018 ^70^; CHHiP; SRCTN97182923; Some concerns | 5-year grade ≥ 2; RTOG/RMH/LENT-SOM | NR | | NR | 60 Gy vs 74 Gy: < 75 years P = NS; ≥ 75 years P = NS; 57 Gy vs 74 Gy; < 75 years P = NS; ≥ 75 years P = NS
Late gastrointestinal (GI) toxicity | Hoffman, 2014 ^53^ ^,^ ^66^; Low; NCT00667888 | 5-year (> 90 days after completion of RT); grade ≥2 RTOG | 11/101; 10.0%; (5.5 to 17.8) | | 5/102; 5.1; (2.1 to 11.7) | P = 0.11
Late gastrointestinal (GI) toxicity | Hoffman, 2014 ^53^ ^,^ ^66^; Low; NCT00667888 | 5-year (> 90 days after RT completion); grade ≥2 RTOG | Intermediate/high vs low NCCN; HR = 0.22 (0.06 to 0.74); P = .02 | | Intermediate/high vs low NCCN; HR = 0.61 (0.10 to 3.65); P =. 59 | --
Late gastrointestinal (GI) toxicity | Hoffman, 2014 ^53^ ^,^ ^66^; Low; NCT00667888 | 8-year (> 90 days after completion of RT) grade ≥2 RTOG | 12/104; 12.6%; (7.3 to 21.2) | | 5/102; 5.0%; (2.1 to 11.6) | P = .08
Late gastrointestinal (GI) toxicity | Lee, 2016 ^41^; RTOG-0415; Low | > 90 days after RT completion; grade ≥2; CTCAE | 121/545; 22.2% | | 75/534; 14.0% | Grade 2: RR = 1.59 (1.22 to 2.06); P = 0.005; Grade 3: RR = 1.55 (0.80 to 2.99); P = 0.19
Late gastrointestinal (GI) toxicity | Lukka, 2005 ^54^; Low | >5 months; grade 3 & 4, standardized National Cancer Institute of Canada toxicity scale | 6/466; 1.3% | | 6/470; 1.3% | ARD = 0.0 (−1.7 to 1.6)
Late gastrointestinal (GI) toxicity | Pollack, 2013 ^52^; NCT00062309; Low | Overall crude incidence at 5 years (≥ 3 months after the end of RT); LENT/RTOG criteria | 18.1% | | 22.5% | P = 0.39
Late gastrointestinal (GI) toxicity | Poon, 2022 ^46^; NCT02339701; Some concerns | 1-year grade ≥2; CTCAE | 4/31; 12.9% | | 6/33; 18.2% | NR
Late gastrointestinal (GI) toxicity | Wang, 2021 ^55^; CHIRP; NCT01488968; Some concerns | Cumulative grade ≥2; CTCAE v4.0 (related to treatment that occurred ≥3 months after RT completion) | 8/50; 16.0% (5.8 to 26.2) | | 5/50; 10.0% (1.7 to 18.3) | P = 0.55
Late gastrointestinal (GI) toxicity | Widmark, 2019 ^39^; HYPO-RT-PC; ISRCTN45905321; Some concerns | 5-year grade ≥2; RTOG | 3/244; 1.2% | | 9/249; 3.6% | P = 0.14
Late gastrointestinal (GI) toxicity | Zhong, 2021 ^56^; NCT02934685; Some concerns | 2-year grade ≥2; RTOG/EORTC | 3/46; 6.5% | | 2/46; 4.3% | P = 0.92

Abbreviations. ARD=absolute rate difference; CHHiP=Conventional or Hypofractionated High Dose Intensity Modulated Radiotherapy in Prostate Cancer trial; CHRIP=Conventional versus Hypofractionated Radiation in High Risk Prostate Patients trial; CTCAE=Common Terminology Criteria for Adverse Events; EORTC=European Organization for Research and Treatment of Cancer; GI=gastrointestinal; GU=genitourinary; Gy=gray; HFRT=hypofractionated radiotherapy; HR=hazard ratio; HYPRO=Hypofractionated versus Conventionally Fractionated Radiotherapy for Patients with Prostate Cancer trial; LENT-SOM=Late Effects in Normal Tissues Subjective, Objective, Management and Analytic scale; NCCN=National Comprehensive Cancer Network; NR=not reported; NS=non-significant; PACE-B=Prostate Advances in Comparative Evidence trial; RMH=Royal Marsden Hospital scoring system; RR=risk ratio; RT=radiation therapy; RTOG=Radiation Therapy Oncology Group.

Appendix Table 10 Detailed Results for Global Quality of Life for Prostate Cancer Studies Rated “Low” or “Some Concerns” Risk of Bias

Trial Name, Year; Trial #; Risk of Bias | Effect Measure/Definition | Hypofractionation N Events/Total N | Comparison N Events/Total N | Results
Fransson, 2021 ^58^; HYPO-RT-PC; ISRCTN45905321; Some concerns | Mean difference in clinically relevant deterioration of global health/quality of life (EORTC QLQ-30) at 6 years after treatment | 46/125; (37%) | 56/134; (42%) | MD 5.0% (95% CI [−5.0,15.0]) P = 0.41
Brand, 2019 ^47^; PACE-B; NCT01584258; Some concerns | EPIC 26 | NR | NR | “We observed no significant difference between the study groups in the proportion of patients with a clinically significant reduction from baseline for any EPIC-26 subdomain score area, neither assessed at any time nor at week-12 only.”
Bruner, 2019 ^67^; RTOG-0415; NCT00331773 | EuroQol-5; EPIC | NR | NR | “There were no differences between arms at any time point for the EuroQol-5 questionnaire.”; “There were no differences in change score between arms with respect to any of the EPIC domain scores at 6, 24, or 60 months.”
Shaikh, 2017 ^68^; NCT00062309; Low | IPSS overall (minimum clinically important difference [0.5 SD change from baseline]) at 5 years | NR | NR | HR = 1.11 (95% CI [0.56, 2.18])
Shaikh, 2017 ^68^; NCT00062309; Low | IPSS QoL (minimum clinically important difference [0.5 SD change from baseline]) at 5 years | NR | NR | HR = 0.68 (95% CI [0.29, 1.62])
Wilkins, 2015 ^69^; CHHiP; SRCTN97182923; Some concerns | 2-year FACT-P, SF-12 and SF-36 | NR | NR | “We identified no significant differences in health-related quality of life domain scores measured by FACT-P, SF-12 and SF-36 between treatment groups at 24 months.”

Abbreviations. CHHiP=Conventional of Hypofractionated High Dose Intensity Modulated Radiotherapy for Prostate Cancer trial; CI=confidence interval; EORTC QLQ-30=European Organization for Research and Treatment of Cancer Quality of Life Questionnaire; EPIC-26=Extended Prostate Cancer Index, 26 item; FACT-P=Functional Assessment of Cancer Therapy-Prostate; HR=hazard ratio; HYPO-RT-PC=Hypofractionated Radiotherapy for Prostate Cancer trial; IPSS=International Prostate Symptom Score; MD=mean difference; NR=not reported; PACE-B=Prostate Advances in Comparative Evidence trial; QoL=quality of life; SF-12=Short Form Survey 12 item; SF-36=Short Form Survey 36 item; SD=standard deviation.