# APPENDIX D BREAST CANCER

Appendix Table 1 Risk of Bias Ratings for All Eligible Breast Cancer Trials

Trial | Outcome | Domain 1: Risk of Bias Arising from the Randomization Process | Domain 2a: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Assignment to Intervention) | Domain 2b: Risk of Bias Due to Deviations from the Intended Interventions (Effect of Adherence to Intervention) | Domain 3: Risk of Bias Due to Missing Outcome Data | Domain 4: Risk of Bias in Measurement of Outcome | Domain 5: Risk of Bias in Selection of the Reported Result | Overall Risk of Bias
APBI-IMRT-Florence^14,37,38^ | Harms | Low | Low | Some concerns | Low | Low | Low | Some concerns
APBI-IMRT-Florence^14,37,38^ | Mortality | Low | Low | Some concerns | Low | Low | Low | Some concerns
APBI-IMRT-Florence^14,37,38^ | Survival | Low | Low | Some concerns | Low | Low | Low | Some concerns
Baillet^103^ | Harms | Some concerns | Some concerns | Some concerns | Low | Low | Some concerns | High
Das^104^ | Harms | Some concerns | Some concerns | High | High | Low | Some concerns | High
Das^104^ | Survival | Some concerns | Some concerns | High | High | Low | Some concerns | High
FAST^15,35^ | Harms^15^ | Low | Low | Low | Low | Low | Low | Low
FAST^15,35^ | Mortality^15^ | Low | Low | Low | Low | Low | Low | Low
FAST^15,35^ | Survival^15,35^ | Low | Low | Low | Low | Low | Low | Low
FAST-Forward^16,17^ | Harms^17^ | Low | Low | Low | Some concerns | Low | Low | Some concerns
FAST-Forward^16,17^ | Mortality^16^ | Low | Low | Low | Low | Low | Low | Low
FAST-Forward^16,17^ | Survival^16^ | Low | Lowf | Low | Low | Low | Low | Low
Hosseini^105^ | Harms | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Hou^106^ | Mortality | Some concerns | Low | Low | Low | Low | Low | High
Hou^106^ | Survival | Some concerns | Low | Low | Low | Low | Low | High
Kalita^107^ | Harms | Some concerns | Some concerns | High | Low | Low | Some concerns | High
King^30^ | QoL | Low | Low | Low | Low | Some concerns | Low | Some concerns
Kumbhaj^108^ | Harms | Some concerns | Some concerns | High | High | High | Some concerns | High
Kumbhaj^108^ | Survival | Some concerns | Some concerns | High | High | Low | Some concerns | High
Maiti^109^ | Harms | High | High | High | Some concerns | Low | Low | High
Maiti^109^ | Mortality | High | High | High | Low | Low | Low | High
Maiti^109^ | Survival | High | High | High | Some concerns | Low | Low | High
Offersen^29^ | Mortality | Low | Low | Low | Low | Low | Low | Low
Offersen^29^ | Survival | Low | Low | Low | Low | Low | Low | Low
Owen^13^ | Survival | Low | Some concerns | Some concerns | Low | Low | Low | Some concerns
RAPID^31,36^ | Harms^31,36^ | Low | Low | Low | Some concerns | Low | Low | Some concerns
RAPID^31,36^ | Mortality^31^ | Low | Low | Low | Low | Low | Low | Low
RAPID^31,36^ | Survival^31^ | Low | Low | Low | Low | Low | Low | Low
Purohit^110^ | Harms | Some concerns | Some concerns | High | High | Some concerns | Some concerns | High
Rastogi^111^ | Harms | Some concerns | Low | Some concerns | High | Some concerns | Some concerns | High
Rastogi^111^ | Survival | Some concerns | Low | Some concerns | High | Some concerns | Some concerns | High
Rodriguez-Li^112,113^ | Harms^112,113^ | Some concerns | Some concerns | High | Some concerns | Low | Low | High
Rodriguez-Li^112,113^ | Mortality^112^ | Some concerns | Some concerns | High | Low | Low | Low | High
Rodriguez-Li^112,113^ | Survival^112,113^ | Some concerns | Some concerns | High | Low | Low | Low | High
Schmeel^19^ | Harms | Some concerns | Low | Some concerns | Low | Low | Low | Some concerns
Shahid^114^ | Harms | Some concerns | Some concerns | High | Some concerns | Low | Low | High
Shahid^114^ | Mortality | Some concerns | Some concerns | High | Some concerns | Low | Low | High
Shahid^114^ | Survival | Some concerns | Some concerns | High | Some concerns | Low | Low | High
NCT01266642^23,24,34^ | Harms^23,24^ | Some concerns | Low | Low | Low | Low | Low | Some concerns
NCT01266642^23,24,34^ | Survival^24^ | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
NCT01266642^23,24,34^ | QoL^23,24,34^ | Some concerns | Low | Low | Some concerns | Low | Low | Some concerns
Spooner^20^ | Mortality | Some concerns | Low | Some concerns | Low | Low | Low | Some concerns
Spooner^20^ | Survival | Some concerns | Low | Some concerns | Low | Low | Low | Some concerns
START^11,12,33^ | Mortality | Low | Low | Low | Low | Low | Low | Low
START^11,12,33^ | Survival | Low | Low | Low | Low | Low | Low | Low
Swanick^115^ | QoL | Some concerns | Low | Low | Some concerns | Some concerns | Low | High
Taher^116^ | Harms | High | Low | High | Low | Some concerns | Some concerns | High
TomoBreast^21,22^ | Harms^22^ | Some concerns | Low | Some concerns | Low | Low | Low | Some concerns
TomoBreast^21,22^ | QoL^21^ | Some concerns | Low | Some concerns | Low | Low | Low | Some concerns
Van Hulle^18^ | Harms | Some concerns | Some concerns | Some concerns | Low | Low | Low | Some concerns
Van Hulle^18^ | QoL | Some concerns | Some concerns | Some concerns | Low | Low | Low | Some concerns
Wang 2019^28^ | Harms | Low | Low | Low | Low | Low | Low | Low
Wang 2019^28^ | Mortality | Low | Low | Low | Low | Low | Low | Low
Wang 2019^28^ | Survival | Low | Low | Low | Low | Low | Low | Low
Wang 2020^27^ | Harms | Low | Low | Low | Low | Low | Low | Low
Wang 2020^27^ | Mortality | Low | Low | Low | Low | Low | Low | Low
Wang 2020^27^ | Survival | Low | Low | Low | Low | Low | Low | Low
NCT00156052^25,26,32^ | Harms^25,32^ | Low | Low | Low | Some concerns | Low | Low | Some concerns
NCT00156052^25,26,32^ | Mortality^25,26^ | Low | Low | Low | Low | Low | Low | Low
NCT00156052^25,26,32^ | Survival^25,26^ | Low | Low | Low | Low | Low | Low | Low
NCT00156052^25,26,32^ | QoL^32^ | Low | Low | Some concerns | High | High | Low | High
Yadav^117^ | Harms | High | Some concerns | High | Low | Low | Low | High
Zhao 2016^118^ | Harms | Some concerns | Some concerns | Some concerns | Some concerns | Low | Low | High
Zhao 2016^118^ | Mortality | Some concerns | Some concerns | Some concerns | Some concerns | Low | Low | High
Zhao 2016^118^ | Survival | Some concerns | Some concerns | Some concerns | Some concerns | Low | Low | High
Zhao 2017^119^ | Harms | Some concerns | Some concerns | High | Low | Low | Low | High
Zhao 2017^119^ | Mortality | Some concerns | Some concerns | High | Low | Low | Low | High
Zhao 2017^119^ | Survival | Some concerns | Some concerns | High | Low | Low | Low | High

Appendix Table 2 Study Characteristics for All Eligible Breast Cancer Trials

Trial Name, Year Trial # Risk of Bias Country Funding Follow-up | Inclusion/Exclusion Criteria | Hypofractionation Characteristics | | Conventional Characteristics | | Outcomes Reported (Risk of Bias If Different by Outcome)
Trial Name, Year Trial # Risk of Bias Country Funding Follow-up | Inclusion/Exclusion Criteria | N Baseline Characteristics (n, %) | Dose/Fraction Total Dose Time | N Baseline Characteristics (n, %) | Dose/Fraction Total Dose Time | Outcomes Reported (Risk of Bias If Different by Outcome)
Trial Name, Year Trial # Risk of Bias Country Funding Follow-up | Inclusion/Exclusion Criteria | N Baseline Characteristics (n, %) | Dose/Fraction Total Dose Time | N Baseline Characteristics (n, %) | Dose/Fraction Total Dose Time | *Primary
Hypofractionation vs Conventional Radiation
BIG3-07/TROG 07.01; NCT00470236 (King, 2020)^30^; SOME CONCERNS; 11 countries (118 sites); National Health and Medical Research Council, Susan G. Komen for the Cure, Breast Cancer Now, OncoSuisse Federation Against Cancer, Dutch Cancer Society; 2 years | Inclusion: Women ≥ 18 years old with completely excised DCIS and increased risk of local recurrence (age <50 years, or in those ≥ 50 years old, symptomatic presentation, palpable tumour, tumour ≥ 15 mm, multifocal disease, intermediate or high nuclear grade, central necrosis, comedo histology, and/or radial surgical margin < 10 mm; Exclusion: NR; Other treatments:; - Radiation boost; - Hormone therapy | N = 532; ≥ 50 years old: 445 (84); Race: NR; Tumor grade: NR | 42.5 Gy/16 fractions over 3.5 weeks | N = 615; ≥ 50 years old: 495 (80); Race: NR; Tumor grade: NR | 50 Gy/25 fractions over 5 weeks | Primary endpoint: Local recurrence (NR); QoL
DBCG HYPO; NCT00909818 (Offersen, 2020)^29^; LOW; Denmark, Germany, and Norway (8 centers); Danish Cancer Society, Centre for Interventional Research in Radiation Oncology, and Danish Comprehensive Cancer Center Radiotherapy Group; 9 years | Inclusion: Women > 40 years old, had breast-conserving surgery without immediate reconstruction, early stage (pT1/2, pN0/1, M0) or DCIS requiring radiotherapy to the residual breast only; Exclusion: Need for regional lymph node radiation, previous breast cancer or bilateral, past radiation of thorax or breast, breast implants, comorbidity which may increase sensitivity to radiation (eg, dermatomyositis, or symptomatic heart/lung disease), or any difficulty completing protocol; Other treatments:; - Radiation boost; - Chemotherapy; - Hormone therapy; - Trastuzumab | N = 917; Median age (IQR): 59 (41,82); Race: NR; DCIS: 123 (13); Tumor stage:; - T1a: 64 (8); - T1b: 191 (24); - T1c: 403 (51); - T2: 136 (17); Node status:; - N0: 683 (86); - N1: 76 (10); Isolated tumor cells: 35 (4) | 40 Gy/15 fractions over 3 weeks | N = 937; Median age (range): 59 (42–83); Race: NR; DCIS: 123 (13); Tumor stage:; - T1a: 48 (6); - T1b: 196 (24); - T1c: 414 (51); - T2: 156 (19); Node status:; - N0: 661 (81); - N1: 107 (13); Isolated tumor cells: 46 (6) | 50 Gy/25 fractions over 5 weeks | Primary endpoint: Cosmetic (breast induration at 3 years); Survival; - Locoregional recurrence; - OS
DRKS00017763; (Schmeel, 2020)^19^; SOME CONCERNS; Germany (University Hospital, Bonn); Funding NR; 6 weeks | Inclusion: Women > 18 years old, had breast-conserving surgery; Exclusion: Metastatic disease, chemotherapy, need for regional nodal irradiation, previous radiation to ipsilateral breast, breast-reconstruction or any previous surgery in radiation area, active smoking, active skin condition, use of topical or oral corticosteroids, tattoos in the irradiation area; Other treatments: NR | N = 71; Mean age (SD): 59.9 (±10.7); Race N (%): Caucasian: 70 (99); Cancer staging:; T1: 48 (68); T2: 16 (23) | 40.05 Gy/15 fractions | N = 72; Mean age (SD): 59.0 (11.7); Caucasian: 70 (97); Cancer staging:; T1: 43 (60); T2: 16 (23) | 50 Gy/25 fractions | Primary endpoint: Dermatitis, grade ≥ 2
NCT00156052; (Whelan, 2010^25^; Whelan, 2002^26^; Arsenault, 2020^32^); LOW; Canada (8 centers); Canadian Breast Cancer Research alliance, Canadian Cancer Society; 10 years | Inclusion: Women with invasive breast cancer, had lumpectomy and negative axillary lymph nodes; Exclusion: Cancer involving margins of excision, tumor > 5 cm, breast width >25 cm; Other treatments; - Chemotherapy; - Hormone therapy | N = 622; ≥ 60 years old: 277 (45); Race: NR; Tumor grade:; I: 215 (35); II: 244 (39); III: 117 (19); Unknown: 46 (7) | 42.5/16 fractions over 22 days | N = 612; ≥ 60 years old: 309 (51); Race: NR; Tumor grade:; I: 209 (34); II: 236 (39); III: 116 (19); Unknown: 51 (8) | 50 Gy/25 fractions over 35 days | Primary endpoint: Local recurrence; Survival:; - OS; - Disease-free; Harms:; Toxicity (acute):; - Skin (some concerns); Toxicity (late):; - Skin (some concerns); QoL (high)
NCT00793962; (Wang, 2019)^28^; LOW; China (1 site); National Key Projects of Research and Development of China, Chinese Academy of Medical Science Innovation Fund for Medical Sciences, and Beijing Marathon of Hope, Cancer Foundation of China; 5 years (median follow-up 59.5 months) | Inclusion: Women 18–75 years old, had mastectomy and axillary dissection with negative margions and ≥ 4 positive axillary lymph nodes or primary T3/4 disease; Karnofsky score ≥ 60%; Exclusion: Bilateral breast cancer, positive supraclavicular or internal mammary node, distant metastasis, had breast reconstruction or previous radiation, had past or current other cancer, or other serious comorbidity (drug use, mental illness, collagen vascular disease, etc); Other treatments:; - Chemotherapy; - Hormone therapy; - Trastuzumab | N = 406; ≥ 50 years old: 194 (48); Race: NR; Cancer stage: Stage 3: 377 (94); Tumor grade: 3: 121 (30) | 43.5 Gy/15 fractions over 3 weeks | N = 414; ≥ 50 years old: 202 (49); Race: NR; Cancer stage: Stage 3: 384 (94); Tumor grade: 3: 111 (27) | 50 Gy/25 fractions over 5 weeks | Primary endpoint: Locoregional recurrence; Survival; - OS; - Disease-free; Harms:; Toxicity (acute); - Skin; - Pneumonitis; Toxicity (late):; - Skin; - Lymphoedema
NCT01266642; (Shaitelman, 2015^23^; Shaitelman, 2018^120^; Weng, 2021^121^); SOME CONCERNS; US (1 site); American Society of Clinical Oncology, Breast Cancer Research Foundation, Cancer Prevention and Research Institute of Texas, University of Texas MD Anderson Cancer Center, gift from Ann and Clarence Cazalot, and NCI; 5 years | Inclusion: Women ≥ 40 years, DCIS or stage I-II breast cancer (Tis-T2, N0N1a, M0), breast-conserving surgery with negative margins (defined as “no tumor on ink”) and no need for third field to cover regional lymph nodes; Exclusion: Ongoing treatment for another cancer, past breast cancer, bilateral breast cancer, prior overlapping irradiation, or lack of fluency in English or Spanish.; Other treatments:; - Boost radiation; - Chemotherapy | N = 138; ≥ 50 years old: 119 (86); Race:; White: 99 (72); Hispanic: 20 (15); Black: 17 (12); Asian: 2 (1); DCIS: 24 (17); Node status:; pN0: 95 (69); pN1mic: 6 (4); pN1a: 7 (5); Tumor grade:; 1: 34 (25); 2: 73 (53); 3: 30 (22) | 2.66 Gy/fraction 42.56 Gy duration NR | N = 149; ≥ 50 years old: 136 (92); Race:; White: 116 (78); Hispanic: 16 (11); Black: 15 (10); Asian: 2 (1); DCIS: 39 (26); Node status:; pN0: 101 (68); pN1mic: 14 (9); pN1a: 1 (1); Tumor grade:; 1: 40 (27); 2: 70 (47); 3: 39 (26) | 2.0 Gy/fraction 50 Gy duration NR | Primary endpoint: cosmetic (3 years); Survival (high):; - OS; - Local recurrence; Harms:; Toxicity (acute); - Overall; - Skin; Toxicity (late); - Overall; - Skin; - Pneumonitis; - Lymphedema; QoL
NCT01413269; (Wang, 2020)^27^; LOW; China (4 centers); Chinese Academy of Science; 5 years (median follow-up 73.5 months) | Inclusion: Women 18–70 years old with invasive breast cancer, T1/2 disease, had undergone lumpectomy and axillary dissection (or sentinel node biopsy if sentinel nodes were negative) with negative margins (microscopically tumor-free ≥1 mm); Exclusion: Supraclavicular/ internal mammary node or distant metastasis, received neoadjuvant chemotherapy, bilateral breast cancer, or had undergone previous irradiation or malignancies; Other treatments:; - Chemotherapy | N = 365; ≥ 45 years old: 216; Race: NR; Staging:; I: 247 (68); II: 106 (29); III: 12 (3); Tumor grade:; 1–2: 228 (63); 3: 101 (28); Unknown: 36 | 2.9 Gy/fraction 43.5 Gy; 3 weeks (+ boost 8.7 Gy in 3 fractions over 3 days) | N = 364; ≥ 45 years old: 223; Race: NR; Staging:; I: 248 (68); II: 104 (29); III: 12 (3); Tumor grade:; 1–2: 248 (72); 3: 82 (23); Unknown: 34 | 2 Gy/fraction 50 Gy; 5 weeks (+ boost 10 Gy in 5 fractions over 1 week) | Primary endpoint: Local recurrence; Survival:; - Locoregional recurrence; - Disease-free; - OS; Harms:; Toxicity (acute); - Skin; - Pneumonitis; Toxicity (late); - Lymphedema; - Lung fibrosis
START A; ISRCTN59368779 (START Trialists, 2008^11^; Haviland, 2013^33^); LOW; UK (17 sites); Cancer Research UK, UK Medical Research Council, Department of Health; Median follow-up 9.3 years | Inclusion: Women ≥ 18 years, invasive breast cancer; (pT1-3a pN0-1M0) requiring radiotherapy after BCS or mastectomy with clear tumor margins ≥1 mm and no immediate reconstruction; Exclusion: NR; Other treatments:; - Chemotherapy; - Hormone therapy | Arm A: N = 750; Mean age (SD): 57.0 (±10.7); Race: NR; Cancer stage:; Tumor size in cm; <1: 26 (4); 1-: 347 (46); 2-: 203 (27); 3-: 169 (23); Not known: 5 (1%); Node status; N0: 536 (72); N1: 197 (26); Not known: 17 (2); Tumor grade:; 1: 150 (20); 2: 379 (51); 3: 207 (28) | Arm A:3.2 Gy/fraction 41.6 Gy 5 weeks | N = 749; Mean age (SD): 57.6 (±10.5); Race: NR; Cancer stage:; Tumor size in cm; <1: 24 (3); 1-: 362 (48); 2-: 202 (27); 3-: 156 (21); Not known: 5 (1); Node status; N0: 514 (69); N1: 222 (30); Not known: 13 (2); Tumor grade:; 1: 157 (21); 2: 369 (49); 3: 212 (28) | 2.0 Gy/fraction 50 Gy 5 weeks | Primary endpoint: Locoregional recurrence; Survival:; - OS; - Local recurrence; - Distant metastasis; - Disease-free
START A; ISRCTN59368779 (START Trialists, 2008^11^; Haviland, 2013^33^); LOW; UK (17 sites); Cancer Research UK, UK Medical Research Council, Department of Health; Median follow-up 9.3 years | | Arm B: N = 737; Mean age (SD): 57.1 (±10.5); Race: NR; Cancer stage:; Tumor size in cm; <1: 24 (3); 1-: 355 (48); 2-: 198 (27); 3-: 157 (21); Not known: 3 (0.3); Node status; N0: 497 (67); N1: 224 (30); Not known: 16 (2); Tumor grade:; 1: 149 (20); 2: 368 (50); 3: 210 (29) | Ar 3.3 3.0 Gy/fraction; 39 Gy; 5 weeks | | 2.0 Gy/fraction 50 Gy 5 weeks | Primary endpoint: Locoregional recurrence; Survival:; - OS; - Local recurrence; - Distant metastasis; - Disease-free
START B; ISRCTN59368779 (START Trialists, 2008^12^; Haviland, 2013^33^); LOW; UK (23 sites); Cancer Research UK, UK Medical Research Council, Department of Health; Median follow-up 9.9 years | Inclusion: Women ≥ 18 years, invasive breast cancer; (pT1-3a pN0-1M0) requiring radiotherapy after BCS or mastectomy with clear tumor margins ≥1 mm and no immediate reconstruction; Exclusion: NR; Other treatments:; - Chemotherapy; - Hormone therapy | N=1110; Mean age (SD): 57.8 (±9.5); Race: NR; Cancer stage:; Tumor size in cm; <1: 167 (15); 1-: 542 (49); 2-: 288 (26); 3-: 107 (10); Not known: 6 (0.5); Node status; N0: 804 (72); N1: 266 (24); Not known: 40 (4); Tumor grade:; 1: 311 (28); 2: 532 (48); 3: 248 (22) | 2.67 Gy/fraction; 40.05 Gy; 3 weeks | N=1105; Mean age (SD): 57.0 (±10.4); Race: NR; Cancer stage:; Tumor size in cm; <1: 151 (14); 1-: 552 (50); 2-: 287 (26); 3-: 113 (10); Not known: 2 (0.2); Node status; N0: 831 (75); N1: 238 (22); Not known: 36 (3); Tumor grade:; 1: 306 (28); 2: 518 (47); 3: 261 (24) | 2.0 Gy/fraction; 50 Gy; 5 weeks | Primary endpoint: Locoregional recurrence; Survival:; - OS; - Local recurrence; - Distant metastasis; - Disease-free
START Pilot; Trial # NR (Owen, 2006)^13^; SOME CONCERNS UK (2 sites); Marks and Spencer PLC, Cancer Research UK; 10 years | Inclusion: < 75 years old, operable invasive breast cancer (T1-3, N0/1, M0), had breast-preserving surgery and complete macroscopic resection; Exclusion: NR; Other treatments:; - Radiation boost (2 Gy/fraction × 7); - Chemotherapy; - Hormone therapy | Arm 1 (42.9 Gy): N = 466; Arm 2 (39 Gy): N= 474; Demographics and cancer stage by arm NR | Arm 1: 3.3 Gy/fraction 42.9 Gy 5 weeks; Arm 2: 3 Gy/fraction; 39 Gy; 5 weeks | N = 470; Demographics and cancer stage by arm NR | 2 Gy/fraction; 50 Gy; 5 weeks | Primary endpoint: Cosmetic (late change in breast appearance); Survival:; - Local recurrence
Trial Name/# NR; (Spooner, 2012)^20^; SOME CONCERNS UK (3 sites); Cancer Research UK; 15 years (median follow-up 16.9 years) | Inclusion: Women with stage I/II breast cancer, had complete surgical resection, tumor <5 cm, no clinically palpable axillary nodes, no systemic disease; Exclusion: Past cancer, or history of radiation or chemotherapy; Other treatments:; - Chemotherapy; - Tamoxifen (all) | N = 181; Median age (IQR): 59 (48–66) for whole group, NR by arm; Race: NR; Tumor grade: NR (by arm) | 2.66 Gy/fraction; 40 Gy; 3 weeks | N = 177; Median age (IQR): 59 (48–66) for whole group, NR by arm; Race: NR; Tumor grade: NR (by arm) | 2 Gy/fraction; 50 Gy; 5 weeks | Primary endpoint: locoregional recurrence (5 years); Survival:; - OS; - Disease-free
TomoBreast; NCT00459628; (Nan Parijs, 2012^22^; Versmessen, 2012^21^); SOME CONCERNS; Belgium (1 site); Foundation against Cancer; 3 years (median follow-up 28 months) | Inclusion: Women ≥ 18 years old, stage I-II (T1-3N0M0 or T1-2N1M0), had BCS or mastectomy with clear margins and axillary node dissection or sentinel node biopsy, had pre-operative imaging (CT, MRI, and/or PET); Exclusion: Past breast or thoracic radiation, psychiatric or addictive disorder; Other treatments; - Boost radiation; - Chemotherapy; - Hormone therapy | N = 59; ≥ 50 years old: 22 (59); Race: NR; T1: 39 (66); T2: 20 (34); Node status:; N0:; N1:; Tumor grade:; 1: 11 (30); 2: 18 (49); 3: 8 (22); Unknown: 0 | 2 Gy/fraction; 50 Gy; 5 weeks | N = 62; ≥ 50 years old: 22 (69); Race: NR; Tumor size:; T1: 38 (61); T2: 24 (39); Node status:; N0:; N1:; Tumor grade:; 1: 11 (34); 2: 8 (25); 3: 10 (31); Unknown: 3 | 2 Gy/fraction; 50 Gy; 5 weeks | Primary endpoint: Lung and cardiac function changes (3 years); Harms:; Toxicity (acute); - Skin; QoL
Ultra-hypofractionation vs Conventional Radiation
FAST; NCT00107497 (Brunt, 2020^35^; FAST Trialists, 2011^15^); LOW; UK (18 sites); National Health Service, Cancer Research UK/Institute of Cancer; 10 years | Inclusion: Women ≥ 50 years old, had breast conserving surgery, tumor < 3.0 cm, complete microscopic resection of tumor, and negative axillary node status; Exclusion: Mastectomy, lymphatic radiotherapy, tumor bed boost dose and neoadjuvant or adjuvant chemotherapy; Other treatments:; - Hormone therapy | Arm A:; N = 308; Mean age (SD): 62.9 (±7.5); Race: NR; Tumor size:; <1 cm: 84 (30); 1–2 cm: 165 (54); ≥2 cm: 59 (19); Tumor grade:; 1: 113 (37); 2: 159 (52); 3: 35 (11); Unknown: 1 (0.3) | Arm A: 30 Gy/5 fractions over 5 weeks | N = 302; Mean age (SD): 63.1 (±7.2); Race: NR; Tumor size:; <1 cm: 90 (30); 1–2 cm: 166 (55); ≥2 cm: 46 (15); Tumor grade:; 1: 94 (31); 2: 176 (58); 3: 29 (10); Unknown: 3 (1) | 50 gy/25 fractions over 5 weeks | Primary endpoint: Cosmetic (change in breast appearance at 2 years); Survival:; - OS; - Local recurrence; - Regional metastasis; - Distant metastasis; - Breast cancer-specific deaths; Harms:; Toxicity (acute); - Skin
FAST; NCT00107497 (Brunt, 2020^35^; FAST Trialists, 2011^15^); LOW; UK (18 sites); National Health Service, Cancer Research UK/Institute of Cancer; 10 years | | Arm B:; N = 305; Mean age (SD): 62.7 (±6.8); Race: NR; Tumor size:; <1 cm: 87 (29); 1–2 cm: 160 (53); ≥2 cm: 58 (19); Tumor grade:; 1: 102 (33); 2: 168 (55); 3: 34 (11); Unknown: 1 (0.3) | Arm B: 28.5 Gy/5 fractions over 5 weeks | N = 302; Mean age (SD): 63.1 (±7.2); Race: NR; Tumor size:; <1 cm: 90 (30); 1–2 cm: 166 (55); ≥2 cm: 46 (15); Tumor grade:; 1: 94 (31); 2: 176 (58); 3: 29 (10); Unknown: 3 (1) | 50 gy/25 fractions over 5 weeks
Ultra-hypofractionation vs Moderate Hypofractionation
FAST-Forward; ISRCTN19906132 (Brunt, 2020^16^; Brunt, 2016^17^); LOW; UK (97 sites); National Institute for Health Research, Cancer Research UK; 5 years (median follow-up 71.5 months) | Inclusion: ≥ 18 years old with stage pT1-3 pN0-1 M0 breast cancer, had breast conservation surgery or mastectomy, axillary staging and/or dissection, and complete microscopic excision of primary tumor; Exclusion: Contralateral breast cancer, or past cancer (except if non-breast malignancy was treated with curative intent and ≥5 years disease free),breast reconstruction using implants, concurrent chemotherapy, or radiation to any regional lymph node areas (except lower axilla included in tangential fields to breast/chest wall); Other treatments:; - Chemotherapy; - Hormone therapy; - Trastuzumab | Arm A: N = 1367; Median age (IQR): 61 (53, 67); Race: NR; Cancer stage:; Tumor; T1mi: 5 (0.4); T1a: 68 (5.0); T1b: 270 (19.8); T1c: 601 (44.0); T2: 389 (28.5); T3: 30 (2.2); Unknown: 4 (0.3); Node; N0: 1124 (82.2); N1: 243 (17.8); Unknown: 0 | Arm A: 27 Gy/5 fractions over 1 week | N = 1361; Median age (IQR): 60 (53, 66); Race: NR; Cancer stage:; Tumor; T1mi: 4 (0.3); T1a: 69 (5.1); T1b: 258 (19.0); T1c: 612 (45.0); T2: 394 (28.9); T3: 31 (1.5); Unknown: 3 (0.2); Node:; N0: 1103 (81.0); N1: 257 (18.9); Unknown: 1 (0.1) | 40 Gy/15 fractions over 3 weeks | Primary endpoint: Local recurrence; Survival:; - OS; - Locoregional recurrence; - Distant metastases; Harms (some concerns):; Toxicity (acute); - Skin
FAST-Forward; ISRCTN19906132 (Brunt, 2020^16^; Brunt, 2016^17^); LOW; UK (97 sites); National Institute for Health Research, Cancer Research UK; 5 years (median follow-up 71.5 months) | | Arm B: N = 1368; Median age (IQR): 61 (52, 66); Race: NR; Tumor information:; Tumor stage:; T1mi: 6 (0.4); T1a: 51 (3.7); T1b: 256 (18.7); T1c: 602 (44.0); T2: 424 (31.0); T3: 25 (1.8); Unknown: 4 (0.3); Node status:; N0: 1110 (81.1); N1: 256 (18.7); Unknown: 2 (0.1) | Arm B: 26 Gy/5 fractions over 1 week | | 40 Gy/15 fractions over 3 weeks | Primary endpoint: Local recurrence; Survival:; - OS; - Locoregional recurrence; - Distant metastases; Harms (some concerns):; Toxicity (acute); - Skin
YO-HAI5; NCT03677427 (Van Hulle, 2021)^18^; SOME CONCERNS; Belgium (single center); University Hospital, Ghent; 2–4 weeks | Inclusion: Women ≥ 18 years old, treated with BCS and adjuvant whole breast radiation (± boost); Exclusion: Lymph node metastases or distant metastases; bilateral breast irradiation or history of radiation to the same region; life expectancy < 2 years; planned reconstructive surgery; conditions making toxicity evaluation difficult (eg, skin disorders); inability to follow protocol; Other treatments:; - Chemotherapy; - Hormone therapy; - Trastuzumab | N = 106; Median age (range): 59 (37–83); Race: NR; Staging (pTNM):; T1N0M0: 86 (81); T1N1(mi)M0: 4 (4); T2N0M0: 11 (10); TisN0M0: 5 (5) | 5.7 Gy/fraction; 28.5 Gy; 10–12 days | N = 94; Median age (range): 62 (26–84); Race: NR; Staging (pTNM):; T1N0M0: 77 (82); T1N1(mi)M0: 2 (2); T2N0M0: 7 (7); TisN0M0: 8 (9) | 2.67 Gy/fraction; 40.05 Gy; 10–12 days | Primary endpoint: Cosmetic (breast retraction at 2 years); Harms:; Toxicity (acute); - Skin; QoL
APBI vs WBI
APBI-IMRT Florence; NCT02104895; (Meattini, 2015^37^; Livi, 2015^14^; Meattini, 2020^38^); SOME CONCERNS; Italy (1 site); Funding: none; Median follow-up 10.7 years | Inclusion: Women > 40 years old with early cancer (tumor ≤ 2.5 cm) “suitable for BCS”; Exclusion: Past cancer solid Tumor); history cardiovascular disease (eg, heart failure, angina); FEV_1_ <1 L/m; extensive intraductal carcinoma; multiple foci cancer; final surgical margins <5 mm; or absence of surgical clips in tumor bed.; Other treatments:; - Chemotherapy; - Hormone therapy | N = 260; ≥ 60 years: 168 (61); Cancer stage:; Tumor:; pTis: 23 (9); pT1a: 28 (11); pT1b: 98 (38); pT1c: (97 (37); pT2: 14 (5); Node status:; N0: 241 (89); N1: 19 (7); Unknown: 9 (4); Tumor grade:; 1: 124 (48); 2: 110 (38); 3: 26 (10) | APBI-IMRT: 30 Gy/5 fractions over 2 weeks | N = 260; ≥ 60 years: 139 (53); Cancer stage:; Tumor:; pTis: 32 (12); pT1a: 18 (7); pT1b: 88 (34); pT1c: 107 (41); pT2:15 (6); Node status:; N0: 229 (82); N1: 31 (13); Unknown: 14 (5); Tumor grade:; 1: 103 (40); 2: 124 (48); 3: 33 (13) | 50 Gy/25 fractions (+ boost 2 Gy/fraction × 5 fractions) | Primary endpoint: LC; Survival:; - OS; - Locoregional recurrence; - Distant metastasis; - Breast cancer-specific survival; Harms; Toxicity (acute); - Overall; - Skin; Toxicity (late); - Overall; - Skin
RAPID; NCT00282035; (Whelan, 2019^31^; Olivotto, 2013^122^); SOME CONCERNS; 3 countries (33 sites); Canadian Institutes for Health Research, Canadian Breast Cancer Research Alliance; Median follow-up 8.6 years | Inclusion: Women ≥ 40 years old with DCIS or invasive ductal carcinoma who had BCS with microscopically clear margins, and negative axillary nodes (by sentinel node biopsy or axillary dissection for invasive cancer, or clinical exam for DCIS); Exclusion: Tumor > 3 cm, lobular carcinoma, >1 primary breast tumor; Other treatments:; - Chemotherapy; - Hormone therapy | N = 1070; ≥ 50 years old: 939 (88); Race: NR; DCIS: 191 (18) Invasive cancer: 879 (82); Staging (invasive cancer):; Tumor size:; <1.5cm: 613 (70); ≥1.5cm: 266 (30); Node status:; pN0: 874 (99); pNi+,pNMi: 5 (<1); Tumor grade:; 1: 387 (44); 2: 353 (40); 3: 133 (15); Unknown: 6 (1) | APBI: 3.85 Gy/fraction 38.5 Gy 5–8 days; (87% 3DCRT, 10% IMRT) | N = 1065; ≥ 50 years old: 939 (88); Race: NR; DCIS: 190 (18) Invasive cancer: 875 (82); Staging (invasive cancer):; Tumor size:; <1.5cm: 587 (67); ≥1.5cm: 288 (33); Node status:; pN0: 865 (99); pNi+,pNMi: 10 (1); Tumor grade:; 1: 362 (41); 2: 361 (41); 3: 143 (16); Unknown: 9 (1) | WBI: 82% received: 2.65 Gy/fraction 42.5 Gy; 18% received: 2 Gy/fraction 50Gy; 4–5 weeks; (+boost in 21%, 10 Gy in 4–5 fractions) | Primary endpoint: local recurrence; Survival:; - OS; - Disease-free; Harms:; Toxicity (acute); - Overall; - Skin; - Pneumonitis; Toxicity (late); - Overall

Notes.

* Unable to extract.

Abbreviations. 3DCRT=three-dimensional conformal radiation therapy; APBI=accelerated partial breast irradiation; BCS=breast-conserving surgery; CT=computed tomography; DCIS=ductal carcinoma in situ; IMRT=intensity-modulated radiation therapy; MRI=magnetic resonance imaging; NR=not reported; OS=overall survival; PET=positron emission tomography; QoL=quality of life; SD=standard deviation; TNM=TNM Classification of Malignant Tumors; UK=United Kingdom; US=United States; WBI=whole-breast irradiation.

Appendix Table 3 Detailed Results for Survival Outcomes for Breast Cancer Trials Rated “Low” or “Some Concerns” Risk of Bias

Outcome | Trial Name, Year Trial # Risk of Bias | Effect Measure/Definition | Hypofractionation Arm N Events/Total N (%) | Comparison Arm N Events/Total N (%) | Results
Breast-cancer-specific deaths | Ultra-hypofractionation vs Conventional Radiation
Breast-cancer-specific deaths | FAST NCT00107497; (FAST Trialists, 2011)^15^; Low | 10 years | Arm A (30 Gy): 2/305 (1); Arm B (28.5 Gy): 6/302 (2) | 2/301 (1) | Comparison NR
Breast-cancer-specific deaths | APBI vs WBI
Breast-cancer-specific deaths | APBI-IMRT Florence NCT02104895; (Meattini, 2020)^38^; Some concerns | 10 years | 5 years: 2/260 (1); 7 years: 3/260 (1); 10 years: 5/260 (2) | 5 years: 3/260 (1); 7 years: 6/260 (2); 10 years: 8/260 (3) | HR (95% CI): 0.65 (0.21, 1.99), P = 0.45
Overall survival | Hypofractionation vs Conventional Radiation
Overall survival | DBCG HYPO; NCT00909818; (Offersen, 2020)^29^; LOW | 9-year survival | 93% (deaths: 60/917) | 93% (deaths: 61/937) | HR (95% CI): 0.98 (0.65, 1.47); RD (95% CI): 0.0% (−2.9%, 2.8%); P = 0.93
Overall survival | NCT00156052; (Whelan, 2002^26^, 2010^25^); LOW | 10 years | 84.6% (deaths: 122/622) | 84.4% (deaths: 126/612) | RD (95% CI): −0.2% (−4.3%, 4.0%), P = 0.79
Overall survival | NCT00156052; (Whelan, 2002^26^, 2010^25^); LOW | 5 years (median follow-up 69 months) | 92.3% (deaths: 48/622) | 91.7% (deaths: 51/612) | P = 0.78
Overall survival | NCT00793962; (Wang, 2019)^28^; LOW | Deaths all-cause, median follow-up 59.5 months | 84% (deaths: 63/401) | 86% (deaths: 56/409) | HR (95% CI): 1.13 (0.78, 1.62); Log-rank P = 0.53
Overall survival | NCT01413269; (Wang, 2020)^27^; LOW | Death from any cause at 5 years (median follow-up 73.5 months) | 97.5% (deaths: 11/365) | 98% (deaths: 9/364) | HR (95% CI): 1.20 (90.50, 2.80); Log-rank P = 0.680
Overall survival | START A; (START Trialists, 2008^11^; Haviland, 2013^33^); LOW | Median follow-up 5.1 and 9.3 years | Arm A (41.6 Gy):; 5 years: 88% (deaths: 89/750); 9 years: 83% (deaths: 128/750); Arm B (39 Gy):; 5 years: 89% (deaths: 83/737); 9 years: 82% (deaths: 134/737) | 5 years: 89% (deaths: 84/749); 9 years: 83% (deaths: 130/749) | HR (95% CI):; Arm A (41.6 Gy): 1.04 (0.77, 1.40), P = 0.81; Arm B (39 Gy): 1.00 (0.74, 1.36), P = 0.99
Overall survival | START B; ISRCTN59368779; (START Trialists, 2008^12^; Haviland, 2013^33^); LOW | Median follow-up 6 and 9.9 years | 6 years: 90% (deaths: 107/1110); 10 years: 86% (deaths: 159/1110) | 6 years: 88% (deaths: 138/1105); 10 years: 83% (deaths: 192/1105) | HR (95% CI): 0.80 (0.65, 0.99), P = 0.04
Overall survival | Trial Name/# NR; (Spooner, 2012)^20^; SOME CONCERNS | Deaths at 2, 5, 10, 15 years | 2 years: 94% years (deaths: 11/181); 5 years: 85% (deaths: 27/181); 10 years: 70% (deaths: 54/181); 15 years: 53% (deaths: 85/181) | 2 years: 92% (deaths: 7/177); 5 years: 81% (deaths: 34/177); 10 years: 67% (deaths: 58/177); 15 years: 52% (deaths: 85/177) | HR (95% CI): 1.02 (0.76, 1.35)
Overall survival | Ultra-hypofractionation vs Conventional Radiation
Overall survival | FAST; NCT00107497; (FAST Trialists, 2011)^15^; LOW | Median follow-up at 3.1 years | Arm A (30 Gy): 98% (deaths 5/305); Arm B (28.5 Gy): 96% (deaths 12/302) | 98% (deaths: 6/301) | Comparison NR
Overall survival | Ultra-hypofractionation vs Moderate Hypofractionation
Overall survival | FAST-Forward; ISRCTN19906132; (Brunt, 2020)^16^; LOW | Deaths any cause, 5 years (median follow-up 71.5 months) | Arm A (27 Gy): 92% (deaths: 105/1367); Arm B (26 Gy): 93% (deaths: 90/1368) | 93% (deaths: 92/1361) | HR (95% CI):; Arm A (27 Gy): 1.12 (0.85, 1.48), P = 0.42; Arm B (26 Gy): 0.96 (0.72, 1.28), P = 0.78
Overall survival | APBI vs WBI
Overall survival | APBI-IMRT Florence; NCT02104895; (Meattini, 2020)^38^; SOME CONCERNS | All cause deaths, 10 years | 5 years: 98% (deaths: 5/260); 7 years: 97% (deaths: 9/260); 10 years: 92% (deaths: 18/260) | 5 years: 97% (deaths: 8/260); 7 years: 94% (deaths: 15/260); 10 years: 92% (deaths: 20/260 | HR (95% CI): 0.95 (0.50, 1.79), P = 0.86
Overall survival | RAPID; NCT00282035; (Whelan, 2019)^31^; SOME CONCERNS | Median follow-up 8.6 years | 93% (deaths: 76/1070) | 94% (deaths: 64/1065) | HR (95% CI): 1.18 (0.84, 1.64)
Disease-free survival | Hypofractionation vs Conventional Radiation
Disease-free survival | NCT00156052; (Whelan, 2002)^26^; LOW | Free from events (local, regional, and distant recurrence; deaths) within 5 years (median follow-up 69 months) | 85.4% (events: 91/622) | 87.1% (events: 79/612) | P = 0.37
Disease-free survival | NCT00793962; (Wang, 2019)^28^; LOW | Free from locoregional recurrence, distant metastasis, or death, median follow-up 59.5 months | 76% (events: 96/401) | 73% (events: 109/401) | HR (95% CI): 0.88 (0.67, 1.16); Log-rank P = 0.43
Disease-free survival | NCT01413269; (Wang, 2020)^27^; LOW | 5-year survival from events (local or locoregional recurrence, distant metastasis, or death due to any cause) | 93% (events: 32/365) | 94% (events: 26/364) | HR (95% CI): 1.24 (0.74, 2.07); Log-rank P = 0.421
Disease-free survival | START A; ISRCTN59368779; (START Trialists, 2008^11^; Haviland, 2013^33^); LOW | Survival from any breast cancer-related event including local, regional, or distant relapse, breast cancer death, or contralateral breast cancer, median follow-up 5.1 and 9.3 years | Arm A (41.6 Gy):; 5 years: 88% (events: 91/750); 9 years: 80% (events: 149/750); Arm B (39 Gy):; 5 years: 84% (events: 115/737); 9 years: 78% (events: 163/737) | 5 years: 86% (events: 102/749); 9 years: 79% (events: 154/749); 102/749 (13.6%) | HR (95% CI): Arm A (41.6 Gy): 0.94 (0.75, 1.17), P = 0.57; Arm B (39 Gy): 1.08 (0.87, 1.35), P = 0.48
Disease-free survival | START B; ISRCTN59368779; (START Trialists, 2008^12^; Haviland, 2013^33^); LOW | Survival from any breast cancer-related event including local, regional, or distant relapse, breast cancer death, or contralateral breast cancer, median follow-up 6.0 and 9.9 years | 6 years: 89% (events: 127/1110); 10 years: 84% (events: 182/1110) | 6 years: 85% (events: 164/1105); 10 years: 80% (events: 222/1105) | HR (95% CI): 0.79 (0.65, 0.97), P = 0.02
Disease-free survival | Trial Name/# NR; (Spooner, 2012)^20^; SOME CONCERNS | Any recurrence or death at 2, 5, 10, 15 years | 2 years: 89% (events: 20/181); 5 years: 81% (events: 34/181); 10 years: 61% (events: 67/181); 15 years: 46% (events: 98/181) | 2 years: 86% (events: 25/177); 5 years: 73% (events: 48/177); 10 years: 59% (events: 73/177); 15 years: 44% (events: 99/177) | HR (95% CI): 0.98 (0.75, 1.29)
Local recurrence | Hypofractionation vs Conventional Radiation
Local recurrence | NCT00156052; (Whelan, 2002^26^; Whelan, 2010^25^); LOW | Recurrent tumor within the treated breast within 5 years (median follow-up 69 months) | 21/622 (2.8) | 23/612 (3.2) | RD (95% CI): 0.4% (−1.5%, 2.4%); P-value NR
Local recurrence | NCT00156052; (Whelan, 2002^26^; Whelan, 2010^25^); LOW | Recurrent tumor within the treated breast within 10 years | 41/622 (6.2) | 42/612 (6.7) | RD (95% CI): 0.5% (−2.5%, 3.5%); Noninferiority test P <; 0.001
Local recurrence | NCT01413269; (Wang, 2020)^27^; LOW | 5-year relapse in breast or chest wall | 1% (events: 5/365) | 2% (events: 8/364) | HR (90% CI): 1.63 (0.64, 4.15); Noninferiority test P = 0.017
Local recurrence | START A; ISRCTN59368779; (START Trialists, 2008^11^; Haviland, 2013^33^); LOW | Recurrence in breast or chest wall, median follow-up 5.1 and 9.3 years | Arm A (41.6 Gy):; 5 years: 28/750 (4); 9 years: 37/750 (5); Arm B (39 Gy):; 5 years: 31/737 (4); 9 years: 47/737 (6) | 5 years: 25/749 (3); 9 years: 40/749 (5) | HR (95% CI):; Arm A (41.6 Gy): 0.90 (0.57, 1.40), P = 0.63; Arm B (39 Gy): 1.20 (0.79, 1.83), P = 0.39
Local recurrence | START B; ISRCTN59368779; (START Trialists, 2008^12^; Haviland, 2013^33^); LOW | Recurrence in breast or chest wall, median follow-up 6.0 and 9.9 years | 6 years: 25/1110 (2); 10 years: 36/1110 (3) | 6 years: 34/1105 (3); 10 years: 50/1105 (5) | HR (95% CI): 0.70 (0.46, 1.07), P = 0.10
Local recurrence | START Pilot; Trial # NR (Owen, 2006)^13^; SOME CONCERNS | 10-year recurrence (ipsilateral breast or overlying skin) | 42.9 Gy: 42/466 (9); 39 Gy: 66/474 (14) | 50/470 (11) | HR (95% CI): 42.9 Gy: 0.86 (0.57, 1.30); 39 Gy: 1.33 (0.91, 1.92)
Local recurrence | Ultra-hypofractionation vs Conventional Radiation
Local recurrence | FAST; NCT00107497; (Brunt, 2020^35^; FAST Trialists, 2011^15^); LOW | Recurrence in ipsilateral breast and/or overlying skin, median follow-up at 3.1 and 9.9 years | Arm A (30 Gy):; 3.1 years: 0/305 (0); 9.9 years: 4/305 (1); Arm B (28.5 Gy):; 3.1 years: 0/302 (0); 9.9 years: 4/302 (1) | 3.1 years: 2/301 (1); 9.9 years: 3/301 (1) | HR (95% CI):; Arm A (30 Gy):; 1.36 (0.30, 6.06); Arm B (28.5 Gy):; 1.35 (0.30, 6.05)
Local recurrence | Ultra-hypofractionation vs Moderate Hypofractionation
Local recurrence | FAST-Forward; ISRCTN19906132; (Brunt, 2020)^16^; LOW | Recurrence in ipsilateral breast, chest wall or skin, 5 years (median follow-up 71.5 months) | Arm A (27 Gy): 27/1367 (2); Arm B (26 Gy): 21/1368 (1) | 31/1361 (2) | HR (95% CI):; Arm A (27 Gy): 0.86 (0.51, 1.44), P = 0.56; Arm B (26 Gy): 0.67 (0.38, 1.16), P = 0.15
Local recurrence | APBI vs WBI
Local recurrence | APBI-IMRT Florence; NCT02104895; (Meattini, 2020)^38^; SOME CONCERNS | Recurrence in ipsilateral breast, 10 years | 5 years: 6/260 (2); 7 years: 7/260 (3); 10 years: 9/260 (4) | 5 years: 3/260 (1); 7 years: 5/260 (2); 10 years: 6/260 (2) | HR (95% CI): 1.56 (0.55, 4.37), P = 0.40
Local recurrence | RAPID; NCT00282035; (Whelan, 2019)^31^; SOME CONCERNS | Recurrence in ipsilateral breast, median follow-up 8.6 years | 37/1070 (4) | 28/1065 (3) | HR (90% CI): 1.27 (0.84, 1.91)
Locoregional recurrence | Hypofractionation vs Conventional Radiation
Locoregional recurrence | DBCG HYPO; NCT00909818; (Offersen, 2020)^29^; LOW | 9-year recurrence (ipsilateral recurrence in the breast tissue and overlying skin, in ipsilateral axilla, fossa supraclavicularis, or in the internal mammary chain lymph nodes) | 14/794 (2) | 19/814 (2) | HR (95% CI): 0.90 (0.51, 1.59) RD (95% CI ): −0.3% (−2.3%, 1.7%) P-value NR
Locoregional recurrence | NCT00793962; (Wang, 2019)^28^; LOW | Recurrence in ipsilateral chest wall or regional lymph nodes, median follow-up 59.5 months | 31/401 (8) | 29/401 (9) | HR (90% CI): 1.10 (0.72, 1.69); Non-inferiority P < 0.0001
Locoregional recurrence | NCT01413269; (Wang, 2020)^27^; LOW | 5-year disease recurrence in the ipsilateral breast and/or regional lymph nodes | 3% (events: 14/365) | 4% (events: 12/364) | HR (95% CI): 0.87 (0.46, 1.66); Log-rank P = 0.758
Locoregional recurrence | START A; ISRCTN59368779; (START Trialists, 2008^11^; Haviland, 2013^33^); LOW | Local or ipsilateral axilla, or supraclavicular fossa, median follow-up 5.1 and 9.3 years | Arm A (41.6 Gy):; 5 years: 30/750 (4); 9 years: 42/750 (6); Arm B (39 Gy):; 5 years: 35/737 (5); 9 years: 52/737 (7) | 5 years: 28/749 (4); 9 years: 45/749 (6) | HR (95% CI):; Arm A (41.6 Gy): 0.91 (0.59, 1.38), P = 0.65; Arm B (39 Gy): 1.18 (0.79, 1.76), P = 0.41
Locoregional recurrence | START B; ISRCTN59368779; (START Trialists, 2008^12^; Haviland, 2013^33^); LOW | Local or ipsilateral axilla, or supraclavicular fossa, median follow-up 6.0 and 9.9 years | 6 years: 29/1110 (3); 10 years: 42/1110 (4) | 6 years: 36/1105 (3); 10 years: 53/1105 (5) | HR (95% CI): 0.77 (0.51, 1.16), P = 0.21
Locoregional recurrence | Trial Name/# NR; (Spooner, 2012)^20^; SOME CONCERNS | 5-year recurrence | 25/181 (43) | 21/177 (40) | HR NR (“no significant differences”)
Locoregional recurrence | Ultra-hypofractionation vs Moderate Hypofractionation
Locoregional recurrence | FAST-Forward; ISRCTN19906132; (Brunt, 2020)^16^; LOW | Local or regional (axilla, supraclavicular fossa, and internal mammary chain), 5 years (median follow-up 71.5 months) | Arm A (27 Gy): 35/1367 (3); Arm B (26 Gy): 29/1368 (2) | 43/1361 (3) | HR (95% CI): Arm A (27 Gy): 0.80 (0.51, 1.25), P = 0.33; Arm B (26 Gy): 0.66 (0.41, 1.06), P = 0.08
Locoregional recurrence | APBI vs WBI
Locoregional recurrence | APBI-IMRT Florence; NCT02104895; (Meattini, 2020)^38^; SOME CONCERNS | Includes recurrence in ipsilateral axillary, supraclavicular or internal mammary nodes, 10 years | 5 years: 6/260 (2); 7 years: 7/260 (3); 10 years: 9/260 (4) | 5 years: 4/260 (2); 7 years: 6/260 (2); 10 years: 7/260 (3) | HR (95% CI): 1.33 (0.49, 3.56), P = 0.58
Regional metastasis | Ultra-hypofractionation vs Conventional Radiation
Regional metastasis | FAST; NCT00107497; (FAST Trialists, 2011)^15^; LOW | Spread to axilla, supraclavicular fossa, and/or internal mammary chain, median follow-up at 3.1 years | Arm A (30 Gy): 0/305 (0); Arm B (28.5 Gy): 2/302 (1) | 1/301 (0.3) | Comparison NR
Distant metastasis | Hypofractionation vs Conventional Radiation
Distant metastasis | START A; ISRCTN59368779; (START Trialists, 2008^11^; Haviland, 2013^33^); LOW | Relapse in non-irradiated organs, median follow-up 5.1 and 9.3 years | Arm A (41.6 Gy):; 5 years: 69/750 (9); 9 years: 110/750 (15); Arm B (39 Gy):; 5 years: 93/737 (13); 9 years: 121/737 (16) | 5 years: 73/749 (10); 9 years: 100/749 (13) | HR (95% CI):; Arm A (41.6 Gy): 1.08 (0.82, 1.41), P = 0.58; Arm B (39 Gy): 1.24 (0.95, 1.61), P = 0.11
Distant metastasis | START B; ISRCTN59368779; (START Trialists, 2008^12^; Haviland, 2013^33^); LOW | Relapse in non-irradiated organs, median follow-up 6.0 and 9.9 years | 6 years: 87/1110 (8); 10 years: 121/1110 (11) | 6 years: 122/1105 (11); 10 years: 158/1105 (20) | HR (95% CI): 0.74 (0.59, 0.94), P = 0.01
Distant metastasis | Ultra-hypofractionation vs Conventional Radiation
Distant metastasis | FAST; NCT00107497; (FAST Trialists, 2011)^15^; LOW | | Arm A (30 Gy): 2/305 (1); Arm B (28.5 Gy): 10/302 (3) | 5/301 (2) | Comparison NR
Distant metastasis | Ultra-hypofractionation vs Moderate Hypofractionation
Distant metastasis | FAST-Forward; ISRCTN19906132; (Brunt, 2020)^16^; LOW | 5 years (median follow-up 71.5 months) | Arm A (27 Gy): 69/1367 (5); Arm B (26 Gy): 76/1368 (6) | 59/1361 (4) | HR (95% CI):; Arm A (27 Gy): 1.16 (0.82, 1.64), P = 0.41; Arm B (26 Gy): 1.27 (0.90, 1.79), P = 0.17
Distant metastasis | APBI vs WBI
Distant metastasis | APBI-IMRT Florence; NCT02104895; (Meattini, 2020)^38^; SOME CONCERNS | Includes recurrence to distant organs (visceral and bone sites), 10 years | 5 years: 4/260 (2); 7 years: 6/260 (2); 10 years: 7/260 (3) | 5 years: 8/260 (3); 7 years: 15/260 (6); 10 years: 20/260 (8) | HR (95% CI): 0.89 (0.32, 2.47), P = 0.83

Appendix Table 4 Detailed Results for Toxicity Outcomes for Breast Cancer Trials Rated “Low” or “Some Concerns” Risk of Bias

Outcome | Trial Name, Year Trial # Risk of Bias | Effect Measure/Definition | Hypofractionation Arm N Events/Total N (%) | Comparison Arm N Events/Total N (%) | Results
Harms
Acute toxicity, overall | Hypofractionation vs Conventional Radiation
Acute toxicity, overall | NCT01266642; (Shaitelman, 2015)^23^; SOME CONCERNS | CTCAE v4.0, grade ≥ 2; < 3 months | 65/138 (47) | 116/149 (78) | P < 0.001
Acute toxicity, overall | APBI vs WBI
Acute toxicity, overall | APBI-IMRT Florence; NCT02104895; (Meattini, 2020)^38^; SOME CONCERNS | RTOG, grade ≥ 2 ≤ 6 months | 5/246 (2.0) | 98/260 (38) | P = 0.0001
Acute toxicity, overall | RAPID; NCT00282035; (Whelan, 2019)^31^; SOME CONCERNS | CTCAE v3, grade 2–3 ≤ 3 months | Grade 2: 281/1070 (26); Grade 3: 19/1070 (2) | Grade 2: 466/1065 (44); Grade 3: 18/1065 (2) | Grade ≥ 2: P < 0.0001
Acute pneumonitis | Hypofractionation vs Conventional Radiation
Acute pneumonitis | NCT00793962; (Wang, 2019)^28^; LOW | CTCAE 3.0, grade 1–3 | Grade 1: 61/401 (15); Grade 2:14/401 (3); Grade 3: 0/401 (0) | Grade 1: 62/409 (15); Grade 2: 7/409 (2); Grade 3: 0/409 (0) | P = 0.28
Acute pneumonitis | NCT01413269; (Wang, 2020)^27^; LOW | CTCAE 3.0, grade 2 < 3 months | 7/365 (2) | 11/363 (3) | P = 0.22
Acute pneumonitis | APBI vs WBI
Acute pneumonitis | RAPID; NCT00282035; (Whelan, 2019)^31^; SOME CONCERNS | CTCAE v3, grade 2–3 ≤ 3 months | Grade 2: 2/1070 (< 0.1); Grade 3: 0/1070 (0) | Grade 2: 7/1065 (0.7); Grade 3: 1/1065 (< 0.1) | Comparison NR
Acute skin toxicity | Hypofractionation vs Conventional Radiation
Acute skin toxicity | DRKS00017763; (Schmeel, 2020)^19^; SOME CONCERNS | CTCAE v4.03, grade ≥ 2 | 19/70 (27) | 30/70 (43%) | OR (95% CI): 2.01 (0.99, 4.09); P = 0.05
Acute skin toxicity | NCT01266642; (Shaitelman, 2015)^23^; SOME CONCERNS | CTCAE v4.0, grade ≥ 2; < 3 months | 50/138 (36) | 103/149 (69) | P < 0.001
Acute skin toxicity | NCT00156052; (Arsenault, 2020)^32^; SOME CONCERNS | ECOG, grade 2–3 At 4–6 weeks | 9/73 (12) | 28/73 (38) | P-value NR
Acute skin toxicity | NCT01413269; (Wang, 2020)^27^; LOW | CTCAE v3.0, grade 2–3; < 3 months | 11/365 (3) | 27/363 (0.7) | P = 0.02
Acute skin toxicity | TomoBreast; NCT00459628; (Nan Parijs, 2012)^22^; SOME CONCERNS | RTOG, grade 2–3 Within 4 weeks | Grade 2: 10/37 (27); Grade 3: 3/37 (8) | Grade 2: 7/32 (22); Grade 3: 2/32 (6) | Comparison NR
Acute skin toxicity | Ultra-hypofractionation vs Conventional Radiation
Acute skin toxicity | FAST; NCT00107497; (FAST Trialists, 2011)^15^; LOW | RTOG, grade 2–4 | Arm A (30 Gy):; 2: 13/111 (12); 3: 3/111 (3); 4: 0/111 (0); Arm B (28.5 Gy):; 2: 9/106 (9); 3: 2/106 (2); 4: 0/106 (0) | 2: 39/110 (36); 3: 12/110 (11); 4: 0/110 (0) | Comparison NR
Acute skin toxicity | Ultra-hypofractionation vs Moderate Hypofractionation
Acute skin toxicity | FAST-Forward; ISRCTN19906132; (Brunt, 2016)^17^; LOW | RTOG, grade 2–3 (substudy 1); Within 4 weeks | Arm A (27 Gy):; Grade 2: 20/51 (39); Grade 3: 5/51 (10); Arm B (26 Gy):; Grade 2: 14/52 (27); Grade 3: 3/52 (6) | Grade 2: 24/55 (55); Grade 3: 6/55 (14) | P-value NR
Acute skin toxicity | FAST-Forward; ISRCTN19906132; (Brunt, 2016)^17^; LOW | CTCAE v4.03, grade 2–3 (substudy 2) Within 4 weeks | Arm A (27 Gy):; Grade 2: 11/41 (27); Grade 3: 1/41 (2); Arm B (26 Gy):; Grade 2: 19/53 (36); Grade 3: 0/53 (0) | Grade 2: 22/43 (51); Grade 3: 0/43 (0) | P-value NR
Acute skin toxicity | YO-HAI5; NCT03677427; (Van Hulle, 2021)^18^; SOME CONCERNS | CTCAE v4.03, grade 2; 16.7 days ± 6.0 days post | 17/105 (16) | 11/94 (20) | P-value NR
Acute skin toxicity | APBI vs WBI
Acute skin toxicity | APBI-IMRT Florence; NCT02104895; (Livi, 2015)^14^; SOME CONCERNS | RTOG, grade ≥ 2 ≤ 6 months | 5/246 (2) | 98/260 (38) | P = 0.0001
Acute skin toxicity | RAPID; NCT00282035; (Whelan, 2019)^31^; SOME CONCERNS | CTCAE v3, grade 2–3 ≤ 3 months | Grade 2: 101/1070 (9); Grade 3: 1/1070 (<0.1) | Grade 2: 322/1065 (30); Grade 3: 6/1065 (0.6) | Comparison NR
Acute skin toxicity | Hypofractionation vs Conventional Radiation
Acute skin toxicity | NCT00793962; (Wang, 2019)^28^; LOW | CTCAE 3.0, grade 1–3 | rade 1–2: 351/401 (89); Grade 3: 14/401 (3) | Grade 1–2: 357/401 (87); Grade 3: 32/401 (8) | P < 0.0001
Acute skin ulceration | Hypofractionation vs Conventional Radiation
Acute skin ulceration | NCT01266642; (Shaitelman, 2015)^23^; SOME CONCERNS | CTCAE v4.0, grade ≥ 2; < 3 months | 1/138 (1) | 2/149 (1) | P = 0.19
Late toxicity, overall | Hypofractionation vs Conventional Radiation
Late toxicity, overall | NCT01266642; (Shaitelman, 2015)^23^; SOME CONCERNS | CTCAE v4.0, grade ≥ 2; 6 months | 40/129 (31) | 46/142 (32) | P = 0.81
Late toxicity, overall | APBI vs WBI
Late toxicity, overall | APBI-IMRT Florence; NCT02104895; (Meattini, 2020)^38^; SOME CONCERNS | RTOG, grade ≥ 2; > 6 months to 10 years | 0/246 (0%) | 7/260 (3) | P = 0.02
Late toxicity, overall | RAPID; NCT00282035; (Whelan, 2019^31^; Olivotto, 2013^122^); SOME CONCERNS | CTCAE v3, grade 2–3 > 3 months through 3 and 8.6 years | 3 years:; Grade 2: 2/1070 (< 0.1); Grade 3: 0/1070 (0); 8.6 years:; Grade 2: 298/1070 (28); Grade 3: 48/1070 (5) | 3 years:; Grade 2: 2/1070 (< 0.1); Grade 3: 0/1070 (0); 8.6 years:; Grade 2: 131/1065 (12); Grade 3: 11/1065 (1) | Grade ≥ 2:; 8.6 years: P < 0.0001
Late dermatitis | Hypofractionation vs Conventional Radiation
Late dermatitis | NCT01266642; (Shaitelman, 2015)^23^; SOME CONCERNS | CTCAE v4.0, grade ≥ 2; 6 months | 0/138 | 1/142 (1) | P = 0.73
Late lymphedema | Hypofractionation vs Conventional Radiation
Late lymphedema | NCT00793962; (Wang, 2019)^28^; LOW | RTOG, grade 1–3 | Grade 1–2: 78/401 (19); Grade 3: 3/401 (1) | Grade 1–2: 81/409 (20); Grade 3: 3/409 (1) | P = 0.96
Late lymphedema | NCT01266642; (Shaitelman, 2015)^23^; SOME CONCERNS | CTCAE v4.0, grade ≥ 2; 6 months | 2/129 (2) | 7/142 (5) | P = 0.78
Late lymphedema | NCT01413269; (Wang, 2020)^27^; LOW | RTOG, grade 2 >6 months | 2/365 (0.5) | 2/363 (0.6) | P = 0.74
Late lung fibrosis | Hypofractionation vs Conventional Radiation
Late lung fibrosis | NCT01413269; (Wang, 2020)^27^; LOW | RTOG, grade 2 > 6 months | 0/365 (0) | 1/363 (0.3) | P = 0.51
Late pneumonitis | Hypofractionation vs Conventional Radiation
Late pneumonitis | NCT01266642; (Shaitelman, 2015)^23^; SOME CONCERNS | CTCAE v4.0, grade ≥2; 6 months | 0/129 (0) | 0/142 (0) | NA
Late skin toxicity | Hypofractionation vs Conventional Radiation
Late skin toxicity | NCT00156052; (Whelan, 2010)^25^; SOME CONCERNS | RTOG, grade 2 and 3 Over 5 years | 14/449 (3) | 14/424 (3) | P-value NR
Late skin toxicity | NCT00156052; (Whelan, 2010)^25^; SOME CONCERNS | RTOG, grade 2 and 3 Over 10 years | 21/235 (9) | 17/220 (8) | P-value NR
Late skin toxicity | NCT00793962; (Wang, 2019)^28^; LOW | RTOG, grade 1–3; Median follow-up 58 months | Grade 1–2: 86/401 (21); Grade 3: 1/401 (<1) | Grade 1–2: 90/409 (22); Grade 3: 0/409 (0) | P = 0.67
Late skin toxicity | APBI vs WBI
Late skin toxicity | APBI-IMRT Florence; NCT02104895; (Livi, 2015)^14^; SOME CONCERNS | RTOG, grade ≥ 2 > 6 months to 5 years | 0/246 (0) | 2/260 (1) | P = 0.26
Late skin ulceration | Hypofractionation vs Conventional Radiation
Late skin ulceration | NCT01266642; (Shaitelman, 2015)^23^; SOME CONCERNS | CTCAE v4.0, grade ≥2; 6 months | 0/129 (0) | 0/142 (0) | NA

Appendix Table 5 Detailed Results for Quality of Life Outcomes for Breast Cancer Trials Rated “Low” or “Some Concerns” Risk of Bias

Outcome | Trial Name, Year Trial # Risk of Bias | Effect Measure/Definition | Hypofractionation Arm N Events/Total N (%) | Comparison Arm N Events/Total N (%) | Results
Overall QoL | Hypofractionation vs Conventional Radiation
Overall QoL | BIG3-07/TROG 07.01; NCT00470236; (King, 2020)^30^; SOME CONCERNS | EORTC QLQ-C30, overall score at 6 months, 1 year, and 2 years | Mean (SD):; 6 months: 77.8 (18.2); 1 year: 79.2 (18.2); 2 years:78.9 (19.1) | Mean (SD):; 6 months: 78.1 (18.2); 1 year: 78.0 (18.0); 2 years: 78.7 (18.9) | Comparison NR
Overall QoL | NCT01266642; (Shaitelman, 2015^23^; Shaitelman, 2018^120^); SOME CONCERNS | FACT-G and FACT-B v4, total mean scores at baseline, 6 months; FACT-B TOI v4, mean scores at baseline, 3 years | FACT-G:; Baseline: 92.8; 6 months: 91.6; FACT-B:; Baseline: 120.1; 6 months: 124.5; FACT-B TOI:; Baseline: 74.5; 3 years: 77.9 | FACT-G:; Baseline: 91.6; 6 months: 93.6; FACT-B:; Baseline: 118.8; 6 months: 122.3; FACT-B TOI:; Baseline: 74.0; 3 years: 77.6 | FACT-G:; Baseline: P = 0.35; 6 months: P = 0.12; FACT-B:; Baseline: P = 0.46; 6 months: P = 0.20; FACT-B TOI:; Baseline: P = 0.72; 3 years: P = 0.20
Global health status (QL) | Hypofractionation vs Conventional Radiation
Global health status (QL) | TomoBreast; NCT00459628; (Versmessen, 2012)^21^; SOME CONCERNS | EORTC QLQ-C30, mean (SD) at baseline, end of radiation, 3 months, annually years 1–3 | Baseline: 67.2 (17.5); End of therapy: 59.0 (2.9); 3 months: 65.8 (3.1); 1 year: 72.6 (3.1); 2 years: 76.2 (3.8); 3 years: 78.5 (5.3) | Baseline: 69.0 (21.7); End of therapy: 67.0 (2.2); 3 months: 68.5 (2.2); 1 year: 72.3 (2.5); 2 years: 72.3 (3.2); 3 years: 74.4 (4.1) | Significant difference only at end of radiation (P = 0.029), otherwise NS (P-value NR)
Global health status (QL) | Ultra-hypofractionation vs Moderate Hypofractionation
Global health status (QL) | YO-HAI5; NCT03677427; (Van Hulle, 2021)^18^; SOME CONCERNS | EORTC QLQ-C30/BR23, ≥ 10 pts decrease (from baseline); 16.7 days ±6.0 days post | Global score: 16/105 (15); Physical functioning: 7/105 (7); Social functioning: 12/105 (11) | Global score: 30/94 (32); Physical functioning: 23/94 (24); Social functioning 29/94 (31) | P = 0.005; P = 0.0005; P =0.0007
Physical functioning | Hypofractionation vs Conventional Radiation
Physical functioning | TomoBreast; NCT00459628; (Versmessen, 2012)^21^; SOME CONCERNS | EORTC-QLQ C30, mean (SD) at baseline, end of radiation, 3 months, annually years 1–3 | Baseline: 83.2 (16.0); End of therapy: 79.4 (2.0); 3 months: 82.0 (2.2); 1 year: 83.6 (2.0); 2 years: 88.7 (1.9); 3 years: 89.9 (3.2) | Baseline: 84.1 (18.7); End of therapy: 80.1 (1.6); 3 months: 80.7 (1.7); 1 year: 85.4 (2.0); 2 years: 84.1 (3.5); 3 years: 84.9 (3.3) | Differences NS (P-value NR)
Role functioning | | | Baseline: 66.4 (29.3); End of therapy: 65.0 (4.2); 3 months: 75.8 (4.3); 1 year: 84.7 (4.5); 2 years: 94.1 (5.4); 3 years: 97.5 (8.7) | Baseline: 70.2 (27.4); End of therapy: 66.9 (3.5); 3 months: 81.9 (4.6); 1 year: 79.9 (3.6); 2 years: 81.1 (4.3); 3 years: 80.3 (3.2) | Differences NS (P-value NR)
Emotional functioning | | | Baseline: 74.4 (20.0); End of therapy: 75.4 (2.6); 3 months: 78.5 (2.7); 1 year: 77.3 (2.8); 2 years: 80.7 (4.1); 3 years: 81.3 (4.5) | Baseline: 78.8 (18.1); End of therapy: 76.0 (2.5); 3 months: 75.6 (2.6); 1 year: 76.7 (3.5); 2 years: 76.7 (4.4); 3 years: 77.7 (6.2) | Differences NS (P-value NR)
Social functioning | | | Baseline: 82.2 (19.8); End of therapy: 71.7 (3.1); 3 months: 82.6 (2.9); 1 year: 84.7 (3.7); 2 years: 90.5 (4.5); 3 years: 89.7 (7.0) | Baseline: 80.6 (22.6); End of therapy: 78.6 (2.1); 3 months: 83.9 (2.6); 1 year: 89.4 (3.3); 2 years: 92.5 (6.2); 3 years:92.9 (7.4) | Differences NS (P-value NR)