# APPENDIX C PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 3 | Yes | Thank you.
4 | 4 | Yes | Thank you.
5 | 5 | Yes | Thank you.
6 | 6 | Yes | Thank you.
7 | 7 | Yes | Thank you.
8 | 9 | Yes | Thank you.
9 | 10 | Yes | Thank you.
10 | 11 | Yes | Thank you.
11 | 12 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
12 | 1 | No | Thank you.
13 | 2 | No | Thank you.
14 | 3 | No | Thank you.
15 | 4 | No | Thank you.
16 | 5 | No | Thank you.
17 | 6 | No | Thank you.
18 | 7 | No | Thank you.
19 | 9 | No | Thank you.
20 | 10 | No | Thank you.
21 | 11 | No | Thank you.
22 | 12 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
23 | 1 | No | Thank you.
24 | 2 | No | Thank you.
25 | 3 | No | Thank you.
26 | 4 | No | Thank you.
27 | 5 | No | Thank you.
28 | 6 | Yes | Reviewer did not provide which studies they thought were missed, so we were unable to directly address this comment.
29 | 7 | No | Thank you.
30 | 9 | No | Thank you.
31 | 10 | Yes - This report appears to be incomplete and the results are not analyzed properly. i would refer the authors to the appendix of this article which is an extremely complete bibliography of all hypofractionated schedules: https://www.redjournal.org/article/S0360-3016(20)31341-9/fulltext | The cited article is a review of all radiation fractionation treatments that were published during the COVID-19 pandemic (and indexed by MEDLINE). As such, this review included many articles with study designs, treatments, and patient populations that would not be eligible for this ESP report. However, we have examined the bibliography for this review and found no additional articles that met our eligibility criteria.
32 | 11 | No | Thank you.
33 | 12 | No | Thank you.
Additional suggestions or comments can be provided below.
34 | 1 | Page 1, bullet 3; this statement implies a negative connotation since it sees no difference in survival or disease progression which is in fact the positive point that with no difference in acute or late harms altered fractionation regimens offer the same survival and disease free progression | We used standard language recommended by GRADE to describe the summary results. The GRADE ratings were based on the effect findings and the thresholds for minimally important differences that were discussed and agreed upon with our partners and TEP members. The current wording does not provide an intrinsic “negative” or “positive” connotation. The alternate wording “offer the same survival and disease-free progression” is not fully accurate and is not consistent with GRADE recommendations.
35 | 1 | Page 6, Line 22; this does not makes sense. Lung SBRT is small volume and we don’t usually see esophagitis. if this is looking at large volume palliative lung hypofractionation then the two should be separated | We checked these results, and they are consistent with reviewer statement that these outcomes are rare (see pg. 58 in the final report). Because the study sizes were very small (total N=101 for each of 2 trials, Ball et al. and Nyman et al.), there were no events observed in either arm in Ball et al. and only 1 event (in the control arm) in Nyman et al. Thus, we have very low certainty in the evidence for differences (or lack thereof) in this harm outcome. We excluded studies evaluating palliative therapy as our report was focused on radiation treatment for curative intent.
36 | 2 | Overall, this report is comprehensive and attempts to synthesize the published data for the purposes of informing national policy on hypofractionated radiotherapy for the definitive treatment of several common cancer subtypes. The draft report is 214 pages long and the body of the report before the references is 69 pages long. There are several forest plots that are not labeled (is the left side of the plot always hypofractionated or conventional?) so the reader is left to scrutinize the data to deduce which arm is favored for which study and for the overall measure of the combined study data. Overall, the document should be combed over by a technical editor for grammar, as there are several instances where commas are either placed in error or omitted in error and this makes reading the manuscript and following along much more challenging. My suggestions for changes are as follows: | The length of this report reflects the large scope of the key questions addressing benefits and harms of hypofractionation for multiple types of cancer. Moreover, this sized scope (and thus length of report) is not unusual for ESP projects. We have also included a much shorter “Executive Summary” with Key Findings that summarize the results and certainty of evidence for cancer types and outcomes of interest.; The forest plots and pooled estimates all reflect the relative rate of the event of interest (eg, survival; toxicity) in the hypofractionation group divided by the rate of the event in the control group. Thus, a RR > 1.0 always indicates that the rate of an event is greater in the hypofractionation group. We have added labeling to all the forest plots to indicate which direction favors hypofractionation vs. conventional or standard of care.
37 | 2 | p 1; line 13, needs a comma between “cancer” and “evidence” | This has been addressed.
38 | 2 | p 1; line 18, need the word “of” inserted between “or” and “very” | This has been addressed.
39 | 2 | p 1; line 44 or 45, this entire sentence is awkward and does not reflect or adequately inform the reader on the definition of hypofractionation. I would suggest the following wording: “Hypofractionation is a treatment schedule in which the total dose of radiation is divided into large doses per fraction and the treatment is given once a day or less often over a smaller total number of fractions and a shorter overall period of time compared to conventional fractionation.” | Thank you for the suggested wording; we have revised this sentence.
40 | 2 | p 1; line 52, “has” should be “have” | This has been addressed.
41 | 2 | p 1; line 60; The word “Quality” should be inserted between “Oncology” and “Task” | This has been addressed.
42 | 2 | p 2; line 6 or 7, there should be a comma after the word “review” | This has been addressed.
43 | 2 | p 3; line 13, there should be a comma after the word “trials” and before the number “47” | This has been addressed.
44 | 2 | p 3, line 13, the comma after bias should either be a period followed by a new sentence or a semicolon | This has been addressed.
45 | 2 | p 3, line 32 or 33, there should be a “<” sign before the number 5 | This has been addressed.
46 | 2 | p 5, line 40, the text is missing the word “no” between “or” and “difference” | This has been addressed.
47 | 2 | p 7, line 17, delete the comma after the word “intent” | This has been addressed.
48 | 2 | p 7, line 29, sentence is missing the word “cancers” between the word “bladder” and the period | This has been addressed.
49 | 2 | p 7, line 36, replace the semicolon with a colon | This has been addressed.
50 | 2 | p 7, line 37 or 38, Replace the word “There” with “While there” | This has been addressed.
51 | 2 | p 7, line 38 or 39, remove the word “however” and add the words “in toxicity” after the word “difference” | This has been addressed.
52 | 2 | p 7, line 39 or 40, replace “vs.” with “and” and place a comma between the words “reviews” and “our” | This has been addressed.
53 | 2 | p 7, line 47, remove the word “Additionally”, remove the comma, and capitalize the letter I in the word “in” | This has been addressed.
54 | 2 | p 7, line 50 or 51, replace the words “more clear” with the word “clearer” | This has been addressed.
55 | 2 | p 7, line 52, the text is missing the word “was” between “certainty” and “low” | This has been addressed.
56 | 2 | p 9, line 25, add the text “in the United States” after the word “(NCI)” | This has been addressed.
57 | 2 | p 9, lines 37 and 38, this entire sentence is awkward and does not reflect or adequately inform the reader on the definition of hypofractionation. I would suggest the following wording: “Hypofractionation is a treatment schedule in which the total dose of radiation is divided into large doses per fraction and the treatment is given once a day or less often over a smaller total number of fractions and a shorter overall period of time compared to conventional fractionation.” | As noted above, this has been revised.
58 | 2 | p 11, line 11 or 12, the word “prostate,” needs to be inserted in between “breast,” and “lung” | This has been addressed.
59 | 2 | p 11, line 31, replace “is” with “are” | This has been addressed.
60 | 2 | p 11, line 32 or 33, add the word “the” between the words “in” and “definitive” | This has been addressed.
61 | 2 | p 11, line 35 or 36, add the word “the” between the words “do” and “efficacy” | This has been addressed.
62 | 2 | p 11, line 37, remove the words “prostate cancer NCCN” | “Prostate cancer NCCN risk stratification” was specifically requested and approved by partners and TEP members for Key Question 2. Both Key Questions and the review protocol were developed and approved a priori. They cannot be changed at this time and changing the Key Question at this time would not accurately represent how we conducted the review.
63 | 2 | p 11, line 38, replace the word “and” with the word “or” | This has been addressed.
64 | 2 | p 11, lines 40 to 43, this entire sentence is awkward and does not reflect or adequately inform the reader on the definition of hypofractionation. I would suggest the following wording: “Hypofractionation is a treatment schedule in which the total dose of radiation is divided into large doses per fraction and the treatment is given once a day or less often over a smaller total number of fractions and a shorter overall period of time compared to conventional fractionation.” | Thank you for the suggested wording; we have revised this sentence.
65 | 2 | p 11, line 56 or 57, remove the word “Cyberknife” (that is a specific model or brand of linear accelerator sold and marketed by a particular vendor and not a type of radiation therapy) | This has been addressed.
66 | 2 | p 14, line 37 or 38, add the words “per fraction” after the words “Hypofractionation: [>220 cGy (2.2 Gy)]” | This has been addressed.
67 | 2 | p 14, line 42 or 43, add the words “per fraction” after the words “…long course radiation [180 to 220 cGy (1.8 to 2.2 Gy)]” | This has been addressed.
68 | 2 | p 15, line 5, add the symbol “</=” before the first use of the phrase “2 years” on this line | This has been addressed.
69 | 2 | p 19, line 46 or 47, remove the parentheses and remove the word “see”, add a comma after the word “trials” and before the number “47” | This has been addressed.
70 | 2 | p 20, line 5 or 6, add the word “of” between “populations” and “less” | This has been addressed.
71 | 2 | p 20, lines 9 or 10, add the word “follow-up” between the words “shorter” and “durations” | This has been addressed.
72 | 2 | p 42, line 7 or 8, the total dose range states “66-50 Gy”, is this correct? | This has been corrected to read “66-80 Gy”.
73 | 2 | p 42, line 16 or 17, the total dose range states “66-50 Gy”, is this correct? | This has been corrected to read “66-80 Gy”.
74 | 2 | P 45, line 18 or 19, add the words “in small cell lung cancer” after the word “harms” | This has been addressed.
75 | 2 | P 51, line 15, all of the patients in the study reference #74 Choudhury et al. had recurrent nasopharyngeal carcinoma, so this sentence needs to be corrected | In response to other reviewer comments, we have reorganized this section such that the results for early stage glottic cancer are separately described from those on recurrent nasopharyngeal (Tian et al.) or locally advanced head and neck cancer (Choudhry et al.).
76 | 2 | P 51, line 23 or 24 to 24 or 25, 3.125 Gy per fraction is referred to as “ultra-hypofractionation”.; This is internally inconsistent with the authors’ definitions in Table 1 of this manuscript. | As noted above, this section has been reorganized. We have double-checked that treatments are correctly described as moderate hypofractionation.
77 | 2 | P 51, line 48 or 49, replace the words “squamous cell carcinoma” with the word “larynx” and change the number “3” to the number “2” then add one more row in this same category of “Sub-cancer type” called Not specified” and list that sub-cancer type as k=1 | As noted above, this section has been reorganized. We no longer have a summary table in this section. We have double-checked that descriptions of the included cancer diagnoses are correct.
78 | 2 | P 60, line 29 or 30, insert the word “survival” between the words “free” and “at” | This has been addressed.
79 | 2 | p 63; line 13, needs a comma between “cancer” and “evidence” | This has been addressed.
80 | 2 | p 63; line 17 or 18, need the word “of” inserted between “or” and “very” | This has been addressed.
81 | 2 | p 63, line 21, replace the word “requires” with the word “require” | This has been addressed.
82 | 2 | p 65, line 37 or 38, the text is missing the word “no” between “or” and “difference” | This has been addressed.
83 | 2 | p 67, line 13 and 14 states, “…in an effort to capture the evidence with the likelihood of highest quality.” What does that mean? Can it be rephrased for clarity? | We have rephrased this sentence to indicate that this refers to the restriction of eligibility to RCTs. Furthermore, we did not abstract detailed outcomes from RCTs rated as high risk of bias.
84 | 2 | P 67, line 25, add the word “cancers” between the word “bladder” and the period | This has been addressed.
85 | 2 | P 67, line 40 or 41 to line 43, remove the entire sentence “Our review found greater variation in the harms related outcomes, however none of the analyses suggested a clinically meaningful difference between hypofractionation vs. conventional radiotherapy.” This is redundant as it was just stated in the preceding paragraph verbatim. | This has been addressed.
86 | 2 | P 67, lines 50 to 52 or 53, remove the phrase “previous systematic reviews and meta-analyses reported similar findings to our report; little or no difference in overall survival between the hypofractionation and conventional radiotherapy.” This is redundant as it was just stated two paragraphs earlier verbatim. | This has been addressed.
87 | 3 | Overall, the authors have done an admirable job of synthesizing a large volume of research across multiple disease sites and condensed it into a reasonable format that covers the salient issues of treatment outcome and toxicity in a relatively short period of time. The authors should be commended for their efforts. | Thank you.
88 | 4 | in the executive summary key findings, the first bullet point has a typo: Key Findings; - Despite many randomized trials enrolling individuals with different cancers evidence was limited regarding the comparative effectiveness and harms of hypofractionation versus radiotherapy for definitive (non-palliative) therapy.; should read: Key Findings; - Despite many randomized trials enrolling individuals with different cancers evidence was limited regarding the comparative effectiveness and harms of hypofractionation versus CONVENTIONALLY FRACTIONATED radiotherapy for definitive (non-palliative) therapy. | The key findings have been substantially revised, and we have clarified the intervention comparisons.
89 | 5 | Page 1, Line 9; Hypofractionated vs. conventional radiotherapy. This phrase is a little confusing as is, consider rewording. | This has been revised to “hypofractionation versus conventionally fractionated radiotherapy”
90 | 5 | Page1, Line 13; Use ‘or’ instead of and. Also, consider specifying what type of evidence as the group was specific in that regard.; Same with bullet 3. | This has been addressed.
91 | 5 | Page 1, Line 21; Hypofractionated radiation or radiotherapy is the preferred language. This bullet does not read well, consider rewording | This has been addressed.
92 | 5 | Page1 Line 41; This should be reworded, too vague | This has been addressed.
93 | | Page 2, Line 9; consider listing only those that were ultimately performed and mention in methods that others were considered and ulimately not pursued due to lack of data | This has been reworded to clarify which cancers were included in the review and which among these did not have any eligible trials. We believe it is also important to highlight existing evidence gaps for clinicians, policy makers and researchers. In this case, the lack of RCTs for several cancer types suggest areas for future research.
94 | 5 | ES-Table 1; please offer more explanation or N and # trials. Consider adding a qualifier in the first column such as (early) or (late) where applicable | We have revised the column heading to read “Total N” for total number of participants across all eligible trials for that outcome. We have also added early and/or late as descriptors for the toxicity outcomes.
95 | 5 | Page 8, After Conclusions; Due to the enormity of the scope of this project, I would highly recommend disease site expert review per section. Within the first several pages there are numerous English language errors/ typos and others have noted errors in findings such as a study being marked as SCC instead of SCLC. | We have undertaken an additional round of reviews (of a revised draft) and assured that those with the relevant expertise had the opportunity to review the report. We have corrected the designation of the specified trial to NSCLC (.
96 | 5 | Page 21, Line 7; First sentence is awkward, please revise. Many are not familiar with ROB | We have revised this sentence for greater clarity. We also describe ROB ratings in the Methods.
97 | 5 | Page 44, Line 15; This needs to be broken out to hypofractionated and ultrahypofractionated. Unfair to pool them as they represent different populations (early vs locally advanced lung cancer) | The lung cancer section has been reorganized to separate the ultrahypofractionated comparison trials from the hypofractionated trials. The lung cancer trials were not pooled due to clinical heterogeneity and the decision a priori to not pool if fewer than 5 trials were identified.
98 | 5 | Table 1 - Cancer type has an asterisk which is not explained. Initially, I was unclear how these are organized within subsections. Based on the first two findings, I thought perhaps certainty of evidence and was looking for a pattern. Consider making it alphabetical to reduce any confusion on organization. Overall though , looks very good. (comments on a revised draft report) | We have removed the asterisk. The Summary of Key Findings is organized by outcome, and then the respective cancers. This reflects the organization of the results sections in the main report.
98 | 5 | Page 46 line 30 please write out the number three (comments on a revised draft report) | We have revised this sentence to clarify the number of treatments and the dose per fraction.
99 | 5 | Table 16 in OS, SCLC and Glottic Caner have a typo that I believe should read “may” (comments on a revised draft report) | This has been addressed.
100 | 6 | I have concerns about entire manuscript after reading briefly through the lung.. they discuss 5 trials but then only mention 3 in their key question and summary for lung NSCLC. | The overview of lung cancer section correctly states that there were 5 trials that were rated low or some concerns for risk of bias (4 trials for NSCLC, and 1 for SCLC). The NSCLC trials involving SABR/SBRT have now been further regrouped. The summaries of findings for each individual cancer type, as well as in the Discussion, are by outcome. The total # of trials listed for each outcome is often less than the total # of eligible trials for that cancer, since not all trials report all outcomes of interest.
101 | 6 | They say that the ROY study is a small cell study see below but it is a squamous cell study. They misclassify this study… | As noted above, we have corrected this misclassification.
102 | 6 | Someone has to go through each disease site… I also noted mistakes they put hyperfraction for an SBRT dosing in the appendix somewhere for lung ….. | As noted above, we undertook an additional round of reviews of an interim revised draft, in order to assure that relevant experts had the opportunity to review. We have also reorganized the lung cancer section and separately pulled out the SABR/SBRT trials.
103 | 6 | [Regarding lung cancer results for Key Question 1]: Roy is small cell and even so their conclusions do not make sense; Ball et al Superior survival in hypofrac statistically significant; Roy et al SBRT superior OS statistically significant and study listed in appendix but not listed in their key question section; Nyman not statistically significant btwn conventional and hypofrac; Qui the p values not reported, median survival not statistically different small cell Iyengar not statistically different | As noted above, we have corrected the classification of the Roy et al. trial. We have also reorganized the lung cancer section to separately discuss results for SABR/SBRT in NSCLC. With this reorganization and separate evaluation of the certainty of evidence for overall survival (SABR vs. conventional) and progression-free survival (SBRT vs. conventional), these were changed from low to moderate certainty for these 2 comparisons. As we described in the Methods section, we evaluated 5 domains in determining the certainty of evidence according to GRADE recommendations. This process does not rely on the p-value of each individual trial effect estimate. Within the Results section for lung cancer, we have also now provided more information about the factors that impacted the certainty of evidence assessment for each outcome.
104 | 7 | sCLC and nSCLC is typically noted SCLC and NSCLC in the literature. The lower case “s” is very atypical. | This has been changed throughout the report.
105 | 7 | For SCLC, the Qui trial’s dose 65 Gy (there is a typo in Appendix table 11 with “GY” and not “Gy”) in 26 daily fractions has a higher biologically effective dose (BED) as compared to conventional fractionation or 42 Gy in 15 fractions as in the Gronberg trial. The BED in the Qui trial is a major confounder. | This typo has been addressed. We provide detailed description of the intervention and comparator treatments in the Qui et al. trial and we downgraded the certainty of evidence for outcomes in SCLC due to substantial methodological limitations of this study.
106 | 7 | Finally, the biggest issue is the unclear separation between SBRT for the lung and Hypofractionation for the lung. These are much different modalities and cannot be lumped together for analysis. The Iyengar trial had stage III patients, which is completely different than the SBRT trials which had stage I patients. The manuscript does not make clear this distinction and there should be a clear SBRT for NSCLC section and separate hypofractionation for NSCLC section. Regimens also for different stages (I/II vs III) should be made as well. | As noted above, we have reorganized the lung cancer results section, such that results from SABR/SBRT trials are separated from the other NSCLC trials. We agree that this is more informative for interpreting these results, given the differences in both treatment characteristics and patient populations.
107 | 7 | The conclusion that “Hypofractionation may result in a reduction in overall survival” in table 1 for NSCLC is highly problematic! It appears SBRT is lumped into that conclusion. Again, this must be changed. | As noted above, results from.SABR/SBRT trials are now separately considered. The detailed results, summary findings, and conclusions have been updated to reflect this.
108 | 7 | Table ES-1 spelling error “Hypofractionation ay result…” for SCLC and early glottic - Should be “may” (comments on a revised draft report) | This had been addressed.
109 | 9 | Breast Cancer.; The authors are commended for compiling the many randomized trials comparing various hypofractionation regimens in breast cancer. | Thank you.
110 | 9 | Prostate Cancer.; The authors are commended for compiling the many randomized trials comparing various hypofractionation regimens in prostate cancer. The authors can consider breaking down the data in terms of risk groups, but probably not necessary and I think the results would largely be the same: little difference between hypofractionation, ultrahypofractionation (SBRT), and conventional (standard) radiation. | Thank you. We are limited in stratification of results by risk groups to what is reported in the published articles. When stratified results are provided, we have included those in our report.
111 | 9 | Rectal Cancer.; The authors are commended for this evaluation of hypofractionation in rectal cancer. | Thank you.
112 | 9 | Head and Neck Cancer; The authors are commended for compiling the data comparing various hypofractionation regimens in Head and Neck Cancers. However, there are some concerns. I disagree with the assessment to key question 2. Given available data, I think results do indeed vary by tumor characteristics. The majority of data here is for early stage glottic cancer, and it is worthwhile to separate out the data for glottic cancer from other head and neck cancers. I think sufficient data exist to support moderate hypofractionation for treatment of early stage glottic cancer on the basis of Yamazaki 2006, Moon 2014, and Kodaira 2018. Moderate hypofractionation for T1 glottic cancer is the preferred regimen per NCCN guidelines. Somewhat beyond the scope of this report, but worth noting for awareness, is the literature on accelerated and hyperfractionation in head and neck cancers. | We appreciate reviewer’s suggestion to separately group studies of early stage glottic cancer from trial for more advanced (or recurrent) disease. We have now reorganized those results and separately assessed certainty of evidence for early glottic cancer, and advanced or recurrent disease.
113 | 9 | Lung Cancer.; The authors are commended for compiling the trials comparing various RT fractionations for lung cancer. However, there are some important points to consider that I think are lost in the manuscript as it currently reads and should be addressed in some detail, which would strengthen the report. First, I disagree with the answer to KQ2. do vary by tumor characteristics: histology matters (NSCLC vs SCLC), stage matters (early stage versus locally advanced), and location of tumor matters (peripheral, central, ultracentral).; Specifically, data is supportive of ultrahypofractionation (SBRT) for early-stage NSCLC. I agree completely with considering SCLC separately from NSCLC. | Thank you. As noted above, we have substantially reorganized the results to report findings separately for NSCLC and SCLC (and for SABR/SBRT within NSCLC). We have noted that none of the eligible trials directly addressed Key Question 2 by providing stratified results by patient or disease characteristics. Thus, we did not identify results to answer this question. As we have separated out the studies of NSCLC and the one trial of SCLC, we cannot compare the Results results across these subtypes of lung cancer.
114 | 9 | SBRT was compared against conventional radiation therapy in two trials, SPACE, and CHISEL, that are reported in this manuscript, as well as numerous non-randomized series. The CHISEL trial compared SBRT versus conventional or moderately fractionated RT in biopsy proven, FDG PET/CT staged patients with NSCLC. The SPACE trial compared SBRT to conventional and did not require biopsy proven NSCLC and did not require FDG PET/CT, thus CHISEL is more applicable to current practice. The results of CHISEL are not subtle and favor SBRT in early-stage NSCLC. Freedom from local failure (HR 0.32) strongly favored SBRT as did Lung cancer specific survival (HR 0.49). The Freedom from Local Failure was not described in the report as currently written and I think should be added. While the authors of this report describe the trial as small in total N, the trial was adequately powered. In fact, I do not think there would be equipoise for a trial to now compare SBRT versus conventional RT for most early-stage NSCLC. Rather, the comparison being made now in randomized trials (including within VA) is between SBRT and surgery for operable patients. Other unanswered questions are evaluating various fractionation regimens for ultracentral lung tumors. These important points are lost in the current version of the report which as currently written broadly concludes that evidence is uncertain on the effects of hypofractionation in NSCLC.; Given the variance with stage, I strongly recommend separating the key questions of overall survival, progression-free survival, and lung cancer specific survival, between the categories of early stage and locally advanced NSCLC. Early Stage NSCLC trials should be evaluated separately from those that include locally advanced disease. The Iyengar trial compared, for example, moderately hypofractionated versus conventional RT in patients who were ineligible for chemotherapy and were mostly Stage III. This is a very different situation than early stage NSCLC (for example CHISEL), with very different treatment volumes. | As noted above, we have reorganized this section and separately considered results from SABR/SBRT trials in NSCLC. Regarding the inclusion of freedom from local failure, the selected outcomes of interest that would be assessed for certainty of evidence were prioritized by the operational partners and TEP for this report; however, all outcomes of interest for each trial are reported in the appendix tables. We appreciate the context of currently ongoing trials, as well as questions to be addressed by future research in this area.
115 | 9 | The descriptions in the table describing radiation regimens have some errors. For example, Slawson et al, page 174, table describes 2Gy/30 Total 60 Gy (6 weeks) as hyperfractionation which is incorrect: it is conventional (or Standard). Similarly, Singh et al, page 175, table describes 20 Gy, 3 fractions, Total dose 60 Gy as hyperfractionation which is incorrect: it is ultrahypofractionation (ie SBRT). | This has been corrected.
116 | 9 | Bladder Cancer.; The authors are commended for their evaluation of hypofractionation in bladder cancer. However, there are some concerns with the report as written. The description of the BC2001 Trial (Huddart et al 2013) and its results are not reported correctly and are misinterpreted in the report as it currently reads. This should be addressed in the tables as well as the text, and will strengthen the manuscript. BC2001 did not randomize patients between hypofractionated RT and conventional RT. Rather, it randomized patients (in a 2 × 2 factorial design) to reduced high dose volume RT (RHDVRT) versus standard whole bladder RT (stRT), and also to RT alone versus RT with chemotherapy. RHDVRT in this trial does not mean hypofractionated and stRT does not mean conventional fractionated. In RHDVRT, the full bladder was treated to a reduced dose with the gross tumor partial bladder volume receiving the full dose. In stRT, the full bladder received the full dose. In either RHDVRT or stRT, two radiation regimens were allowed: either 55 Gy in 20 fractions or 64 Gy in 32 fractions, but this was not randomized. The choice between the two was up to each participating center. Both of these regimens were considered standard RT regimens in the UK where the trial took place. | We agree with the reviewer that this trial is not eligible. We have now removed it from the results.
117 | 9 | A separate randomized Trial, Bladder Carbogen Nicotinamide (BCON), randomized patients to RT with or without carbogen. In this trial, similarly, these two radiation regimens were allowed, and again these regimens were up to the treating centers. A meta-analysis of these trials (Chaudhury et al, Lancet Oncology, 2021) aimed to compare 55 Gy in 20 fractions to 64 Gy in 32 fractions using individual patient data from the two trials. This meta-analysis concluded that the hypofractionated regimen of 55 Gy in 20 fractions was non-inferior to 64 Gy in 32 fractions for invasive locoregional control and toxicity, and is superior in regard to invasive locoregional control. Chaudhury et al Lancet Oncol . 2021 Feb;22(2):246-255. doi: 10.1016/S14702045(20)30607-0. PMID: 33539743. 33539743. | We appreciated this additional information about another trial involving hypofractionation in bladder cancer. Due to the choice of the radiation regimen and the key intervention studied being carbogen, the BCON trial also does not meet our eligibility criteria. As a hypofractionated radiation regimen was not randomized in either BCON or the Huddart et al. trial, meta-analysis using these data (as was done by Chaudhury et al.) would not provide high certainty results regarding the efficacy of hypofractionation.
118 | 10 | Glottic T1 cancers have been shown in 2 randomized trials to have better local control with hypofractionation. Survival is not an issue for these cancers as they are salvaged with surgery so patients do not die from this disease. Moderate hypofractionation 55 Gy in 20 fractions has been tested in phase 2 trials and is currently being explored in the IAEA-HYPNO trial. Again, the benefit is not survival but decreased use of resources in under-resourced settings or strained public health sectors. I unfortunately do not feel that the conclusions are written in such a way as to demonstrate a strong understanding of this literature. | As noted above, we have now separated out the results from trials for early stage glottic cancer, where there may not be expected differences in survival, from those for locally advanced or recurrent head and neck cancer. Although no included studies directly addressed resource utilization or cost, we do provide the length of treatment and number of sessions, as an indicator of the relative burden (on patients and health systems) of different radiation therapies. In Discussion, we have added the importance of considering resource use (especially when comparing treatments with similar survival and toxicity outcomes).
119 | 11 | Comments re: VAESP-D-22-00053; Hypofractionation Radiation Therapy…; I focused on the Prostate section since that is my area of expertise.; 1. I didn’t see the Catton “PROFIT” trial. Why did that trial not make the selection of studies in Figs 8 and 9? Catton CN JCO 35:1884, 2017 is reference 39.; 2. Overall I have no suggestions or edits to make. | The Catton “PROFIT” trial was not included in Figure 7 (prostate-cancer specific survival) or Figure 8 (prostate-cancer biochemical recurrence) because neither of these outcomes were reported in the publication. This study reported “biochemical clinical failure” which was a composite outcome of 4 different outcomes; it would not be appropriate to combine this outcome with biochemical recurrence, which was separately reported in other studies.