# APPENDIX B EXCLUDED STUDIES

1 Concurrent boost with adjuvant breast hypofractionated radiotherapy and toxicity assessment. Middle East Journal of Cancer. 2015;6(1):21–27. Ineligible study design
2 Aboziada MA, Shehata S. Acute and late adverse effects of breast cancer radiation: Two hypo-fractionation protocols. Journal of Solid Tumors. 2017;7(2):1–6. Ineligible outcome
3 Adebahr S, Kirste S, Sprave T, . Psma-pet/mri-based focal dose escalation in patients with primary prostate cancer treated with stereotactic body radiation therapy (Hypofocal-sbrt): Study protocol of a randomized, multicentric phase iii trial. Cancers. 2021;13(22):5795. Ineligible study design34830950
4 Alayed Y, Cheung P, Chu W, . Two StereoTactic ablative radiotherapy treatments for localized prostate cancer (2STAR): Results from a prospective clinical trial. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2019;135:86–90. Ineligible intervention/comparison31015175
5 Awwad H, El-Baki HA, El-Bolkainy N, . Pre-operative irradiation of T3-carcinoma in bilharzial bladder: a comparison between hyperfractionation and conventional fractionation. International journal of radiation oncology, biology, physics. 1979;5(6):787–94. Ineligible intervention/comparison500410
6 Bartelink H, Horiot J-C, Poortmans PM, . Impact of a higher radiation dose on local control and survival in breast-conserving therapy of early breast cancer: 10-year results of the randomized boost versus no boost EORTC 22881-10882 trial. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2007;25(22):3259–65. Ineligible intervention/comparison17577015
7 Bartelink H, Van den Bogaert W, Horiot JC, Jager J, van Glabbeke M. Concomitant cisplatin and radiotherapy in a conventional and modified fractionation schedule in locally advanced head and neck cancer: a randomised phase II EORTC trial. European journal of cancer (Oxford, England : 1990). 2002;38(5):667–73. Ineligible intervention/comparison11916549
8 Bates TD. A prospective clinical trial of postoperative radiotherapy delivered in three fractions per week versus two fractions per week in breast carcinoma. Clinical Radiology. 1975;26(3):297–304. Ineligible intervention/comparison1201630
9 Bauman G, Chen J, Rodrigues G, Davidson M, Warner A, Loblaw A. Extreme hypofractionation for high-risk prostate cancer: Dosimetric correlations with rectal bleeding. Practical radiation oncology. 2017;7(6):e457–e462. Ineligible intervention/comparison28734642
10 Beaudry MM, Carignan D, Foster W, . Ultra-Hypofractionated (UHF) Compared to Moderate-Hypofractionated (MHF) Prostate IGRT With HDR Brachytherapy Boost (BB): Four-Year Toxicities and Local Control. International journal of radiation oncology, biology, physics. 2021;111(3):e265. Ineligible study design
11 Beckendorf V, Guerif S, Le Prise E, . 70 Gy versus 80 Gy in localized prostate cancer: 5-year results of GETUG 06 randomized trial. International journal of radiation oncology, biology, physics. 2011;80(4):1056–63. Ineligible intervention/comparison21147514
12 Beckendorf V, Guerif S, Le Prise E, . The GETUG 70 Gy vs. 80 Gy randomized trial for localized prostate cancer: feasibility and acute toxicity. International journal of radiation oncology, biology, physics. 2004;60(4):1056–65. Ineligible intervention/comparison15519775
13 Beitler JJ, Zhang Q, Harris J, . Final results of local-regional control and late toxicity of rtog 9003: A randomized trial of altered fractionation radiation for locally advanced head and neck cancer. International Journal of Radiation Oncology Biology Physics. 2014;89(1):13–20. Ineligible intervention/comparison24613816
14 Benson R, Prashanth G, Mallick S. Moderate hypofractionation for early laryngeal cancer improves local control: a systematic review and meta-analysis. European archives of oto-rhino-laryngology : official journal of the European Federation of Oto-Rhino-Laryngological Societies (EUFOS) : affiliated with the German Society for Oto-Rhino-Laryngo–ogy - Head and Neck Surgery. 2020;277(11):3149–3154. Ineligible study design
15 Bentzen SM, Haviland JS, Bliss JM, Yarnold JR. Prolongation of overall treatment time as a cause of treatment failure in early breast cancer: An analysis of the UK START (Standardisation of Breast Radiotherapy) trials of radiotherapy fractionation. Radiotherapy and Oncology. 2016;121(3):420–423. Ineligible study design27666929
16 Bhangoo RS, Vargas CE, DeWees TA, . Updated Toxicity and Quality-of-Life Outcomes From a Randomized Phase III Trial of Extreme Hypofractionated vs. Standard Fractionated Proton Therapy for Low-Risk Prostate Cancer. International journal of radiation oncology, biology, physics. 2021;111(3):e266. Ineligible intervention/comparison
17 Bolner A, Signor M, Gava A, . Long-term results of conventional radiotherapy versus accelerated hyperfractionated radiotherapy versus concomitant radiotherapy and chemotherapy in locoregionally advanced carcinoma of the oropharynx. Tumori. 2006;92(1):41–54. Ineligible intervention/comparison16683383
18 Bonner JA, McGinnis WL, Stella PJ, . The possible advantage of hyperfractionated thoracic radiotherapy in the treatment of locally advanced nonsmall cell lung carcinoma: results of a North Central Cancer Treatment Group Phase III Study. Cancer. 1998;82(6):1037–48. Ineligible intervention/comparison9506347
19 Bourgier C, Acevedo-Henao C, Dunant A, . Higher toxicity with 42 Gy in 10 fractions as a total dose for 3D-conformal accelerated partial breast irradiation: results from a dose escalation phase II trial. Radiation oncology (London, England). 2012;7:141. Ineligible study design22913640
20 Brunt AM, Haviland JS, Bliss JM, . Five-fraction Radiotherapy for Breast Cancer: FAST-Forward to Implementation. Clinical Oncology. 2021;33(7):430–439. Ineligible study design34023185
21 Buchholz TA, Strom EA, Oswald MJ, . Fifteen-year results of a randomized prospective trial of hyperfractionated chest wall irradiation versus once-daily chest wall irradiation after chemotherapy and mastectomy for patients with locally advanced noninflammatory breast cancer. International journal of radiation oncology, biology, physics. 2006;65(4):1155–60. Ineligible intervention/comparison16750325
22 Bujko K, Rutkowski A, Pietrzak L, . Preoperative radiotherapy and local excision of rectal cancer with immediate radical re-operation for poor responders: A prospective multicentre study. Radiotherapy and Oncology. 2013;106(2):198–205. Ineligible intervention/comparison23333016
23 Buyyounouski MK, Pugh S, Rodgers J, . Primary Endpoint Analysis of a Randomized Phase III Trial of Hypofractionated vs. Conventional Post-Prostatectomy Radiotherapy: NRG Oncology GU003. International journal of radiation oncology, biology, physics. 2021;111(3):S2–S3. Ineligible study design
24 Chatterjee S, Chakraborty S. Hypofractionated radiation therapy comparing a standard radiotherapy schedule (over 3 weeks) with a novel 1-week schedule in adjuvant breast cancer: an open-label randomized controlled study (HYPORT-Adjuvant)-study protocol for a multicentre, randomized phase III trial. Trials. 2020;21(1):819. Ineligible study design32998747
25 Choi KH, Ahn SJ, Jeong JU, . Postoperative radiotherapy with intensity-modulated radiation therapy versus 3-dimensional conformal radiotherapy in early breast cancer: A randomized clinical trial of KROG 15-03. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2021;154:179–186. Ineligible intervention/comparison32980384
26 Cooke S, van Diessen J, Sikorska K, . Sites of First Progression in the Randomized PET-Boost Trial for Patients With Locally Advanced NSCLC. International journal of radiation oncology, biology, physics. 2021;111(3):S91. Ineligible intervention/comparison
27 Corkum M, Loblaw A, Hasan Y, . Prostate high dose-rate brachytherapy as monotherapy for prostate cancer: Late toxicity and patient reported outcomes from a randomized phase II clinical trial. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2021;156:160–165. Ineligible intervention/comparison33359269
28 Cox JD, Pajak TF, Marcial VA, . ASTRO plenary: interfraction interval is a major determinant of late effects, with hyperfractionated radiation therapy of carcinomas of upper respiratory and digestive tracts: results from Radiation Therapy Oncology Group protocol 8313. International journal of radiation oncology, biology, physics. 1991;20(6):1191–5. Ineligible intervention/comparison2045293
29 Coy P, Hodson I, Payne DG, . The effect of dose of thoracic irradiation on recurrence in patients with limited stage small cell lung cancer. Initial results of a Canadian Multicenter Randomized Trial. International journal of radiation oncology, biology, physics. 1988;14(2):219–26. Ineligible intervention/comparison2828289
30 Cummings B, Warde P, Waldron J, . Five year results of a randomized trial comparing hyperfractionated to conventional radiotherapy over four weeks in locally advanced head and neck cancer. Radiotherapy and Oncology. 2007;85(1):7–16. Ineligible intervention/comparison17920715
31 De Felice F, Musio D, Abate G, Moscarelli E, Bulzonetti N, Tombolini V. Impact of clinical complete response on treatment outcomes in patients with locally advanced HPV-negative oropharyngeal squamous cell carcinoma. Journal of Cancer Research and Clinical Oncology. 2020;146(2):477–483. Ineligible study design31686249
32 Dearnaley D, Huddart R, Graham J, . A randomised trial of accelerated radiotherapy for localised invasive bladder cancer. Radiotherapy and Oncology. 2005;75(1):34–43. Ineligible intervention/comparison15878099
33 Dearnaley DP, Sydes MR, Langley RE, . The early toxicity of escalated versus standard dose conformal radiotherapy with neo-adjuvant androgen suppression for patients with localised prostate cancer: results from the MRC RT01 trial (ISRCTN47772397). Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2007;83(1):31–41. Ineligible intervention/comparison17391791
34 Deore SM, Shrivastava SK, Supe SJ, Viswanathan PS, Dinshaw KA. Alpha/beta value and importance of dose per fraction for the late rectal and recto-sigmoid complications. Strahlentherapie und Onkologie : Organ der Deutschen Rontgengesellschaft [et al]. 1993;169(9):521–6. Ineligible population
35 Erlandsson J, Ahlberg M, Holm T, . Tumour regression after radiotherapy for rectal ca–cer - Results from the randomised Stockholm III trial. Radiotherapy and Oncology. 2019;135:178–186. Ineligible outcome31015165
36 Fadavi P, Jafarnejadi B, Nafissi N, Mahdavi SR, Javadinia SA. Outcome of hypofractionated breast irradiation and intraoperative electron boost in early breast cancer: A randomized non-inferiority clinical trial. Cancer Reports. 2021;4(5):e1376. Ineligible study design33797199
37 Fernandez K, Brand DH, Gao A, . Estimates of Alpha/Beta (alpha/beta) Ratios for Individual Late Rectal Toxicity Endpoints: An Analysis of the CHHiP Trial. International Journal of Radiation Oncology Biology Physics. 2021;110(2):596–608. Ineligible intervention/comparison33412260
38 Fersino S, Fiorentino A, Giaj Levra N, . Impact of Ialuril Soft Gels in reducing urinary toxicity during radical hypofractionated radiotherapy in prostate cancer: a preliminary experience. Minerva urologica e nefrologica = The Italian journal of urology and nephrology. 2016;68(1):9–13. Ineligible intervention/comparison26491889
39 Finney R. The treatment of carcinoma of the bladder by external irradiation. A clinical trial. Part II. Clinical Radiology. 1971;22(2):225–229. Ineligible study design4995808
40 Forster T, Jakel C, Akbaba S, . Fatigue following radiotherapy of low-risk early breast ca–cer - a randomized controlled trial of intraoperative electron radiotherapy versus standard hypofractionated whole-breast radiotherapy: the COSMOPOLITAN trial (NCT03838419). Radiation oncology (London, England). 2020;15(1):134. Ineligible study design32487184
41 Fragkandrea I, Kouloulias V, Mavridis P, . Radiation induced pneumonitis following whole breast radiotherapy treatment in early breast cancer patients treated with breast conserving surgery: A single institution study. Hippokratia. 2013;17(3):233–238. Ineligible outcome24470733
42 Fu KK, Clery M, Ang KK, Byhardt RW, Maor MH, Beitler JJ. Randomized phase I/II trial of two variants of accelerated fractionated radiotherapy regimens for advanced head and neck cancer: results of RTOG 88-09. International journal of radiation oncology, biology, physics. 1995;32(3):589–97. Ineligible intervention/comparison7790243
43 Fu KK, Pajak TF, Marcial VA, . Late effects of hyperfractionated radiotherapy for advanced head and neck cancer: long-term follow-up results of RTOG 83-13. International journal of radiation oncology, biology, physics. 1995;32(3):577–88. Ineligible intervention/comparison7790242
44 Fu KK, Pajak TF, Trotti A, . A Radiation Therapy Oncology Group (RTOG) phase III randomized study to compare hyperfractionation and two variants of accelerated fractionation to standard fractionation radiotherapy for head and neck squamous cell carcinomas: first report of RTOG 9003. International journal of radiation oncology, biology, physics. 2000;48(1):7–16. Ineligible intervention/comparison10924966
45 Fu X-L, Wang L-J, Qian H, . Hyperfractionated accelerated radiation therapy for nonsmall cell lung cancer: Clinical phase I/II trial. International Journal of Radiation Oncology Biology Physics. 1997;39(3):545–552. Ineligible intervention/comparison9336130
46 Gerard J-P, Azria D, Gourgou-Bourgade S, . Clinical outcome of the ACCORD 12/0405 PRODIGE 2 randomized trial in rectal cancer. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2012;30(36):4558–65. Ineligible intervention/comparison23109696
47 Ghadjar P, Hayoz S, Bernhard J, . Acute Toxicity and Quality of Life After Dose-Intensified Salvage Radiation Therapy for Biochemically Recurrent Prostate Cancer After Prostatectomy: First Results of the Randomized Trial SAKK 09/10. Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2015;33(35):4158–66. Ineligible intervention/comparison26527774
48 Ghoshal S, Goda JS, Mallick I, Kehwar TS, Sharma SC. Concomitant boost radiotherapy compared with conventional radiotherapy in squamous cell carcinoma of the head and–eck--a phase III trial from a single institution in India. Clinical oncology (Royal College of Radiologists (Great Britain)). 2008;20(3):212–20. Ineligible intervention/comparison18343310
49 Goel A, Kaushal V, Hooda HS, Das BP. Comparison of two radiation dose schedules in post mastectomy carcinoma of the breast. Indian journal of medical sciences. 2000;54(7):278–83. Ineligible intervention/comparison11143847
50 Gronberg BH, Killingberg KT, Flotten O, . High-dose versus standard-dose twice-daily thoracic radiotherapy for patients with limited stage small-cell lung cancer: an open-label, randomised, phase 2 trial. The Lancet Oncology. 2021;22(3):321–331. Ineligible intervention/comparison33662285
51 Gupta M, Mahajan R, Kaushal V, Seem RK, Gupta M, Bhattacharyya T. Prospective randomized trial to compare accelerated (six fractions a week) radiotherapy against concurrent chemoradiotherapy (using conventional fractionation) in locally advanced head and neck cancers. Journal of cancer research and therapeutics. 2015;11(4):723–9. Ineligible intervention/comparison26881508
52 Ha B, Cho KH, Lee KH, . Long-term results of a phase II study of hypofractionated proton therapy for prostate cancer: moderate versus extreme hypofractionation. Radiation oncology (London, England). 2019;14(1):4. Ineligible intervention/comparison30630500
53 Hafeez S, Patel E, Webster A, . Protocol for hypofractionated adaptive radiotherapy to the bladder within a multicentre phase II randomised trial: radiotherapy planning and delivery guidance. BMJ open. 2020;10(5):e037134. Ineligible intervention/comparison
54 Hall WA, Deshmukh S, Pugh SL, . Quality of Life Implications of Dose-Escalated External Beam Radiation for Localized Prostate Cancer: Results of a Prospective Randomized Phase 3 Clinical Trial, NRG/RTOG 0126. International Journal of Radiation Oncology Biology Physics. 2022;112(1):83–92. Ineligible intervention/comparison34919884
55 Halvorsen TO, Valan CD, Slaaen M, Gronberg BH. Associations between muscle measures, survival, and toxicity in patients with limited stage small cell lung cancer. Journal of cachexia, sarcopenia and muscle. 2020;11(5):1283–1290. Ineligible outcome32725772
56 Hannan R, Tumati V, Xie X-J, . Stereotactic body radiation therapy for low and intermediate risk prostate cancer-Results from a multi-institutional clinical trial. European journal of cancer (Oxford, England : 1990). 2016;59:142–151. Ineligible intervention/comparison27035363
57 Hatton MQF, Lawless CA, Faivre-Finn C, . Accelerated, Dose escalated, Sequential Chemoradiotherapy in Non-small-cell lung cancer (ADSCaN): a protocol for a randomised phase II study. BMJ open. 2019;9(1):e019903. Ineligible outcome
58 Haviland JS, Mannino M, Griffin C, . Late normal tissue effects in the arm and shoulder following lymphatic radiotherapy: Results from the UK START (Standardisation of Breast Radiotherapy) trials. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2018;126(1):155–162. Ineligible outcome29153463
59 Heemsbergen WD, Incrocci L, Sinzabakira F, Pos FJ. Patient-Reported Outcomes in the Acute Phase of the Randomized Hypofractionated Irradiation for Prostate Cancer (HYPRO) Trial. International Journal of Radiation Oncology Biology Physics. 2021. Ineligible outcome
60 Henk JM, Adams GE, Ash D. A study of the effect of misonidazole in conjunction with radiotherapy for the treatment of head and neck cancer. British Journal of Radiology. 1984;57(679):585–595. Ineligible intervention/comparison6329395
61 Hopwood P, Haviland JS, Sumo G, Mills J, Bliss JM, Yarnold JR. Comparison of patient-reported breast, arm, and shoulder symptoms and body image after radiotherapy for early breast cancer: 5-year follow-up in the randomised Standardisation of Breast Radiotherapy (START) trials. The Lancet Oncology. 2010;11(3):231–40. Ineligible outcome20138809
62 Horiot JC, Le Fur’R, N’Guyen T, . Hyperfractionated compared with conventional radiotherapy in oropharyngeal carcinoma: an EORTC randomized trial. European journal of cancer (Oxford, England : 1990). 1990;26(7):779–80. Ineligible intervention/comparison2145894
63 Horiot JC, Le Fur’R, N’Guyen T, . Hyperfractionation versus conventional fractionation in oropharyngeal carcinoma: final analysis of a randomized trial of the EORTC cooperative group of radiotherapy. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 1992;25(4):231–41. Ineligible intervention/comparison1480768
64 Jain S, Poon I, Soliman H, . Lung stereotactic body radiation therapy (SBRT) delivered over 4 or 11 days: a comparison of acute toxicity and quality of life. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2013;108(2):320–5. Ineligible intervention/comparison23993401
65 Jeremic B, Shibamoto Y, Igrutinovic I. Absence of cervical radiation myelitis after hyperfractionated radiation therapy with and without concurrent chemotherapy for locally advanced, unresectable, nonmetastatic squamous cell carcinoma of the head and neck. Journal of cancer research and clinical oncology. 2001;127(11):687–91. Ineligible intervention/comparison11710599
66 Johnson RJ, Walton RJ, Lim ML, Zylak CJ, Painchaud LA. A randomized study on survival of bronchogenic carcinoma treated with conventional or short fractionation radiation. Clinical radiology. 1973;24(4):494–7. Ineligible intervention/comparison4621257
67 Kacprowska A, Jassem J. Hypofractionated radiotherapy for early breast cancer: Review of phase III studies. Reports of Practical Oncology and Radiotherapy. 2012;17(2):66–70. Ineligible study design24377002
68 Kang B-H, Yu T, Kim JH, . Early Closure of a Phase 1 Clinical Trial for SABR in Early-Stage Glottic Cancer. International journal of radiation oncology, biology, physics. 2019;105(1):104–109. Ineligible study design30880271
69 Katori H, Tsukuda M, Watai K. Comparison of hyperfractionation and conventional fractionation radiotherapy with concurrent docetaxel, cisplatin and 5-fluorouracil (TPF) chemotherapy in patients with locally advanced squamous cell carcinoma of the head and neck (SCCHN). Cancer Chemotherapy and Pharmacology. 2007;60(3):399–406. Ineligible intervention/comparison17096160
70 Kawahara D, Ozawa S, Kimura T, . Marginal prescription equivalent to the isocenter prescription in lung stereotactic body radiotherapy: preliminary study for Japan Clinical Oncology Group trial (JCOG1408). Journal of radiation research. 2017;58(1):149–154. Ineligible study design28115532
71 Kim KN, Dyer MA, Qureshi MM, . Hypofractionated radiotherapy and surgery compared to standard radiotherapy in early glottic cancer. American journal of otolaryngology. 2020;41(5):102544. Ineligible study design32505989
72 Kim Y-J, Cho KH, Pyo HR, . A phase II study of hypofractionated proton therapy for prostate cancer. Acta oncologica (Stockholm, Sweden). 2013;52(3):477–85. Ineligible intervention/comparison23398594
73 Kinhikar R, Ghadi Y, Sahoo P, . Dosimetric comparison of three-dimensional conformal radiotherapy, intensity modulated radiotherapy, and helical tomotherapy for lung stereotactic body radiotherapy. Journal of Medical Physics. 2015;40(4):190–197. Ineligible study design26865754
74 Kirova YM, Campana F, Savignoni A, . Breast-conserving treatment in the elderly: long-term results of adjuvant hypofractionated and normofractionated radiotherapy. International journal of radiation oncology, biology, physics. 2009;75(1):76–81. Ineligible study design19168297
75 Koerber SA, Katayama S, Sander A, . Prostate bed irradiation with alternative radio-oncological approaches (PA–OS) - a prospective, multicenter and randomized phase III trial. Radiation oncology (London, England). 2019;14(1):122. Ineligible study design31291969
76 Konski AA, Winter K, Cole BF, Ang K-K, Fu KK. Quality-adjusted survival analysis of Radiation Therapy Oncology Group (RTOG) 90-03: phase III randomized study comparing altered fractionation to standard fractionation radiotherapy for locally advanced head and neck squamous cell carcinoma. Head & neck. 2009;31(2):207–12. Ineligible intervention/comparison19107946
77 Kougioumtzopoulou A, Platoni K, Kelekis N, . Moderate Hypofractionated Radiotherapy for Localized Prostate Cancer: The Triumph of Radiobiology. Reviews on recent clinical trials. 2021. Ineligible study design
78 Koukourakis G, Zacharias G, Petridis A. Evidence based whole breast hypo-fractionated radiation therapy in patients with early breast cancer. Journal of BUON : official journal of the Balkan Union of Oncology. 2015;20(2):473–8. Ineligible study design
79 Kron T, Chesson B, Hardcastle N, . Credentialing of radiotherapy centres in Australasia for TROG 09.02 (Chisel), a Phase III clinical trial on stereotactic ablative body radiotherapy of early stage lung cancer. The British journal of radiology. 2018;91(1085):20170737. Ineligible study design29446317
80 Krug D, Baumann R, Combs SE, . Moderate hypofractionation remains the standard of care for whole-breast radiotherapy in breast cancer: Considerations regarding FAST and FAST-Forward. Strahlentherapie und Onkologie : Organ der Deutschen Rontgengesellschaft [et al]. 2021;197(4):269–280. Ineligible study design
81 Krug D, Dellas K, Dunst J, . Impact of guideline changes on adoption of hypofractionation and breast cancer patient characteristics in the randomized controlled HYPOSIB trial. Strahlentherapie und Onkologie. 2021;197(9):802–811. Ineligible intervention/comparison33320286
82 Lawton C, Scott C, Sause WT, . Response, toxicity, failure patterns, and survival in five radiation therapy oncology group (RTOG) trials of sequential and/or concurrent chemotherapy and radiotherapy for locally advanced non-small-cell carcinoma of the lung. International Journal of Radiation Oncology Biology Physics. 1998;42(3):469–478. Ineligible intervention/comparison9806503
83 Liu L, Yang Y, Guo Q, . Comparing hypofractionated to conventional fractionated radiotherapy in postmastectomy breast cancer: a meta-analysis and systematic review. Radiation oncology (London, England). 2020;15(1):17. Ineligible study design31952507
84 Lukka HR, Pugh SL, Bruner DW, . Patient Reported Outcomes in NRG Oncology RTOG 0938, Evaluating Two Ultrahypofractionated Regimens for Prostate Cancer. International journal of radiation oncology, biology, physics. 2018;102(2):287–295. Ineligible intervention/comparison29913254
85 Marcial VA, Hanley JA, Chang C, Davis LW, Moscol JA. Split-course radiation therapy of carcinoma of the nasopharynx: results of a national collaborative clinical trial of the Radiation Therapy Oncology Group. International journal of radiation oncology, biology, physics. 1980;6(4):409–14. Ineligible intervention/comparison6993442
86 Mark RJ, Gorman V, Wolski M, McCullough S. Five Day Accelerated Partial Breast Irradiation (APBI) Using Stereotactic Body Radiation Therapy (SBRT) in Stage 0-II Breast Cancer: A Report of 218 Cases With Up to 39 Month Follow-Up. International journal of radiation oncology, biology, physics. 2021;111(3):e208. Ineligible study design
87 Marzi S, Saracino B, Petrongari MG, . Modeling of alpha/beta for late rectal toxicity from a randomized phase II study: conventional versus hypofractionated scheme for localized prostate cancer. Journal of experimental & clinical cancer research : CR. 2009;28:117. Ineligible outcome19689825
88 Mendez LC, Arifin AJ, Bauman GS, . Is hypofractionated whole pelvis radiotherapy (WPRT) as well tolerated as conventionally fractionated WPRT in prostate cancer patients? The HOPE trial. BMC cancer. 2020;20(1):978. Ineligible study design33036579
89 Michalski JM, Perez CA, Purdy JA, . Preliminary report of toxicity following 3D radiation therapy for prostate cancer on 3DOG/RTOG 9406. International Journal of Radiation Oncology Biology Physics. 2000;46(2):391–402. Ineligible intervention/comparison10661346
90 Min C, Connolly E, Chen T, Jozsef G, Formenti SC. Hypofractionated radiation therapy for early stage breast cancer: outcomes, toxicities, and cost analysis. The breast journal. 2014;20(3):267–73. Ineligible study design24750510
91 Murray J, Griffin C, Gulliford S, . A randomised assessment of image guided radiotherapy within a phase 3 trial of conventional or hypofractionated high dose intensity modulated radiotherapy for prostate cancer. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2020;142:62–71. Ineligible outcome31767473
92 Murthy V, Mallick I, Gavarraju A, . Study protocol of a randomised controlled trial of prostate radiotherapy in high-risk and node-positive disease comparing moderate and extreme hypofractionation (PRIME TRIAL). BMJ open. 2020;10(2):e034623. Ineligible intervention/comparison
93 Niibe Y, Karasawa K, Mitsuhashi T, Tanaka Y. Hyperfractionated radiation therapy for hypopharyngeal carcinoma compared with conventional radiation therapy: local control, laryngeal preservation and overall survival. Japanese journal of clinical oncology. 2003;33(9):450–5. Ineligible intervention/comparison14594938
94 Nowacki MP, Nasierowska-Guttmejer A, Michalski W, Bebenek M, Kryj M, Bujko K. Long-term results of a randomized trial comparing preoperative short-course radiotherapy with preoperative conventionally fractionated chemoradiation for rectal cancer. British Journal of Surgery. 2006;93(10):1215–1223. Ineligible intervention/comparison16983741
95 Olivotto IA, Weir LM, Kim-Sing C, . Late cosmetic results of short fractionation for breast conservation. Radiotherapy and Oncology. 1996;41(1):7–13. Ineligible study design8961362
96 Ottosson S, Zackrisson B, Kjellen E, Nilsson P, Laurell G. Weight loss in patients with head and neck cancer during and after conventional and accelerated radiotherapy. Acta oncologica (Stockholm, Sweden). 2013;52(4):711–8. Ineligible intervention/comparison23106176
97 Parajon SB, Payo MPP, Aguera AI, . Extreme weekly hypofractionation in breast cancer in elderly. Translational Cancer Research. 2020;9(Supplement1):S139–S145. Ineligible study design35117957
98 Park G, Kim YJ, Kim YS, Ahn H, Park W, Lee Js. Salvage hypofractionated accelerated versus standard radiotherapy for the treatment of biochemical recurrence after radical prostatectomy (SHARE): the protocol of a prospective, randomized, open-label, superiority, multi-institutional trial. Trials. 2021;22(1):728. Ineligible study design34674739
99 Perez CA, Stanley K, Rubin P, . A prospective randomized study of various irradiation doses and fractionation schedules in the treatment of inoperable non-oat-cell carcinoma of the lung. Preliminary report by the Radiation Therapy Oncology Group. Cancer. 1980;45(11):2744–53. Ineligible intervention/comparison6991092
100 Pietrzak L, Bujko K, Kepka L, . Quality of life, anorectal and sexual functions after preoperative radiotherapy for rectal cancer: Report of a randomised trial. Radiotherapy and Oncology. 2007;84(3):217–225. Ineligible intervention/comparison17692977
101 Pinto LH, Canary PC, Araujo CM, Bacelar SC, Souhami L. Prospective randomized trial comparing hyperfractionated versus conventional radiotherapy in stages III and IV oropharyngeal carcinoma. International journal of radiation oncology, biology, physics. 1991;21(3):557–62. Ineligible intervention/comparison1869454
102 Pollack A, Kwon D, Walker G, . Prospective Validation of Diagnostic Tumor Biomarkers in Men Treated With Radiotherapy for Prostate Cancer. Journal of the National Cancer Institute. 2017;109(2):1–8. Ineligible outcome
103 Poortmans PM, Collette L, Horiot J-C, . Impact of the boost dose of 10 Gy versus 26 Gy in patients with early stage breast cancer after a microscopically incomplete lumpectomy: 10-year results of the randomised EORTC boost trial. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2009;90(1):80–5. Ineligible intervention/comparison18707785
104 Poulsen M, Denham J, Spry N, . Acute toxicity and cost analysis of a phase III randomized trial of accelerated and conventional radiotherapy for squamous carcinoma of the head and neck: a Trans-Tasman Radiation Oncology Group study. Australasian radiology. 1999;43(4):487–94. Ineligible intervention/comparison10901965
105 Poulsen MG, Denham JW, Peters LJ, . A randomised trial of accelerated and conventional radiotherapy for stage III and IV squamous carcinoma of the head and neck: a Trans-Tasman Radiation Oncology Group Study. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2001;60(2):113–22. Ineligible intervention/comparison11439206
106 Prosnitz LR, Albers ME, Huang AT, . Hyperfractionated irradiation with or without concurrent chemotherapy for locally advanced head and neck cancer. New England Journal of Medicine. 1998;338(25):1798–1804. Ineligible intervention/comparison9632446
107 Quilty PM, Duncan W, Kerr GR. Results of a randomised study to evaluate influence of dose on morbidity in radiotherapy for bladder cancer. Clinical radiology. 1985;36(6):615–8. Ineligible intervention/comparison4064546
108 Rasmusson E, Gunnlaugsson A, Wieslander E, . Erectile Dysfunction and Absorbed Dose to Penile Base Structures in a Randomized Trial Comparing Ultrahypofractionated and Conventionally Fractionated Radiation Therapy for Prostate Cancer. International journal of radiation oncology, biology, physics. 2020;107(1):143–151. Ineligible outcome32004582
109 Reddy JP, Lei X, Huang S-C, . Quantitative Assessment of Breast Cosmetic Outcome After Whole-Breast Irradiation. International journal of radiation oncology, biology, physics. 2017;97(5):894–902. Ineligible outcome28333010
110 Rezvani M, Alcock CJ, Fowler JF, Haybittle JL, Hopewell JW, Wiernik G. A comparison of the normal-tissue reactions in patients treated with either 3F/Wk or 5F/Wk in the BIR (British Institute of Radiology) trial of radiotherapy for carcinoma of the laryngo-pharynx. International journal of radiation biology. 1989;56(5):717–20. Ineligible intervention/comparison2573668
111 Ringash J, Waldron JN, Siu LL, . Quality of life and swallowing with standard chemoradiotherapy versus accelerated radiotherapy and panitumumab in locoregionally advanced carcinoma of the head and neck: A phase III randomised trial from the Canadian Cancer Trials Group (HN.6). European Journal of Cancer. 2017;72:192–199. Ineligible intervention/comparison28040660
112 Saad E, Radwan RH, Hadi EA. Comparison between hypo-fractionated dose-escalated volumetric modulated arc therapy and conventional concurrent chemo-radiation in locally advanced head and neck cancer: A pilot study. Journal of Radiotherapy in Practice. 2020;19(2):132–138. Ineligible intervention/comparison
113 Sanguineti G, Giannarelli D, Petrongari MG, . Leukotoxicity after moderately Hypofractionated radiotherapy versus conventionally fractionated dose escalated radiotherapy for localized prostate Cancer: a secondary analysis from a randomized study. Radiation oncology (London, England). 2019;14(1):23. Ineligible outcome30700317
114 Sause WT, Cooper JS, Rush S, . Fraction size in external beam radiation therapy in the treatment of melanoma. International journal of radiation oncology, biology, physics. 1991;20(3):429–32. Ineligible outcome1995527
115 Schwartz DL, Sosa A, Chun SG, . SBRT for early-stage glottic larynx cancer-Initial clinical outcomes from a phase I clinical trial. PloS one. 2017;12(3):e0172055. Ineligible study design28253270
116 Scobioala S, Kittel C, Elsayad K, . A treatment planning study comparing IMRT techniques and cyber knife for stereotactic body radiotherapy of low-risk prostate carcinoma. Radiation oncology (London, England). 2019;14(1):143. Ineligible intervention/comparison31399115
117 Servagi Vernat S, Guilbert P, Bouche G, Ramiandrisoa F, Bellefqih S. Hypofractionated radiotherapy in rectal cancer for elderly patients. Cancer/Radiotherapie. 2018;22(6–7):644–646. Not published in English30166091
118 Sethukavalan P, Cheung P, Tang CI, . Patient costs associated with external beam radiotherapy treatment for localized prostate cancer: the benefits of hypofractionated over conventionally fractionated radiotherapy. The Canadian journal of urology. 2012;19(2):6165–9. Ineligible outcome22512958
119 Shah C, Badiyan S, Khwaja S, . Evaluating radiotherapy options in breast cancer: does intraoperative radiotherapy represent the most cost-efficacious option? Clinical breast cancer. 2014;14(2):141–6. Ineligible intervention/comparison24291378
120 Shi Y-s, Xu S-j, Zheng X-k, Yan W-p, Chen L-h. Therapeutic effect of three-dimensional conformal radiotherapy on locally advanced pancreatic carcinoma. Di 1 jun yi da xue xue bao = Academic journal of the first medical college of PLA. 2004;24(2):213–219. Not published in English14965832
121 Siegel R, Burock S, Wernecke K-D, . Preoperative short-course radiotherapy versus combined radiochemotherapy in locally advanced rectal cancer: a multi-centre prospectively randomised study of the Berlin Cancer Society. BMC cancer. 2009;9:50. Ineligible outcome19200365
122 Skladowski K, Maciejewski B, Golen M, . Continuous accelerated 7-days-a-week radiotherapy for head-and-neck cancer: long-term results of phase III clinical trial. International journal of radiation oncology, biology, physics. 2006;66(3):706–13. Ineligible intervention/comparison17011446
123 Storey MR, Pollack A, Zagars G, Smith L, Antolak J, Rosen I. Complications from radiotherapy dose escalation in prostate cancer: preliminary results of a randomized trial. International journal of radiation oncology, biology, physics. 2000;48(3):635–42. Ineligible intervention/comparison11020558
124 Strigari L, Arcangeli G, Arcangeli S, Benassi M. Mathematical model for evaluating incidence of acute rectal toxicity during conventional or hypofractionated radiotherapy courses for prostate cancer. International journal of radiation oncology, biology, physics. 2009;73(5):1454–60. Ineligible outcome18990503
125 Swindell R, Coote J, Stratford J, . Dose-escalated hypofractionated intensity-modulated radiotherapy in high-risk carcinoma of the prostate: Outcome and late toxicity. Prostate Cancer. 2012:450246. Ineligible study design
126 Syndikus I, Morgan RC, Sydes MR, Graham JD, Dearnaley DP. Late gastrointestinal toxicity after dose-escalated conformal radiotherapy for early prostate cancer: results from the UK Medical Research Council RT01 trial (ISRCTN47772397). International journal of radiation oncology, biology, physics. 2010;77(3):773–83. Ineligible intervention/comparison19836155
127 Tallari RV, Singh OP, Yogi V, Yadav S. Five versus ten fractions per week radiotherapy in locally advanced head and neck cancer. Journal of Cancer Research and Therapeutics. 2017;13(2):224–229. Ineligible intervention/comparison28643738
128 Thorpe CS, McGee LA, Vern-Gross TZ, . MC1635: Randomized Phase III Trial of Hypofractionated Radiotherapy to the Whole Breast After Breast Conserving Surgery. International journal of radiation oncology, biology, physics. 2021;111(3):S6–S7. Ineligible study design
129 Tsang Y, Haviland J, Venables K, Yarnold J. The impact of dose heterogeneity on late normal tissue complication risk after hypofractionated whole breast radiotherapy. Radiotherapy and oncology : journal of the European Society for Therapeutic Radiology and Oncology. 2012;104(2):143–7. Ineligible outcome22809586
130 Vargas CE, Hartsell WF, Dunn M, . Hypofractionated Versus Standard Fractionated Proton-beam Therapy for Low-risk Prostate Cancer: Interim Results of a Randomized Trial PCG GU 002. American journal of clinical oncology. 2018;41(2):115–120. Ineligible intervention/comparison26523442
131 Vargas CE, Niska JR, Keole SR, . Initial toxicity, quality-of-life outcomes, and dosimetric impact in a randomized phase 3 trial of hypofractionated versus standard fractionated proton therapy for low-risk prostate cancer. Advances in Radiation Oncology. 2018;3(3):322–330. Ineligible intervention/comparison30202801
132 Verbanck S, Hanon S, Schuermans D, . Mild Lung Restriction in Breast Cancer Patients After Hypofractionated and Conventional Radiation Therapy: A 3-Year Follow-Up. International journal of radiation oncology, biology, physics. 2016;95(3):937–945. Ineligible outcome27302510
133 Verbanck S, Hanon S, Schuermans D, . Small airways function in breast cancer patients before and after radiotherapy. Breast cancer research and treatment. 2012;135(3):857–65. Ineligible outcome22910929
134 Vicini FA, Cecchini RS, White JR, . Long-term primary results of accelerated partial breast irradiation after breast-conserving surgery for early-stage breast cancer: a randomised, phase 3, equivalence trial. Lancet (London, England). 2019;394(10215):2155–2164. Ineligible intervention/comparison31813636
135 Videtic GMM, Truong PT, Dar AR, Yu EW, Stitt LW. Shifting from hypofractionated to “conventionally” fractionated thoracic radiotherapy: a single instit’tion’s 10-year experience in the management of limited-stage small-cell lung cancer using concurrent chemoradiation. International journal of radiation oncology, biology, physics. 2003;57(3):709–16. Ineligible study design14529775
136 Voong KR, Lal LS, Kuban DA, . Long-term economic value of hypofractionated prostate radiation: Secondary analysis of a randomized trial. Advances in Radiation Oncology. 2017;2(3):249–258. Ineligible outcome29114589
137 Waldron J, Warde P, Payne D, . Durable therapeutic gain despite competing mortality in long-term follow-up of a randomized hyperfractionated radiotherapy trial for locally advanced head and neck cancer. Clinical and Translational Radiation Oncology. 2020;21:69–76. Ineligible intervention/comparison32055717
138 Wang G, Song M, Xu H, Fang Y. Prospective trial of combined hyperfractionated radiotherapy and bronchial arterial infusion of chemotherapy for locally advanced nonsmall cell lung cancer. International journal of radiation oncology, biology, physics. 1996;34(2):309–13. Ineligible intervention/comparison8567331
139 Weissberg JB, Son YH, Percarpio B, Fischer JJ. Randomized trial of conventional versus high fractional dose radiation therapy in the treatment of advanced head and neck cancer. International journal of radiation oncology, biology, physics. 1982;8(2):179–85. Ineligible intervention/comparison6806218
140 Witte M, Pos F, Incrocci L, Heemsbergen W. Association between incidental dose outside the prostate and tumor control after modern image-guided radiotherapy. Physics and Imaging in Radiation Oncology. 2021;17:25–31. Ineligible outcome33898774
141 Wolfson AH, Bae K, Komaki R, . Primary analysis of a phase II randomized trial radiation therapy Oncology Group (RTOG) 0212: Impact of different total doses and schedules of prophylactic cranial irradiation on chronic neurotoxicity and quality of life for patients with limited-disease small-cell lung cancer. International Journal of Radiation Oncology Biology Physics. 2011;81(1):77–84. Ineligible intervention/comparison20800380
142 Wortel RC, Heemsbergen WD, Smeenk RJ, . Local Protocol Variations for Image Guided Radiation Therapy in the Multicenter Dutch Hypofractionation (HYPRO) Trial: Impact of Rectal Balloon and MRI Delineation on Anorectal Dose and Gastrointestinal Toxicity Levels. International journal of radiation oncology, biology, physics. 2017;99(5):1243–1252. Ineligible intervention/comparison28943074
143 Wortel RC, Pos FJ, Heemsbergen WD, Incrocci L. Sexual Function After Hypofractionated Versus Conventionally Fractionated Radiotherapy for Prostate Cancer: Results From the Randomized Phase III HYPRO Trial. The journal of sexual medicine. 2016;13(11):1695–1703. Ineligible outcome27665195
144 Yang F, Usmani NH, Danielson BL, . Conventional vs. Hypofractionation Radiation for High-Risk Prostate Cancer Patients (CHIRP): 24 Months Patient-Reported Quality of Life Outcomes of the Randomized Phase II CHIRP Trial. International journal of radiation oncology, biology, physics. 2021;111(3):S79. Ineligible study design
145 Yeoh EE, Botten R, Russo A, . Chronic effects of therapeutic irradiation for localized prostatic carcinoma on anorectal function. International journal of radiation oncology, biology, physics. 2000;47(4):915–24. Ineligible intervention/comparison10863060
146 Yeoh EK, Holloway RH, Fraser RJ, Botten RJ, Di Matteo AC, Butters J. Pathophysiology and natural history of anorectal sequelae following radiation therapy for carcinoma of the prostate. International journal of radiation oncology, biology, physics. 2012;84(5):e593–9. Ineligible outcome22836050
147 Yom SS, Torres-Saavedra P, Caudell JJ, . Reduced-Dose Radiation Therapy for HPV-Associated Oropharyngeal Carcinoma (NRG Oncology HN002). Journal of clinical oncology : official journal of the American Society of Clinical Oncology. 2021;39(9):956–965. Ineligible intervention/comparison33507809
148 Yuan C, Wang Q. Comparative analysis of the effect of different radiotherapy regimes on lymphocyte and its subpopulations in breast cancer patients. Clinical and Translational Oncology. 2018;20(9):1219–1225. Ineligible outcome29536332
149 Zackrisson B, Modig H, Franzen L, . Two-year results from a Swedish study on conventional versus accelerated radiotherapy in head and neck squamous cell carci–oma - The ARTSCAN study. Radiotherapy and Oncology. 2011;100(1):41–48. Ineligible intervention/comparison21295880
150 Zemplenyi AT, Kalo Z, Kovacs G, . Cost-effectiveness analysis of intensity-modulated radiation therapy with normal and hypofractionated schemes for the treatment of localised prostate cancer. European journal of cancer care. 2018;27(1). Ineligible study design
151 Zilli T, Jorcano S, Bral S, . Once-a-week or every-other-day urethra-sparing prostate cancer stereotactic body radiotherapy, a randomized phase II trial: 18 months follow-up results. Cancer medicine. 2020;9(9):3097–3106. Ineligible intervention/comparison32160416
152 Zygogianni A, Platoni K, Patriki E, . A randomized study comparing two hypofractioned 3-D conformal radiotherapy for stage IIIb-IV non small cell lung cancer. Journal of BUON : official journal of the Balkan Union of Oncology. 2020;25(2):842–847. Ineligible population