# APPENDIX A SEARCH STRATEGIES

| Search Terms (MEDLINE and Embase)
1 | exp Adenocarcinoma/ or adenocarcinoma.mp.
2 | neoplasm.mp. or exp Neoplasms/
3 | (hematologic or haematologic or lymphoma or leukemia).ti,ab.
4 | 1 or 2
5 | 4 not 3
6 | Radiation Dose Hypofractionation/ or (radiotherapy minibeam$1 or radiation hypofractionated dose or radiation dose hypofractionation or hypofractionated radiation therapy or short?course radiation therapy).ti,ab.
7 | dose fractionation/ or dose response relationship, radiation/ or radiotherapy dosage/
8 | ((radiotherapy* or radiat*) adj2 (dose or dosage or regimen* or schedule*)).tw.
9 | hypofractionat*.mp.
10 | hypo-fraction*.mp.
11 | multi-fraction*.tw.
12 | (hypo adj3 fraction*).tw.
13 | Stereotactic body radiation therapy/ or SBRT.mp.
14 | Stereotactic ablative body radiation therapy/ or SABR.mp.
15 | (Stereotactic body radiation therapy or SBRT).tw.
16 | (Stereotactic ablative body radiation therapy or SABR).tw.
17 | or/6-16
18 | 5 and 17
19 | Randomized controlled trial.pt. or randomized.mp. or placebo.mp.
‘21 | (‘clinical ’trial‘ or 'randomized controlled ’study‘ or 'randomized controlled ’rial‘ or 'double blind clinical ’study‘ or 'single blind clinical ’tudy‘ or 'random alloc’tion').ti,ab.
22 | (meta-analy$ or metaanaly$ or meta analy$).tw. or exp Meta-Analysis/ or (systematic adj (review$ or overview$)).tw. or (systematic review or literature review or rapid review or umbrella review or meta synthesis or metasynthesis or meta-analysis or meta-synthesis or integrative review or data synthesis or comparative effectiveness review).mp
23 | or/19-22
24 | (Animals/ or Models, Animal/ or Disease Models, Animal/) not Humans/
25 | ((animal or animals or canine* or cat or cats or dog or dogs or feline or goat or hamster* or horse or lamb or lambs or mice or monkey or monkeys or mouse or murine or pig or pigs or piglet* or porcine or primate* or rabbit* or rats or rat or rodent* or sheep98urrent98ryrinar*) not (human* or patient*)).ti,kf,jw.
26 | 24 or 25
27 | 23 not 26
28 | 18 and 27
29 | limit 28 to (case reports or comment or editorial or letter or news or newspaper article or personal narrative or conference abstract) [Limit not valid in Embase; records were retained]
30 | 28 not 29
31 | limit 398urrentglish language
32 | (child or children or pediat* or neonat*).ti,ab.
33 | 31 not 32
| Removed duplicates in EndNote
| Removed “childhood” cancer articles in EndNote
| Removed “commentary” articles in EndNote
| Removed “abstract” in EndNote
| Removed “annual meeting” in EndNote
| Removed “conference”, “proceedings”, and “symposium” in EndNote
| Removed duplicates in Distiller