# ABBREVIATIONS TABLE

Abbreviation: Definition
AE: Adverse event
AHRQ: Agency for Healthcare Research and Quality
APBI: Accelerated partial breast irradiation
ARD: Absolute risk difference
ASTRO: American Society for Radiation Oncology
BCQ: Breast cancer questionnaire
CC: Coordinating Center
CDC: Centers for Disease Control and Prevention
CI: Confidence interval
COE: Certainty of evidence
CTCAE: Common Terminology Criteria for Adverse Events
DCIS: Ductal carcinoma in situ
DFS: Disease-free survival
EBRT: External Beam Radiation Therapy
EORTC QLQ-C30: European Organization for Research and Treatment core quality of life questionnaire
ESP: Evidence Synthesis Program
FACT-B: Functional assessment of cancer therapy for breast cancer
FACT-G: Functional assessment of cancer therapy – general
GI: Gastrointestinal
GRADE: Grading of Recommendations, Assessment, Development, and Evaluation
GU: Genitourinary
HR: Hazard ratio
IMRT: Intensity-modulated radiation therapy
KQ: Key Question
LR: Local recurrence
LRR: Local-regional recurrence
MeSH: Medical Subject Heading
NCI: National Cancer Institute
NSCLC: Non-small cell lung carcinoma
NPC: Nasopharyngeal carcinoma
NR: Not repored
OS: Overall survival
PRISMA: Preferred Reporting Items for Systematic Reviews and Meta Analyses
QOL: Quality of life
RCT: Randomized controlled trial
RoB: Risk of bias
RR: Risk ratio
RTOG: Radiation Therapy Oncology Group
SABR: Stereotactic ablative body radiation therapy
SBRT: Stereotactic body radiation therapy
SCLC: Small cell lung cancer
SR: Systematic review
TEP: Technical expert panel
UK: United Kingdom
US: United States
VA: Department of Veterans Affairs
WBI: Whole breast irradiation