# REFERENCES

1 National Ambulatory Medical Care Survey: 2018 National Summary Tables. https://www.cdc.gov/nchs/data/ahcd/namcs_summary/2018-namcs-web-tables-508.pdf
2 Thygesen K, Alpert JS, Jaffe AS, . Fourth Universal Definition of Myocardial Infarction (2018). Circulation. Nov 13 2018;138(20):e618–e651. doi:10.1161/cir.0000000000000617 30571511
3 Amsterdam EA, Wenger NK, Brindis RG, . 2014 AHA/ACC guideline for the management of patients with non-ST-elevation acute coronary syndromes: executive summary: a report of the American College of Cardiology/American Heart Association Task Force on Practice Guidelines. Circulation. Dec 23 2014;130(25):2354–94. doi:10.1161/cir.0000000000000133 25249586
4 Herren KR, Mackway-Jones K. Emergency management of cardiac chest pain: a review. Emergency Medicine Journal. 2001;18(1):6–10. doi:10.1136/emj.18.1.6 11310466
5 Lane BH, Mallow PJ, Hooker MB, Hooker E. Trends in United States emergency department visits and associated charges from 2010 to 2016. Am J Emerg Med. Aug 2020;38(8):1576–1581. doi:10.1016/j.ajem.2019.158423 31519380
6 Lee TH, Goldman L. Evaluation of the Patient with Acute Chest Pain. New England Journal of Medicine. 2000;342(16):1187–1195. doi:10.1056/nejm200004203421607 10770985
7 Kaier TE, Alaour B, Marber M. Cardiac troponin and defining myocardial infarction. Cardiovascular Research. 2021;117(10):2203–2215. doi:10.1093/cvr/cvaa331 33458742
8 Stark M KC, Sharma S. Troponin In: StatPearls [Internet]. Treasure Island (FL): StatPearls Publishing; 2022.
9 Mahajan VS, Jarolim P. How to interpret elevated cardiac troponin levels. Circulation. Nov 22 2011;124(21):2350–4. doi:10.1161/circulationaha.111.023697 22105197
10 Body R, Mahler S. Welcome to the Real World: Do the Conditions of FDA Approval Devalue High-sensitivity Troponin? Academic Emergency Medicine. 2017;24(10):1278–1280. doi:10.1111/acem.13256 28715149
11 Howell SJ, Amsterdam EA, Mumma BE, López JE, Tran NK. Implementation of High-Sensitivity Cardiac Troponin: Challenges From the International Experience. Crit Pathw Cardiol. Dec 2018;17(4):173–178. doi:10.1097/hpc.0000000000000156 30418246
12 Gulati M, Levy PD, Mukherjee D, . 2021 AHA/ACC/ASE/CHEST/SAEM/SCCT/SCMR Guideline for the Evaluation and Diagnosis of Chest Pain: A Report of the American College of Cardiology/American Heart Association Joint Committee on Clinical Practice Guidelines. J Cardiovasc Comput Tomogr. Jan–Feb 2022;16(1):54–122. doi:10.1016/j.jcct.2021.11.009 34955448
13 Lee CC, Huang SS, Yeo YH, . High-sensitivity-cardiac troponin for accelerated diagnosis of acute myocardial infarction: A systematic review and meta-analysis. Am J Emerg Med. Jul 2020;38(7):1402–1407. doi:10.1016/j.ajem.2019.11.035 31932131
14 Collet JP, Thiele H, Barbato E, . 2020 ESC Guidelines for the management of acute coronary syndromes in patients presenting without persistent ST-segment elevation. Eur Heart J. Apr 7 2021;42(14):1289–1367. doi:10.1093/eurheartj/ehaa575 32860058
15 Mueller C, Giannitsis E, Christ M, . Multicenter Evaluation of a 0-Hour/1-Hour Algorithm in the Diagnosis of Myocardial Infarction With High-Sensitivity Cardiac Troponin T. Ann Emerg Med. Jul 2016;68(1):76–87.e4. doi:10.1016/j.annemergmed.2015.11.013 26794254
16 Neumann JT, Sörensen NA, Schwemer T, . Diagnosis of Myocardial Infarction Using a High-Sensitivity Troponin I 1-Hour Algorithm. JAMA Cardiol. Jul 1 2016;1(4):397–404. doi:10.1001/jamacardio.2016.0695 27438315
17 Twerenbold R, Neumann JT, Sörensen NA, . Prospective Validation of the 0/1-h Algorithm for Early Diagnosis of Myocardial Infarction. J Am Coll Cardiol. Aug 7 2018;72(6):620–632. doi:10.1016/j.jacc.2018.05.040 30071991
18 Pickering JW, Than MP, Cullen L, . Rapid Rule-out of Acute Myocardial Infarction With a Single High-Sensitivity Cardiac Troponin T Measurement Below the Limit of Detection: A Collaborative Meta-analysis. Ann Intern Med. May 16 2017;166(10):715–724. doi:10.7326/m16-2562 28418520
19 Wallace BC, Trikalinos TA, Lau J, Brodley C, Schmid CH. Semi-automated screening of biomedical citations for systematic reviews. BMC Bioinformatics. Jan 26 2010;11:55. doi:10.1186/1471-2105-11-55 20102628
20 Sterne JA, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. bmj. 2016;355
21 Sterne JA, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. bmj. 2019;366
22 Guyatt GH, Oxman AD, Vist GE, . GRADE: an emerging consensus on rating quality of evidence and strength of recommendations. Bmj. Apr 26 2008;336(7650):924–6. doi:10.1136/bmj.39489.470347.AD 18436948
23 Anand A, Lee KK, Chapman AR, . High-Sensitivity Cardiac Troponin on Presentation to Rule Out Myocardial Infarction: A Stepped-Wedge Cluster Randomized Controlled Trial. Circulation. Jun 8 2021;143(23):2214–2224. doi:10.1161/circulationaha.120.052380 33752439
24 Than MP, Pickering JW, Aldous SJ, . Effectiveness of EDACS Versus ADAPT Accelerated Diagnostic Pathways for Chest Pain: A Pragmatic Randomized Controlled Trial Embedded Within Practice. Ann Emerg Med. Jul 2016;68(1):93–102.e1. doi:10.1016/j.annemergmed.2016.01.001 26947800
25 Barnes C, Fatovich DM, Macdonald SPJ, . Single high-sensitivity troponin levels to assess patients with potential acute coronary syndromes. Heart. May 2021;107(9):721–727. doi:10.1136/heartjnl-2020-317997 33436490
26 Hyams JM, Streitz MJ, Oliver JJ, . Impact of the HEART Pathway on Admission Rates for Emergency Department Patients with Chest Pain: An External Clinical Validation Study. J Emerg Med. Apr 2018;54(4):549–557. doi:10.1016/j.jemermed.2017.12.038 29478861
27 Sandeman D, Syed MBJ, Kimenai DM, . Implementation of an early rule-out pathway for myocardial infarction using a high-sensitivity cardiac troponin T assay. Open Heart. Nov 2021;8(2)doi:10.1136/openhrt-2021-001769
28 Stoyanov KM, Hund H, Biener M, . RAPID-CPU: a prospective study on implementation of the ESC 0/1-hour algorithm and safety of discharge after rule-out of myocardial infarction. Eur Heart J Acute Cardiovasc Care. Feb 2020;9(1):39–51. doi:10.1177/2048872619861911 31298551
29 Than MP, Pickering JW, Adamson P, . Reducing Patient Risk and Enhancing Care Through the Development and Implementation of a New Chest Pain Pathway, Expedited by and for the COVID-19 Era. Ejifcc. Feb 2021;32(1):27–40.33753972
30 Chew DP, Lambrakis K, Blyth A, . A Randomized Trial of a 1-Hour Troponin T Protocol in Suspected Acute Coronary Syndromes: The Rapid Assessment of Possible Acute Coronary Syndrome in the Emergency Department With High-Sensitivity Troponin T Study (RAPID-TnT). Circulation. Nov 5 2019;140(19):1543–1556. doi:10.1161/circulationaha.119.042891 31478763
31 Conde D, Costabel JP, Lambardi F. Algorithm for probable acute coronary syndrome using high-sensitivity troponin T assay vs fourth-generation troponin T assay. Am J Emerg Med. Aug 2013;31(8):1226–9. doi:10.1016/j.ajem.2013.05.045 23810070
32 Crowder KR, Jones TD, Lang ES, . The impact of high-sensitivity troponin implementation on hospital operations and patient outcomes in 3 tertiary care centers. Am J Emerg Med. Dec 2015;33(12):1790–4. doi:10.1016/j.ajem.2015.08.041 26387473
33 Ford JS, Chaco E, Tancredi DJ, Mumma BE. Impact of high-sensitivity cardiac troponin implementation on emergency department length of stay, testing, admissions, and diagnoses. Am J Emerg Med. Jul 2021;45:54–60. doi:10.1016/j.ajem.2021.02.021 33662739
34 Ljung L, Lindahl B, Eggers KM, . A Rule-Out Strategy Based on High-Sensitivity Troponin and HEART Score Reduces Hospital Admissions. Ann Emerg Med. May 2019;73(5):491–499. doi:10.1016/j.annemergmed.2018.11.039 30661856
35 Suh EH, Tichter AM, Ranard LS, . Impact of a rapid high-sensitivity troponin pathway on patient flow in an urban emergency department. J Am Coll Emerg Physicians Open. Jun 2022;3(3):e12739. doi:10.1002/emp2.12739 35571147
36 Sweeney M, Bleeze G, Storey S, . The impact of an acute chest pain pathway on the investigation and management of cardiac chest pain. Future Healthcare Journal. 2020;7(1):53.32104767
37 Twerenbold R, Costabel JP, Nestelberger T, . Outcome of Applying the ESC 0/1-hour Algorithm in Patients With Suspected Myocardial Infarction. J Am Coll Cardiol. Jul 30 2019;74(4):483–494. doi:10.1016/j.jacc.2019.05.046 31345421
38 Vigen R, Diercks DB, Hashim IA, . Association of a Novel Protocol for Rapid Exclusion of Myocardial Infarction With Resource Use in a US Safety Net Hospital. JAMA Netw Open. Apr 1 2020;3(4):e203359. doi:10.1001/jamanetworkopen.2020.3359 32320036
39 Costabel JP, Conde D, Lambardi F, . Evaluation of a new diagnostic algorithm for acute coronary syndrome using high-sensitivity troponin T assay. Revista Argentina de Cardiología. 2014;82(4):316–321.
40 Twerenbold R, Jaeger C, Rubini Gimenez M, . Impact of high-sensitivity cardiac troponin on use of coronary angiography, cardiac stress testing, and time to discharge in suspected acute myocardial infarction. Eur Heart J. Nov 21 2016;37(44):3324–3332. doi:10.1093/eurheartj/ehw232 27357358
41 Ambavane A, Lindahl B, Giannitsis E, . Economic evaluation of the one-hour rule-out and rule-in algorithm for acute myocardial infarction using the high-sensitivity cardiac troponin T assay in the emergency department. PLoS One. 2017;12(11):e0187662. doi:10.1371/journal.pone.0187662 29121105
42 Reinhold T, Giannitsis E, Möckel M, . Cost analysis of early discharge using combined copeptin/cardiac troponin testing versus serial cardiac troponin testing in patients with suspected acute coronary syndrome. PLoS One. 2018;13(8):e0202133. doi:10.1371/journal.pone.0202133 30138394
43 Kaushik N, Khangulov VS, O’Hara M, Arnaout R. Reduction in laboratory turnaround time decreases emergency room length of stay. Open Access Emerg Med. 2018;10:37–45. doi:10.2147/oaem.S155988 29719423
44 Li L, Georgiou A, Vecellio E, . The effect of laboratory testing on emergency department length of stay: a multihospital longitudinal study applying a cross-classified random-effect modeling approach. Acad Emerg Med. Jan 2015;22(1):38–46. doi:10.1111/acem.12565 25565488
45 Winchester DE, Betageri O, Perche P, Allen B, Theis R. Implementation of a High-Sensitivity Troponin-I Assay in an Academic Medical Center: A Qualitative and Quantitative Assessment. J Invasive Cardiol. Jul 2021;33(7):E549–e556.34224384
46 Six AJ, Backus BE, Kelder JC. Chest pain in the emergency room: value of the HEART score. Neth Heart J. Jun 2008;16(6):191–6. doi:10.1007/bf03086144 18665203
47 Granger CB, Goldberg RJ, Dabbous O, . Predictors of Hospital Mortality in the Global Registry of Acute Coronary Events. Archives of Internal Medicine. 2003;163(19):2345–2353. doi:10.1001/archinte.163.19.2345 14581255
48 Antman EM, Cohen M, Bernink PJLM, . The TIMI Risk Score for Unstable Angina/Non–ST Elevation MIA Method for Prognostication and Therapeutic Decision Making. JAMA. 2000;284(7):835–842. doi:10.1001/jama.284.7.835 10938172
49 Mueller C, Boeddinghaus J, Nestelberger T. Downstream Consequences of Implementing High-Sensitivity Cardiac Troponin. Journal of the American College of Cardiology. 2021;77(25):3180–3183. doi:doi:10.1016/j.jacc.2021.04.063 33957240
50 McCarthy C, Li S, Wang TY, . Implementation of high-sensitivity cardiac troponin assays in the United States. Journal of the American College of Cardiology. 2023;81(3):207–219.36328155
51 Winchester DE. Implementation of high sensitivity troponin in a veterans health system: Lessons learned. Vessel Plus. 2021;5:1.
52 Beattie WS, Lalu M, Bocock M, . Systematic review and consensus definitions for the Standardized Endpoints in Perioperative Medicine (StEP) initiative: cardiovascular outcomes. Br J Anaesth. Jan 2021;126(1):56–66. doi:10.1016/j.bja.2020.09.023 33092804
53 Devereaux PJ, Yang H, Yusuf S, . Effects of extended-release metoprolol succinate in patients undergoing non-cardiac surgery (POISE trial): a randomised controlled trial. Lancet. May 31 2008;371(9627):1839–47. doi:10.1016/s0140-6736(08)60601-7 18479744
54 Committee for Medicinal Products for Human Use (CHMP). European Medicines Agency. Reflection paper on assessment of cardiovascular safety profile of medicinal products. 2016 https://www.ema.europa.eu/en/documents/scientific-guideline/reflection-paper-assessment-cardiovascular-safety-profile-medicinal-products_en.pdf.