# ACKNOWLEDGMENTS

The authors are grateful to Gaelen Adam, MLIS for literature searching and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Chad Kessler, MD MBA
  National Director
  VA Emergency Medicine
- Neil Patel, MD
  Acting Deputy National Program Director
  VA Emergency Medicine
- Douglas Villard, MD
  Emergency Department Medical Director
  Fayetteville VAMC

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Dianna Langdon, MD
  Emergency Medicine Chief
  Albany Stratton VAMC
- Roy Keys, MD
  Emergency Medicine Physician
  Fayetteville VAMC
- John Vallone, MD
  Chief
  VHA Pathology and Laboratory Medicine
- Keith Kocher, MD, MPH
  Emergency Medicine Physician
  Ann Arbor VAMC

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix D for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.