# DISCUSSION

We identified 17 primary studies that reported 23 ADPs. Only a single study compared an ADP to hs-cTn without an ADP. Six studies compared different ADPs and 10 single group studies evaluated a single ADP. Two comparative studies were RCTs and 4 were NRCSs. Four studies compared ADPs with different hs-cTn timings and 2 studies compared ADPs with similar hs-cTn timing but different risk scores. The most frequently evaluated outcome was ED length of stay. We evaluated overall certainty of evidence for all comparative studies. No studies were conducted in the VA system. Key findings include the following:

- ADPs with hs-cTn may increase discharges to the community but may not impact clinical outcomes.
- Use of ADP with hs-cTn compared to no ADP may be associated with reduced ED resource use.
  ○ Use of an ADP with hs-cTn is associated with more discharges from the ED to the community and no difference in 30-day MACE, MI, death, and cardiac testing (low confidence for all findings).
  ○ It is unknown if use of an ADP with hs-cTn is associated with differences in revascularization (very low confidence). No study reported ED length of stay, 30-day return to the ED or hospital, cardiac testing, or hospital length of stay for an ADP with hs-cTn compared to no ADP.
- Use of ADPs with shorter compared to longer hs-cTn timing is probably associated with reduced ED use, but not associated with cardiovascular events.
  ○ Shorter ADP protocols are probably associated with shorter ED length of stay and more discharges to the community (moderate confidence).
  ○ Shorter ADP protocols are probably not associated with the proportion of patients who experience 30-day MACE or MI (moderate confidence) and, maybe, death rates (low confidence).
- Use of ADPs with different risk scores (but with similar hs-cTn timing) probably does not affect cardiovascular events, but ADPs that use the HEART rather than the TIMI risk score may decrease ED length of stay and increase discharge to the community form ED (low confidence for all findings).
- No study compared ADPs with 1-hour versus 2-hour (or other time) delta troponins.
- There was sparse reporting of data on the effectiveness of ADPs in patients triaged to a grey or observation zone, and on differences in outcomes based on patient characteristics like gender and chest pain duration.
- All ADPs appear to successfully stratify patients based on their risks of 30-day MACE, MI, and death.

Rapid rule in or rule out of MI has the potential to reduce ED overcrowding and health care costs.^41,42^ To facilitate rapid triage, ED providers and administrators can choose from multiple described ADPs, which may have to be tailored to fit local structural needs. We identified 23 ADPs that varied in complexity, hs-cTn variation (I or T), hs-cTn timing, use of risk score, and other features. Unfortunately, heterogeneity across studies in ADPs, how patients were stratified and analyzed, and study design make comparisons challenging. No 2 studies compared the same ADPs. Studies stratified patients into multiple (often poorly defined) overlapping risk categories (eg, rule out, low risk, discharge).

Most comparative studies used a pre-post design. That is, they evaluated the effect of an ED’s implementation of a new ADP on clinical and health service use outcomes, compared with their prior ADP. This is a pragmatic approach with strong internal validity to understand the effects of an ADP on outcomes. However, findings from these studies may not generalize to an average ED, because the EDs reporting these studies likely implemented ADPs that they believed would be successful in their health system. There are many factors that may impact the ability to implement an ADP and quickly diagnose patients. For example, the ability to execute a specific hs-cTn timing (eg, 0/1) depends on resources for rapid serial blood draws and labs being able to process specimens within a defined time. Fast lab turnaround times may not be feasible in low resource hospitals.^43–45^ Successful implementation also depends on support across service lines from the ED, lab, and inpatient units.^11^ For example, the HEART score was the most commonly employed risk score. HEART was developed for implementation in the ED, is relatively easy to administer/calculate, and many ED providers are familiar with the tool,^46^ although other providers may be less familiar with HEART. TIMI and GRACE, also employed in several ADPs, were initially developed to determine whether patients need invasive therapy and not for the evaluation of chest pain, and ED staff may be less comfortable with using them.^47,48^ These measures are more relevant for risk stratifying and managing those with MI. One eligible study found a HEART-based ADP was associated with shorter length of stay and ED discharge compared with TIMI ADP, but the effect cannot be solely attributed to the use of HEART.^25^ The ADPs differed on several factors, including use of chest pain duration as a feature and employing different times patients were eligible for discharge from first hs-cTn. In general, across studies, multiple points of variation between ADPs makes it challenging to know whether a specific risk score-based ADP would be effective in an average ED.

One would not expect ADPs to substantively change the rate of within-ED MI or MACE, but they may affect the timing of final diagnosis (rule in or rule out MI), which help (or hinder) more rapid appropriate management (of MI or alternative diagnosis). When hs-cTn was introduced, there was concern that that more rapid (or delayed) diagnoses could impact both clinical outcomes and health system resources (eg, more downstream testing).^49,50^ However, limited data from the included comparative studies did not find differences between ADPs and outcomes other than ED length of stay. Limited data by ADP disposition (eg, rule out or low risk versus rule in or high risk) demonstrate that the use of ADPs enabled appropriate patient triage. Most patients where triaged to rule out, low risk, or a discharge group. As expected, patients triaged to rule in or higher risk generally had more clinical events than patients triaged to low risk or rule out. In the latter group, poor clinical outcomes were rare. Even among high-risk patients, 30-day MACE, MI, and mortality are relatively rare events, and many of the studies may have been underpowered to detect differences between ADPs. In comparative studies, ADPs with shorter compared to longer hs-cTn timing were able to meaningfully reduce ED length of stay. These between ADP studies are supported by single group data that show ADPs with up to 12 hours of hs-cTn have considerably longer ED length of stay than ADPs with up to 6 hours of hs-cTn timing. These findings imply ADPs with 12 hour hs-cTn timing may increase ED congestion without clinical benefit.

Variation across studies in analytic comparisons and definitions presented substantial challenges for interpretation and synthesis of results. The ADPs are complex and with varying structures that at times were poorly reported. Relatedly, the studies applied different terminology to describe similar concepts for ADP disposition. Some studies used terms such as rule in or rule out, while others described populations as being high risk or low risk. The description of a grey or observation zone and associated follow-up care was also inconsistently reported. Studies also varied in the reporting of outcomes by ADP disposition and not all studies reported outcomes by disposition. This presented a major challenge when interpreting single group design studies. ED length of stay was reported in nearly all studies; however, there was sparse reporting of clinical data. As expected, the definition of MACE varied between studies. Most studies that reported clinical data relied on electronic medical records or other administrative data and did not use independent outcome adjudicators. Thus, it is generally difficult to determine with high certainty the effect of any single ADP on clinical and health service use outcomes.

## IMPLICATIONS FOR VA POLICY

No study was conducted in the VA. Furthermore, only 1 comparative study^26^ and 3 single group studies were conducted in the US.^33,35,38^ Although most studies included a majority of men (range 46%–64%), the VA population is 89% male. hs-cTn assays can be interpreted with a general or sex-specific cutoff and the selection of threshold may impact ADP disposition.^11^ Only 1 eligible study reported outcomes within an ADP between males and females, and it found no difference in 30-day MACE.^37^

Most studies were conducted in countries with integrated health systems, which may influence how an ADP is implemented and the consequences of mis-stratification (eg, inappropriate discharge or admission). For example, health systems with well-coordinated outpatient care may be positioned to discharge more patients knowing they will receive timely follow-up care. Unfortunately, most of the studies only reported on the structure of the ADP and provided minimal detail on protocols to ensure timely follow-up. As a large integrated health system, VA Medical Centers may be well positioned to implement ADPs, as long as they have established protocols to ensure outpatient follow-up.

As the VA moves to include hs-cTn in ED clinical pathways,^45^ there are clear opportunities for system-level implementation. The VA can leverage its system and purchasing capacity to identify a single hs-cTn manufacturer, develop timing and measurement standards, and build the necessary normative ranges for the Veteran population. Supporting a common ADP would allow infrastructure developments in the electronic medical record, universal data collection, process measure construction, and outcome development necessary to create a high-reliability system for chest pain management. The ADPs typically incorporated features (eg, clinical history) that are already captured in the medical record, but often unstandardized in collection. As a high-reliability organization, the VA could automate a standard ADP that pulls relevant data from the medical record to generate a disposition suggestion (eg, rule in). Finally, the VA could create a system for routing Veterans who were at high risk but ruled out into important prevention programs such as preventive cardiology and cardiac rehabilitation.

This review summarizes evidence regarding the effect of hs-cTn ADPs on clinical and health care utilization outcomes. Most comparative studies were conducted in health systems that already had experience implementing an ADP. The relative complexity of hs-cTn and ADPs may hamper their implementation; however, we did not evaluate implementation outcomes as part of this review. Importantly, any system adopting an ADP should be aware of the natural variation between troponin I and T. The ADPs in the included studies used both variants, but the 2 troponin markers are not interchangeable, which may pose challenges to standardizing an ADP across sites. Other barriers to implementation of ADPs with hs-cTn within the VA may be cost and availability of the hs-cTn laboratory test. Costs may be magnified by protocols that require serial hs-cTn.^11^ Other challenges to implementation include updating clinical workflows and obtaining buy in from providers across service lines including ED, pathology, laboratory, and cardiology.^11^ Many VA EDs are staffed by part-time providers who have limited familiarity with local protocols or may not have the resources/training to perform additional point-of care testing such as echocardiography. Finally, 1 large academic-affiliated VA Medical Center’s transition from cTn to hs-cTn (without an ADP) may provide helpful lessons.^45,51^ The process of implementing hs-cTn took 6 months, required a multidisciplinary team, and a series of educational interventions. Even after implementation and the educational interventions, providers initially reported challenges interpreting hs-cTn. Furthermore, hs-cTn alone was perceived as providing limited additional benefit.^45^ Implementing an ADP with complex decision rules would likely take more time and resources.

## RESEARCH GAPS/FUTURE RESEARCH

A number of observational studies have computationally derived and evaluated the performance of proposed hs-cTn ADPs.^18^ However, we found only a few studies that evaluated hs-cTn ADPs implemented in routine practice and even fewer that compared ADPs implemented in practice. Heterogeneity in ADPs and comparative data presents challenges to determine the causal effect of a specific ADP on outcomes. In addition, ADP complexity makes it challenging to determine the effect of specific ADPs features (eg, risk score) on outcomes. To address this gap, there is a need for repeat comparative studies of already-studied ADPs, with an eye toward comparisons of ADP duration and, separately, ADP complexity. There is also a need for comparisons of ADP implementation in different hospital and geographic settings (eg, urban/rural and low-resource/high-resource communities). It is also important to understand whether hs-cTn ADPs can be successfully and safely implemented in US EDs that may not be part of large integrated health systems. Very few included studies reported outcomes by subgroups. There is an opportunity to conduct secondary database analyses to identify effects of ADPs in different subgroups (eg, sex and chest pain duration).

ADPs stratified patients into different risk groups, but studies used inconsistent and poorly defined terminology to describe such groups. Use of standardized, clinically meaningful, and interpretable risk categorizations is needed. ADPs should categorize patients as rule in, rule out, grey zone rule out and grey zone rule in and clearly define terms that do not correspond to clinical disposition (eg, low risk that is not equivalent to rule out). In addition, all studies, whether comparative or single group, should report important clinical and resource outcomes by risk categories. Related to terminology, each study uniquely defined MACE. This challenge is not unique to the ADP literature and there are competing consensus statements on definitions of MACE.^52,53,54^

## LIMITATIONS

This evidence review has several limitations. The focus of the review was on the effect and not the implementation of hs-cTn ADPs. The organizational factors that affect implementation may be important for clinical and health service use outcomes. Relatedly, we did not evaluate the factors that make an ED, hospital, or health system a strong candidate to implement an hs-cTn ADP. We excluded studies or data from studies that implemented a conventional troponin. We did this because evidence is consistent that the performance of hs-cTn is superior to conventional troponin. However, hs-cTn is relatively new in the US and many EDs, including those in the VA, may still be using conventional troponin. Outpatient care and ED structure may also be different between VA EDs and the mostly international EDs that implemented ADPs in the eligible studies. We categorized some outcomes for high-risk patients if an ADP implied this categorization even if the term was not explicitly used. Finally, depending on one’s perspective, an additional limitation is that we included only studies evaluating real-world implementation of ADPs and we excluded numerous studies of theoretical ADPs, which may have provided some further insights.

## CONCLUSIONS

ADPs can help standardize practice, which may avoid overuse of health services and reduce ED congestion. ADPs with shorter compared to longer hs-cTn timing may reduce ED length of stay, increase discharges to the community, and probably are not associated with changes in 30-day MACE, MI, or mortality. Use of an ADP (with hs-cTn), compared to no ADP, may be associated with reduced admissions, but without worsening clinical outcomes. An ADP that used HEART may be associated with shorter ED length of stay than a TIMI-based ADP, but with no difference in clinical outcomes. Among ADPs that reduce ED length of stay, there is no clear or obvious best choice. For an ED that seeks to implement an ADP, the best option will be based on the available evidence (eg, validated risk tools and hs-cTn timing), but the specific structure likely will need to be tailored to local context and preferences. Findings were limited due to great variability across studies in evaluated ADPs and inconsistent reporting and analyses. These findings may generalize to the VA, which is a large integrated care system capable of providing follow-up outpatient care. More comparative studies evaluating a homogenous set of ADPs with rigorous analysis of a range of clinical and resource-related outcomes are required to determine the effects of ADPs and comparisons between ADPs.