# RESULTS

## LITERATURE FLOW

Of 6,591 unique titles and abstracts screened, 377 articles underwent full-text review, and ultimately 17 primary studies (reported in 18 articles) were eligible and included (Figure 1). The 17 primary studies evaluated 23 ADPs. Studies excluded at full-text review are available in Appendix B. The most common reasons for exclusion of articles were the ADP was not clinically applied in an ED (128 articles) and the study did not evaluate an ADP (122 articles). In the next sections, we describe the evidence base and 23 ADPs; evaluate the evidence of ADP use versus no ADP followed by comparisons of different ADPs; and conclude by summarizing evidence about how well ADPs stratify patients by risk of cardiovascular events.

## LITERATURE OVERVIEW

Seventeen studies (in 18 publications) reported 23 ADPs with hs-cTn. Table 2 shows the characteristics of the eligible studies. Study designs varied and included 2 RCTs,^23,24^ 5 NRCSs^25–29^ and 10 single group designs^30–39^ (these include 8^30–39^ comparative studies from which we evaluated only a single eligible study group). Six of the 7 comparative studies included an ADP as a comparator;^23–25,27–29^ in contrast only 1 study compared an ADP with hs-cTn to hs-cTn without an ADP.^26^ Of the 10 single group studies, 1 was a RCT evaluated as a single group design^30^ and 7 were NRCSs evaluated as a single group design.^30–39^ We analyzed these 8 studies as single group designs since the comparator employed a standard troponin, which did not meet our inclusion criteria.

Appendix F shows the study design details including study-level eligibility criteria. One RCT conducted in Scotland was large (N = 31,492)^23^ and the second RCT conducted in New Zealand included 558 patients.^24^ Both RCTs had independent outcome assessors for the clinical measures and overall low risk of bias for clinical and health service measures. Five NRCSs included 18,377 participants total and all used a pre-post design, which consisted of evaluating a hospital or health systems change in ADP.^25–29^ For example, Sandeman et al compared a “pre” period during which patients received a local ED’s standard 0/6/12 GRACE ADP and a “post” period when the ED introduced a new 0/3/6 ADP.^27^ One of the NRCSs had blinded or independent outcome adjudicators for the clinical measures,^28^ and the remaining 4 either relied on record linkage (eg, electronic medical record) or did not describe how clinical outcomes were determined.^25–27,29^ Four of the NRCSs analyzed at least some outcomes using multivariate regression to control for possible confounders.^25–28^ One NRCS conducted only crude (unadjusted) analyses.^29^ The 10 single group studies included 44,016 patients. Six of the single group studies either did not describe how they assessed clinical outcomes or relied on record linkage (all medium risk of bias for measurement of clinical measures).^30–39^

Study eligibility criteria were consistent across studies. All studies included patients with either chest pain or symptoms suggestive of acute coronary syndrome. Fourteen studies explicitly excluded patients with STEMI.^23–32,34,35,37,39^ As presented in summary tables below and discussed in various design-specific sections, the outcomes evaluated across studies varied and included ED length of stay (N = 15), 30-day mortality (N = 12), discharge to the community (N = 11), 30-day MI (N = 10), revascularization (N = 10), return to ED or hospital (N = 9), cardiac testing (N = 8), and 30-day MACE (N =5).

Figure 1 Literature Flowchart

Abbreviations. ADP=accelerated diagnostic protocol.

Table 2 Summary Characteristics of Eligible Studies

Characteristics | RCT; (n=2) | NRCS; (n=5) | Single Group; (n=10)^a^
Risk of Bias for Clinical Measures
Low | 2 | - | 5^b^
Medium | - | 4 | 4
High | - | 1 | -
Risk of Bias for Health Service Use Measures
Low | 2 | 4 | 10
Medium | - | - | -
High | - | 1 | -
Funding
Industry | - | 1 | -
Non-industry | 2 | 1 | 2
Both industry and non-industry | - | 1 | 3
Not reported | - | 2 | 5
Countries
United States | - | 1 | 3
Canada | - | - | 1
Europe (multiple countries) | 1 | 2 | 1^c^
Australia | - | 1 | 1
New Zealand | 1 | 1
Argentina | - | - | 2
Sweden | - | - | 1
United Kingdom | - | - | 1
Centers
Single emergency department | 1 | 5 | 5
Multiple emergency departments | 1 | - | 5
High-sensitivity Troponin Manufacturer ^d^
Roche | - | 3 | 6
Abbott | 2 | 2 | 2
Siemens | - | - | -
Not reported | - | - | 3
Risk Score ^d^
HEART | - | 2 | 4
TIMI | 1 | 1 | 1
EDACS | 1 | 2 | -
GRACE | - | 1 | 1
Maximum Serial Troponin Timing ^d^
1 hr | - | - | 4
2 hr | 1 | 1 | 1
3 hr | 1 | 1 | 5
6 hr | 1 | 6 | -
12 hr | 1 | 1 | -
Clinical and Health Service Use Outcomes
MACE | 2 | 1 | 3
MI | 2 | 3 | 5
Death | 1 | 4 | 7
Cardiac testing | - | 2 | 6
Revascularization | 1 | 2 | 7
ED length of stay | 1 | 4 | 10
Discharge to community | 1 | 3 | 7
Return to ED or hospital | - | 2 | 7

Notes.

a One RCT and seven NRCS were analyzed as a single group study;

b One single group study did not report clinical measures;

c Conducted in Switzerland and Argentina;

d Some studies include multiple risk scores, assays or troponin timings.

Abbreviations. ED=emergency department; EDACS=(Emergency Department Assessment of Chest Pain Score); GRACE=(Global Registry of Acute Coronary Events); h=hour; HEART=(History, Electrocardiogram, Age, Risk factors, Troponin); MACE=major adverse cardiac events; MI=myocardial infarction; n=number; NRCS=nonrandomized comparative studies; RCT=randomized clinical trial; TIMI=(Thrombolysis in Myocardial Infarction).

## DESCRIPTION OF ADPs AND hs-cTn

As displayed in Table 3, we describe the ADPs evaluated in each of the 23 studies based on use of risk score (eg, HEART), additional features of the ADP (eg, chest pain duration), hs-cTn timing, earliest time patients were eligible for discharge, and whether the final disposition includes a grey or observation zone. Appendix G shows the characteristics of common risk scores and Appendix H shows the characteristics (eg, manufacturer and limit of detection) of the hs-cTn used in each ADP.

Most ADPs (N = 13) included an explicit risk score.^24–27,29,33–36,38^ Six ADPs included HEART or a modification of HEART,^25,26,33–35,38^ 3 ADPs included EDACS,^24,29^ 2 ADPs include TIMI,^24,25^ 1 ADP included GRACE and TIMI,^36^ and 1 ADP included GRACE.^27^ Seventeen ADPs included chest pain duration as a factor in the ADP.^23,25,27–33,35–39^ Five ADPs included 0/1 serial hs-cTn,^28,30,34,35,37^ 6 ADPs included 0/3 serial hs-cTn,^23,26,28,31,36,39^ 2 ADPs included 0/1/3 serial hs-cTn,^33,38^ and the remaining ADPs used other combinations of serial hs-cTn up to 12 hours. In 18 ADPs, the earliest time patients were eligible for discharge was after the first troponin.^23,25–33,35–39^ Finally, 2 ADPs included a grey or observation zone as a final disposition, and 3 included a “medium risk category” not described as grey zone or observation, or rule in or rule out.

ADPs varied in complexity. Relatively simple ADPs such as the ESC 0/1 protocol described by Twerenbold et al used time from symptom onset and hs-cTn at presentation to immediately rule out patients or, if needed, obtaining a second sample 1 hour after.^37^ Barnes et al describes the ADP 0/(2 or 3)/6 TIMI, which is relatively complex and involves multiple decision pathways based on hs-cTn, TIMI, and ECG changes.^25^

Table 3 Description of Accelerated Diagnostic Protocol

Author, Year, PMID | Arm, ADP Name | Risk Score | Additional Features of ADP (Yes / No) | | | | | | hs-cTn Timing (hr from ED Admission) | Earliest Time Eligible for Discharge^a^ | Grey Zone / Observation Inclusion
Author, Year, PMID | Arm, ADP Name | Risk Score | Age | Sex | RF | History of MI | ECG | CP Duration | hs-cTn Timing (hr from ED Admission) | Earliest Time Eligible for Discharge^a^ | Grey Zone / Observation Inclusion
Anand 2021 33752439 | High-STEACS ADP 0/3 | | | | | | | Y | 0/3 | 0 | N
Anand 2021 33752439 | ADP 0/6/12 | | | | | | | Y | 0/6/12 | 0 | N
Barnes 202133436490 | STAT ADP 0/2/6 HEART | HEART | Y | | | Y | Y | Y | 0/2/6 | 0 | N
Barnes 202133436490 | ADP 0/(2 or 3)/6 TIMI | TIMI | Y | | | Y | Y | | 0/2/3/6 | 2
Chew 2019 31478763; Lambrakis 2021 33998255 | ADP 0/1 | | | | | | | Y | 0/1 | 0 | Y
Conde 2013 23810070 | ADP 0/3 | | Y | | Y | Y | Y | Y | 0/3 | 0 | N
Costable 2014 | ADP 0/3 | | Y | | Y | Y | Y | Y | 0/3 | 0 | N
Crowder 2015 26387473 | ADP 0/2-4 | | | | | | | Y | 0/2-4 | 0 | N^b^
Ford 2021 33662739 | ADP 0/1/3 HEART | HEART | | | | | | Y | 0/1/3 | 0 | N
Hyams 2018 29478861 | ADP 0/3 HEART | HEART | | | | | | | 0/3 | 0 | N
Ljung 2019 30661856 | ADP 0/1 HEART | HEART | | Y | | | | | 0/1 | 1 | N^b^
Sandeman 2021 34824100 | ADP 0/3/6 | | | | | | | Y | 0/3/6 | 0 | N
Sandeman 2021 34824100 | ADP 0/6/12 GRACE | GRACE | | | | | | | 0/6/12 | 6 | N
Stoyanov 2020 31298551 | ADP ESC 0/1 | | | | | | | Y | 0/1 | 0 | N
Stoyanov 2020 31298551 | ADP ESC 0/3 | | | | | | | Y | 0/3 | 0 | N
Suh 2022 35571147 | ADP 0/1 mHEART | Modified HEART | | Y | | | | Y | 0/1 | 0 | N^b^
Sweeney 2020 32104767 | ADP 0/3 TIMI & GRACE | TIMI & GRACE | | | | | Y | Y | 0/3 | 0 | N
Than 2021 33753972 | COVID-ADP 0/2 EDACS | EDACS | | Y | | | Y | Y | 0/2 | 0 | N
Than 2021 33753972 | ADP 0/2/6 EDACS | EDACS | | Y | | | Y | Y | 0/2/6 | 0 | N
Than 2016 26947800 | ADP 0/2 EDACS | EDACS | | Y | | | Y | | 0/2 | 2 | N
Than 2016 26947800 | ADAPT ADP 0/2 TIMI | TIMI | | Y | | | Y | | 0/2 | 2 | N
Twerenbold 2019 31345421 | ADP ESC 0/1 | | | | | | | Y | 0/1 | 0 | Y
Vigen 2020 32320036 | ADP 0/1/3 mHEART | Modified HEART | | | | | | Y | 0/1/3 | 0 | N

Notes.

a Hours from first measurement: 0 indicates patients are eligible for discharge after the first hs-cTn measurement;

b Includes a medium risk category that is not described as grey zone or observation, or rule in or rule out.

Abbreviations. ADP=accelerated diagnostic protocol; CP=chest pain, ECG=electrocardiogram; ED=emergency department; EDACS=Emergency Department Assessment of Chest Pain Score; ESC=European Society of Cardiology; GRACE=Global Registry of Acute Coronary Events; HEART=(History, Electrocardiogram, Age, Risk factors, Troponin); High-STEACS=High-Sensitivity Troponin in the Evaluation of Patients With Suspected Acute Coronary Syndrome; hr= hours; mHEART=Modified HEART; MI=myocardial infarction; N=no; PMID=PubMed Identifier; RF=risk factor; STAT=single troponin accelerated triage; TIMI=Thrombolysis in Myocardial Infarction; Y=yes.

## EFFECT OF USING ADPS IN THE ED (ADP vs NO ADP)

Only 1 eligible study addressed the effect of using ADPs in the ED by comparing an ADP with hs-cTn without ADP.^26^ The pre-post study of 866 patients in a single US ED compared the ADP 0/3 HEART to a period during which the ED used only the hs-cTn value. The study had moderate risk of bias; they did not adjust for possible confounders for outcomes of interest to this review (they did a multivariate regression for hospital admission) and clinical outcomes were not independently adjudicated. Appendix I presents the baseline characteristics of the sample. Half of the patients were male, they were on average 55 years of age, and 12% had a prior MI.

This study found risks of 30-day MACE, MI, death, and any revascularization did not differ between an ADP with hs-cTn (0/3 HEART) and use of hs-cTn without an ADP. Discharges from the ED to the community (vs hospital admission) were higher for patients in the ADP group compared to the no-ADP group. We have low confidence in these findings primarily because they are based on evidence from a single observational study, with some methodological concerns (Table 4). The study did not report on ED length of stay, 30-day return to the hospital, cardiac testing, or hospital length of stay.

MACE was defined as mortality, nonfatal MI or revascularization within 6 weeks post discharge. There was no significant difference in 30-day MACE among patients who received the ADP 0/3 HEART or hs-cTn without ADP (risk difference [RD] = −1.8%, 95% CI [−5.1, 1.5]; Appendix Table J-1). No patients with a HEART score ≤3 (ie, low risk) in either cohort had MACE.

ED length of stay was not reported (Appendix K). However, patients who received the ADP 0/3 HEART were much more likely to be discharged to the community compared with those who received hs-cTn without an ADP (RD = 15.2%, 95% CI [8.7, 21.7]; Appendix Table L-1). No data were reported on 30-day return to ED (Appendix M).

The proportion of patients who had an MI (RD = −0.1%, 95% CI [−2.9, 2.7]; Appendix Table N-1), death (RD = −0.8%, 95% CI [−1.8, 0.2]; Appendix Table O-1), or any revascularization (RD = −1.7%, 95% CI [−4.6, 1.1]; Appendix Table P-1) within 6 weeks were similar in both cohorts. No data were reported for cardiac testing (Appendix Q) or hospital length of stay (Appendix R).

Table 4 Summary of Findings for ADP Compared to hs-cTn without ADP

Outcome | Studies (Patients); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Overall Confidence | Summary of Findings
MACE | 1 (866); NRCS^26^ | Some limitations^a,b^ | Direct | Precise | NA | Single study | Low | No evidence of a difference; RD = −1.8%, 95% CI (−5.1 to 1.5)
ED length of stay | 0 (0) | | | | | | | (none)
Discharge to the community | 1 (866); NRCS^26^ | Some limitations^a^ | Direct | Precise | NA | Single study | Low | ADP associated with higher proportion of patients discharge to community, vs hs-cTn alone RD = 15.2%, 95% CI (8.7, 21.8)
Return to ED or hospital | 0 (0) | | | | | | | (none)
MI | 1 (866); NRCS^26^ | Some limitations^a,b^ | Direct | Precise | NA | Single study | Low | No evidence of a difference; RD = −0.1, 95% CI (−2.9, 2.7)
Death | 1 (866); NRCS^26^ | Some limitations^a,b^ | Direct | Precise | NA | Single study | Low | No evidence of a difference; RD = −0.8, 95% CI (−1.8, 0.2)
Cardiac testing | 0 (0) | | | | | | | (none)
Revascularization | 1 (866); NRCS^26^ | Some limitations^a^ | Direct | Precise | NA | Single study | Low | No evidence of a difference; RD = −1.7, 95% CI (−4.6, 1.1)
Hospital length of stay | 0 (0) | | | | | | | (none)

Notes.

a Used crude unadjusted analysis to evaluate this outcome;

b Outcome assessors were not blinded.

Abbreviations. ADP=accelerated diagnostic protocol; CI=confidence interval; ED=emergency department; hs-cTn=high-sensitivity cardiac troponin; MACE=major adverse cardiovascular event; MI=myocardial infarction; NA=not applicable; NRCS=nonrandomized comparative study; RD=risk difference.

## COMPARISONS OF DIFFERENT ADPS

Six studies (2 RCTs^23,24^ and 4 NRCSs^25,27–29^) compared ADPs, which are summarized in Table 5. The 6 studies included 12 unique ADPs; thus, comparisons within each study were unique. The 2 RCTs had low risk of bias for the clinical and health service use measures.^23,24^ Three NRCSs relied on record linkage for the clinical outcomes (moderate risk of bias) and had no concerns for the health service outcomes (low risk of bias health service measures).^25,27,28^ One NRCS had high risk of bias for both the clinical and health service use measures.^29^ This study did not provide a description of the method for adjudicating clinical outcomes, did not provide data on the characteristics of patients by cohort, and used crude unadjusted analyses to evaluate all outcomes.

All 6 comparator studies included 49,561 patients (RCT N = 32,050;^23,24^ NRCS N = 17,511^25,27–29^). Table 2 shows the characteristics of the studies. Only 1 study was conducted in multiple EDs.^23^ Three studies were conducted in Europe,^23,27,28^ 2 in New Zealand,^24,29^ and 1 in Australia.^25^ All studies explicitly excluded patients with STEMI. Appendix I shows the baseline characteristics of patients in the 6 studies. Race/ethnicity data were reported in 2 studies, both of which were conducted by the same author in New Zealand.^24,29^ Across the studies, the mean age range was 54 to 64 years and men were in the majority (range 53%–62%). There was variation in the proportion of patients who had a prior MI (range 8%–23%), with 1 study not reporting these data.^29^ In all studies, the assay manufacturer did not change between comparisons.

Table 5 Comparisons of Accelerated Diagnostic Protocols

Author, Year, PMID | Arm, ADP Name | Additional Features of ADP (Yes / No) | | | | | | hs-cTn Timing (hr from ED Admission) | Final Disposition Includes Grey Zone / Observation
Author, Year, PMID | Arm, ADP Name | Age | Sex | RF | History of MI | ECG | CP Duration | hs-cTn Timing (hr from ED Admission) | Final Disposition Includes Grey Zone / Observation
Shorter vs Longer ADP
Anand 2021 33752439 | High-STEACS ADP 0/3 | | | | | | Y | 0 | N
Anand 2021 33752439 | ADP 0/6/12 | | | | | | Y | 0 | N
Sandeman 2021 34824100 | ADP 0/3/6 | | | | | | Y | 0 | N
Sandeman 2021 34824100 | ADP 0/6/12 GRACE | | | | | | | 6 | N
Stoyanov 2020 31298551 | ADP ESC 0/1 | | | | | | Y | 0 | N
Stoyanov 2020 31298551 | ADP ESC 0/3 | | | | | | Y | 0 | N
Than 2021 33753972 | COVID-ADP 0/2 EDACS | | Y | | | Y | Y | 0 | N
Than 2021 33753972 | ADP 0/2/6 EDACS | | Y | | | Y | Y | 0 | N
Comparison of Risk Scores
Barnes 202133436490 | STAT ADP 0/2/6 HEART | Y | | | Y | Y | Y | 0 | N
Barnes 202133436490 | ADP 0/(2 or 3)/6 TIMI | Y | | | Y | Y | | 2 | N
Than 2016 26947800 | ADP 0/2 EDACS | | Y | | | Y | | 2 | N
Than 2016 26947800 | ADAPT ADP 0/2 TIMI | | Y | | | Y | | 2 | N

Abbreviations. ADP=accelerated diagnostic protocol; CP=chest pain; ECG=electrocardiogram; ED=emergency department; EDACS=Emergency Department Assessment of Chest Pain Score; ESC=European Society of Cardiology; GRACE=Global Registry of Acute Coronary Events; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; High-STEACS=High-sensitivity Troponin in the Evaluation of Patients with Suspected Acute Coronary Syndrome; MI=myocardial infarction; N=no; PMID=PubMed identifier; RF=Risk factor(s); TIMI=Thrombolysis in Myocardial Infarction; Y=yes.

### Comparisons of ADPs with Different Durations

Four studies directly compared ADPs with shorter versus longer times between first and last hs-cTn (Table 5).^23,27–29^ Two of these studies compared ADPs with different hs-cTn timings that did not include risk scores.^23,28^ Specifically, 1 RCT^21^ compared a novel High-STEACS 0/3 ADP to the standard 0/6/12 ADP, and 1 NRCS^26^ compared the ESC 0/1 to the ED standard ESC 0/3 ADP. In Than 2021 et al, the EDACS risk score was used in the novel (COVID-ADP 0/2 EDACS) and standard (0/2/6 EDACS) ADPs.^29^ This study was unique in that it compared an ADP developed in response to the COVID-19 pandemic (COVID-ADP 0/2 EDACS) to the ED’s standard ADP. Finally, a NRCS compared a novel shorter ADP that did not include a risk score (0/3/6) to a longer ADP that included GRACE (0/6/12 GRACE).^27^ In the longer ADP, patients were not eligible for discharge till 6 hours after the first hs-cTn measurement. As noted above, the Than et al study had high risk of bias for both the clinical and health service use measures.^29^

In summary, there is no evidence of differences between shorter and longer duration ADPs in 30-day MACE or 30-day MI, but shorter ADPs probably increase discharge to the community from the ED (Table 6; moderate confidence). In addition, together with evidence from single group (noncomparative) studies, shorter duration ADPs probably reduce ED length of stay. There is no evidence of differences in 30-day mortality or follow-up cardiac testing (low confidence). The studies provide insufficient evidence (very low confidence) regarding coronary artery revascularization. The studies did not evaluate return to ED or hospital or hospital length of stay.

#### MACE

One RCT compared the High-STEACS ADP 0/3 to ADP 0/6/12 and evaluated risk of 30-day MACE.^23^ As a primary analysis, MACE was defined as MI (type 1/4b/4c) or cardiac death. The study also evaluated a version of MACE that includes MI type 2. Overall, 0.4% of patients had 30-day MACE. With both definitions, there were no significant differences in 30-day MACE between ADPs (RD = −0.1%, 95% CI [−0.2, 0.03] and RD = −0.1%, 95% CI [−0.2, 0.05], respectively; Appendix Table J-1).

Table 6 Summary of Findings for Shorter versus Longer Duration ADPs

Outcome | Studies (Patients);Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Overall Confidence | Summary of Findings
MACE, 30-day | 1 (31,492); RCT^23^ | No limitations | Direct | Precise | NA | Single study | Moderate | Probably no difference RD = −0.1, 95% CI (−0.2, 0.03)
ED length of stay | 4 (46,784); 1 RCT^23^ and 3 NRCS^27–29^ | Some limitations^a^ | Direct | Precise | Consistent | None | Moderate | ADPs with shorter hs-cTn probably reduce length of stay.
Discharge to the community | 2 (33,908); 1 RCT^23^ and 1 NRCS^29^ | Some limitations^a^ | Direct | Precise | Consistent | None | Moderate | ADPs with shorter hs-cTn probably increase discharge to the community.
Return to ED or hospital, 30-day | 0 (0) | | | | | | | (none)
MI, 30-day | 1 (31,492); RCT^23^ | No limitations | Direct | Precise | NA | Single study | Moderate | Probably no difference RD = −0.1, 95% CI (−0.2, 0.01)
Death, 30-day | 1 (10,873); NRCS^27^ | No limitations | Direct | Imprecise | NA | Single study | Low | Maybe no difference in all-cause (RD = 0.1, 95% CI [−0.7, 0.9]) or cardiovascular (RD = 0.1, 95% CI [−0.5, 0.7]) death
Cardiac testing | 1 (2525); NRCS^28^ | Some limitations^c^ | Direct | Precise | NA | Single study | Low | Maybe no difference in angiograms RD = −3.2, 95% CI (−6.7, 0.3)
Revascularization | 1 (2525); NRCS^28^ | Some limitations^c^ | Indirect^b^ | Precise | NA | Single study | Very low | Insufficient evidence
Hospital length of stay | 0 (0) | | | | | | | (none)

Notes.

a One NRCS did not provide data on the characteristics of patients by cohort and used crude unadjusted analyses to evaluate all outcomes;

b Report revascularization only among patients who received coronary angiography;

c Used crude unadjusted analysis to evaluate this outcome.

Abbreviations. ADP=accelerated diagnostic protocol; CI=confidence interval; ED=emergency department; hs-cTn=high-sensitivity cardiac troponin; MACE=major adverse cardiovascular event; MI=myocardial infarction; NA=not applicable; NRCS=nonrandomized comparative study; RCT=randomized controlled trial; RD=risk difference.

#### ED Length of Stay

In summary, ED length of stay was considerably longer for ADPs with up to 12 hours of hc-Tn compared to ADPs with 6 or less hours of hs-cTn timing. One RCT^23^ and 3 NRCSs^27–29^ all found that ADPs with shorter serial hs-cTn testing compared to longer hs-cTn testing significantly reduced ED length of stay (Appendix Table K-1). Three of the 4 studies had low risk bias^23,27,28^ and 1 had high risk of bias, resulting in some overall methodological limitations.^29^ Anand et al and Sandeman et al both compared novel ADPs (High-STEACS 0/3 and 0/3/6) to standard ADPs with up to 12 hours of hs-cTn (0/6/12 and 0/6/12 GRACE). In both studies, a novel ADP was associated with a significantly shorter length of stay (High-STEACS 0/3 vs 0/6/12: mean 6.8 vs 10 hours, p < 0.001^23^ and 0/3/6 vs 0/6/12 GRACE: median 6.5 vs 8.9 hours, p < 0.001; Appendix Table K-1).^23,27^ Another study found length of stay was shorter for patients who received ESC 0/1 compared to patients who received ESC 0/3 (median difference −2.1 hours, p < 0.001).^28^ Finally, Than et al (2021) found a novel COVID-19 0/2 EDACS ADP reduced median length of stay compared to the standard 0/2/6 EDACS ADP (median 3.4 vs 3.8 hours, p < 0.001).

Two NRCSs reported subgroup comparisons for ED length of stay.^27,29^ Sandeman et al found that among patients with initial hs-cTn <14 ng/L (ie, not high risk), a novel ADP 0/3/6 was associated with a shorter length of stay than the standard ADP 0/6/12 GRACE. Than et al (2021) found that among discharged patients, those who received a novel COVID-ADP 0/2 EDACS had a shorter length of stay than patients who received ADP 0/2/6 EDACS (median 3.1 vs 3.7 hours, p-value not reported).

Evaluating the comparative and single group studies together, 15 studies (of 20 ADPs) reported on ED length of stay (Table 7).^23,25,27–29,31–39^ Five ADPs included 0/1 hs-cTn timing (length of stay range 2.5–4.8 hours),^28,30,34,35,37^ 2 ADPs included 0/2 hs-cTn timing (length of stay range 3.5–6.1 hours),^29,32^ 5 ADPs included 0/3 hs-cTn timing (length of stay range 4.1–6.8 hours),^23,28,31,36,39^ 2 ADPs included 0/1/3 hs-cTn timing (length of stay range 3.4–6.5 hours),^33,38^ 4 ADPs included hs-cTn timing up to 6 hours (length of stay range 3.6–6.5 hours),^25,27,29^ and 2 ADPs included 0/6/12 hs-cTn timing (length of stay range 8.9–10 hours)^23,27^

Table 7 Summary of Findings for ED Length of Stay by ADP hs-cTn Timing

Study, Year, PMID | ADP | N | Median (IQR) Length of Stay, Hours
Chew 2019 31478763 | ADP 0/1 | 1646 | 4.6 (3.4,6.4)
Ljung 2019 30661856 | ADP 0/1 HEART | 621 | 4.7 (3.5, 24.7)
Stoyanov 2020 31298551 | ADP ESC 0/1 | 1282 | 3.2 (2.7,4.4)
Suh 2022 35571147^a^ | ADP 0/1 mHEART | 821 | 4.8 (3.1,7.1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 2296 | 2.5 (2.2, 3.91)
| | | 0/1 Summary Range: 2.5-4.8
Than 2021 33753972 | COVID-ADP 0/2 EDACS | 1343 | 3.4 (2.6,4.6)
Crowder 2015 26387473 | ADP 0/2-4 | 5754 | 6.1 (4.25, 9.8)
| | | 0/2 Summary Range: 3.4-6.1
Anand 2021 33752439 | High-STEACS ADP 0/3 | 16792 | Mean (SD) 6.8 (4.1)
Conde 2013 23810070 | ADP 0/3 | 300 | Mean (SD) 4.3 (2.6)
Costable 2014 | ADP 0/3 | 528 | Mean (SD) 4.5 (2.6)
Stoyanov 2020 31298551 | ADP ESC 0/3 | 1243 | 5.3 (4.7,6.5)
Sweeney 2020 32104767 | ADP 0/3 TIMI & GRACE | 15882 | 3.8 (0.6, 7)
| | | 0/3 Summary Range: 4.1-6.8
Vigen 2020 32320036 | ADP 0/1/3 mHEART | 14552 | 6.5 (4.9, 9.3)
Ford 2021 33662739^b^ | ADP 0/1/3 HEART | 1616 | 3.4 (2.2, 4.9)
| | | 0/1/3 Summary Range: 3.4-6.5
Barnes 2021 33436490 | ADP 0/(2 or 3)/6 TIMI | 1131 | 4.3 (3.3, 7.1)
Than 2021 33753972 | ADP 0/2/6 EDACS | 1073 | 3.8 (2.8,4.9)
Barnes 2021 33436490 | STAT ADP 0/2/6 HEART | 1124 | 3.6 (2.6, 5.4)
Sandeman 2021 34824100 | ADP 0/3/6 | 3673 | 6.5 (3.6, 19.8)
| | | 0/(2 or 3)/6 Summary Range: 3.6-6.5
Anand 2021 33752439 | ADP 0/6/12 | 14700 | Mean (SD) 10 (4.1)
Sandeman 2021 34824100 | ADP 0/6/12 GRACE | 6642 | 8.9 (3.6, 38)
| | | 0/6/12 Summary Range: 8.9-10

Notes.

a Provider time to disposition, median (IQR) for total ED LOS 11.5 (7.6, 22.9);

b Median (IQR) for patient physically entered ED to patient physically left the ED 6.4 (4.3, 9.6).

Abbreviations. ADP=accelerated diagnostic protocol; ED=emergency department; EDACS=Emergency Department Assessment of Chest Pain Score; ESC=European Society of Cardiology; GRACE=Global Registry of Acute Coronary Events; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; High-STEACS=High-sensitivity Troponin in the Evaluation of Patients with Suspected Acute Coronary Syndrome; hs-cTn=high-sensitivity cardiac troponin; mHEART=modified HEART (History, Electrocardiogram, Age, Risk factors, Troponin); IQR=interquartile range; N=sample size; PMID=PubMed identifier; SD=standard deviation; STAT=single troponin accelerated triage; TIMI=Thrombolysis in Myocardial Infarction.

#### Discharge from the ED to the Community

One RCT (Annand et al^23^) and 1 NRCS (Than et al 2021^29^) both found that ADPs with shorter hs-cTn timing compared to longer hs-cTn timing discharged more patients to the community (Table 6; Appendix Table L-1). In the RCT, the High-STEACS ADP 0/3 compared to standard 0/6/12 ADP significantly increased discharges to the community (RD = 21%, 95% CI [20.0, 22.0]). The NRCS found that a novel ADP developed in response to COVID-19 (0/2 EDACS) discharged more patients home compared to the standard 0/2/6 EDACS ADP (RD = 3%, 95% CI [0.5, 5.5]). However, the NRCS had high risk of bias because it did not provide data on the characteristics of patients by cohort and used crude unadjusted analyses to evaluate all outcomes.^29^

In addition, 2 NRCSs reported the proportion of patients discharged from the ED within a pre-defined period of time (eg, proportion discharged ≤4 hours; Appendix Table K-2).^27,29^ In 1 study, patients were more likely to be discharged from the ED within 4 hours if they received a novel ADP (0/3/6) compared to standard ADP (0/6/12 GRACE; RD = 2.3%, 95% CI [0.4, 4.2]). Similarly, Than et al (2021) found a novel COVID-19 ADP resulted in a greater proportion of patients discharged from the ED within 3 hours compared to the standard ADP (44.2% vs 35.2%; p-value not reported).^29^

#### Return to ED or Hospital

No study reported data on return to the ED between ADPs with shorter hs-cTn timing compared to ADPs with longer hs-cTn timing.

#### Myocardial Infarction

One RCT (Annand et al)^23^ found no difference in 30-day MI between patients who received the High-STEACS ADP 0/3 compared patients who received the standard 0/6/12 ADP (Table 6). Overall, 30-day MI was low and varied between 0.2% and 0.4% between patients who received each ADP. In a primary analysis, MI was defined as type 1/4b/4c and a secondary analysis evaluated a version of MI that included type 2 (1/2/4b/4c). With both definitions, there were no significant differences in 30-day MI (RD = −0.1, 95% CI [−0.2, 0.1] and RD = −0.1, 95% CI [−0.2, 0.03], respectively; Appendix Table N-1).

#### Mortality

One NRCS (Sandeman et al) comparing a shorter (0/3/6) to longer (0/6/12 GRACE) ADP found no difference in 30-day all-cause (RD = 0.1%, 95% CI [−0.7, 0.9]) or cardiovascular (RD = 0.01%, 95% CI [−0.5, 0.7]) related death (Table 6 and Appendix Table O-1).^27^ In a subanalysis, the same study reported overall more deaths at 30-days among high-risk patients (defined by initial hs-cTn value), but there were no differences in mortality between ADP.

#### Cardiac Testing

One NRCS (Stoyanov et al) compared the ESC 0/1 to ESC 0/3 and reported cardiac testing outcomes.^28^ The study found no difference between ESC 0/1 and ESC 0/3 and the proportion of patients who received an angiogram (RD = −3.2%, 95% CI [−6.7, 0.3]; Appendix Table P-1). In subanalyses and among people ruled out and discharged, there was no difference between patients who received ESC 0/1 and 0/3 and angiogram imaging, or stress testing.

#### Revascularization

One NRCS found no difference (ADP ESC 0/1 vs ADP ESC 0/3) in the proportion of patients who received a percutaneous coronary intervention among a subgroup who received a coronary angiography (RD = 0.2%, 95% CI [−7.2, 7.6]; Appendix Table Q-1).^28^ No other study reported comparative data on revascularization.

#### Hospital Length of Stay

No study reported compared hospital length of stay between ADPs with shorter and longer hs-cTn timing.

### Comparison of ADPs with Different Risk Scores

Two studies compared ADPs with similar hs-cTn timing but different risk scores.^24,25^ One NRCS compared a novel STAT 0/2/6 HEART ADP to the ED’s standard 0/(2 or 3)/6 TIMI ADP.^25^ The novel STAT ADP and standard ADP both incorporated age, history of MI, and ECG as features.^25^ The novel ADP also incorporated the HEART risk score and chest pain duration, and patients were eligible for discharge after the first hs-cTn draw. In contrast, the standard ADP incorporated TIMI, did not include chest pain duration as a feature, and patients where not eligible for discharge until 2 hours after the first hs-cTn. It was unclear whether clinical outcomes were independently adjudicated, so the study had medium risk of bias for clinical outcomes. There were no other concerns and the study was low risk of bias for the health service use measures. One RCT compared a novel 0/2 EDACS ADP to the ADAPT 0/2 TIMI ADP.^24^ In both ADPs, patients were not eligible for discharge until 2 hours after first hs-cTn. The novel ADP included the EDACS risk score and the standard ADP included TIMI risk score. The study had no concerns and was rated low risk of bias for the clinical and health service use measures.

In summary, there is no evidence of differences in 30-day MACE, 30-MI, and 30-day death among ADPs with similar hs-cTn timing and different risk scores. We have moderate confidence in these findings due to the large size of available studies and lack of major methodological limitations (Table 8). A HEART-based ADP compared to TIMI-based ADP with similar hs-cTn timing may reduce ED length of stay and increase discharge to the community from the ED. We have moderate confidence in these findings due to the large size of available studies and lack of major methodological limitations. Thirty-day return to the ED is probably similar among patients administered a HEART-based ADP or TIMI-based ADP with similar hs-cTn timing. We have low confidence in these findings because only 1 nonrandomized study was available for this outcome. Studies did not report on revascularization or hospital length of stay.

#### MACE

One RCT reported 30-day MACE.^24^ The authors defined MACE as death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI. There was no significant difference in 30-day MACE between patients who received the 0/2 EDACS ADP and ADAPT 0/2 TIMI ADP (RD = 0.3, 95% CI [−0.9, 1.5]; Appendix Table J-2). All MACE events (0/2 EDACS N = 2 [0.7%] vs ADAPT 0/2 TIMI N =1 [0.4%]) occurred in non-low risk patients. No other study reported MACE outcomes.

#### ED Length of Stay

One RCT found that the proportion of patients discharged from the ED within 6 hours and who did not have 30-day MACE was similar for patients who received a novel 0/2 EDACS ADP or ADAPT 0/2 TIMI ADP (RD = −2.1%, 95% CI [−10.3, 6]; Appendix Table K-2).^24^ This finding held in a subanalysis among low risk patients (RD = 3.2%, 95% CI [−4.3, 10.7]). One NRCS reported a consistent finding that a novel HEART-based ADP resulted in a shorter length of stay than the TIMI-based ADP (median 3.4 vs 3.8 hours; incident rate ratio = 0.71, 95% CI [0.65, 0.77]; Appendix Table K-1).^25^

#### Discharge from the ED to the Community

One NRCS found the HEART-based ADP compared to TIMI-based ADP was associated with an increase in the proportion of patients discharged home (RD = 25%, 95% CI [21, 29]; Appendix Table L-1).^25^

#### Return to ED or Hospital

One NRCS found no difference in the proportion of patients who returned to the ED for any reason between people who received the HEART- or TIMI-based ADP (RD = 1.1%, 95% CI [−1.3, 3.4]; Appendix Table M-1).^25^ In a secondary analysis, there were no differences in the proportion of patients who returned to the ED for chest pain (RD = −2%, 95% CI [−14.9, 10.9]).

#### Myocardial Infarction

An NRCS^23^ and RCT^24,25^ both reported 30-day MI. The NRCS reported no 30-day MI among patients who received either the 0/2/6 HEART ADP or 0/(2 or 3)/6 TIMI ADP (Appendix Table N-1).^25^ The RCT found patients who received a novel 0/2 EDACS ADP and ADAPT 0/2 TIMI ADP had similar risk of 30-day non-ST-elevation myocardial infarction (NSTEMI; RD = 0.7%, 95% CI [−2.1, 0.6]) and ST-elevation myocardial infarction (STEMI; RD = −0.4%, 95% CI [−0.7, 1.4]; Appendix Table N-1).^24^ The same RCT reported 3 MIs (1 STEMI and 2 NSTEMI) at 30 days all in non-low risk patients.

#### Mortality

An NRCS^23^ and RCT^24,25^ reported 30-day mortality. The NRCS reported no patients who received either ADP died within 30 days (Appendix Table O-1).^25^ The RCT reported no 30-day all-cause mortality among patients who received a novel 0/2 EDACS ADP and 1 30-day death (0.4%) among a non-low risk patient who received the 0/2 TIMI ADP (RD = −0.4%, 95% CI [−0.7, 1.4]).^24^

#### Cardiac Testing

One NRCS reported follow-up stress (ECG and imaging) and angiogram (standard and imaging) data (Appendix Table P-1).^25^ Patients who received a novel STAT 0/2/6 HEART ADP compared to 0/(2 or 3)/6 ADP had similar use of stress ECG (RD = 1%, 95% CI [−1.2, 3.2]) and CT angiogram (RD = 1.7%, 95% CI [0.1, 3.3]). The novel STAT 0/2/6 HEART ADP compared to 0/(2 or 3)/6 ADP resulted in more myocardial perfusion scans (RD = −2%, 95% CI [−3.4, −0.6]) and CT angiograms (RD = 1.7%, 95% CI [0.1, 3.3]).

#### Revascularization and Hospital Length of Stay

No study reported data on revascularization or hospital length of stay.

Table 8 Summary of Findings for ADPs with Similar hs-cTn Timing and Different Risk Scores

Outcome | Studies (N); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Overall Confidence | Summary of Findings
MACE, 30-day | 1 (558); RCT^24^ | No limitations | Direct | Precise | NA | Single study | Moderate | Probably no difference (RD = 0.3, 95% CI [−0.9, 1.5])
ED length of stay | 1 (2,255); NRCS^25^ | No limitations | Direct | Precise | NA | Single study | Low | ADP 0/2/6 HEART may reduce length of stay compared to ADP 0/(2 or 3)/6 TIMI (IRR = 0.71, 95% CI [0.65, 0.77]; p < 0.001)
Discharge to the community | 1 (2,255); NRCS^25^ | No limitations | Direct | Precise | NA | Single study | Low | ADP 0/2/6 HEART may increase discharge to the community compared to ADP 0/(2 or 3)/6 TIMI (RD = 25, 95% CI [21.0, 29.0]; p < 0.001)
Return to ED or hospital | 1 (2,255); NRCS^25^ | No limitations | Direct | Precise | NA | Single study | Low | No difference between ADP 0/2/6 HEART and ADP 0/(2 or 3)/6 TIMI (RD = 1.1, 95% CI [1.3, 3.4])
MI, 30-day | 2 (2,813); 1 RCT^24^ and 1 NRCS^25^ | No limitations | Direct | Precise | NA | Sparse data | Moderate | Probably no difference between ADPs with similar hscTn but different risk scores
Death, 30-day | 2 (2,813); 1 RCT^24^ and 1 NRCS^25^ | No limitations | Direct | Precise | NA | Sparse data | Moderate | Probably no difference between ADPs with similar hscTn but different risk scores
Cardiac testing | 1 (2,255); NRCS^25^ | Serious limitations^a^ | Direct | Precise | Inconsistent^b^ | Single study | Very Low | Insufficient evidence
Revascularization | 0 (0) | | | | | | | (none)
Hospital length of stay | 0 (0) | | | | | | | (none)

Notes.

a Used crude unadjusted analyses to evaluate this outcome;

b No difference in stress ECG and CT angiogram but differences in myocardial perfusion scans and CT angiograms.

Abbreviations. ADP=accelerated diagnostic protocol; CI=confidence interval; ED=emergency department; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; hs-cTn=high-sensitivity cardiac troponin; MACE=major adverse cardiovascular event; MI=myocardial infarction; NA=not applicable; NRCS=nonrandomized comparative study; RCT=randomized controlled trial; RD=risk difference; TIMI= Thrombolysis in Myocardial Infarction.

## OUTCOMES BY ADP DISPOSITION

We reviewed comparative and single group studies to summarize the relationship between ADP stratification into disposition groups and outcomes. We first note, though, that the 17 studies did not use a standard system nor set of definitions for how patients were risk stratified. This was in part due to differences in how the various ADPs stratified patients and in part due to differences in language (or classification) across studies. Ultimately, we found 6 partially overlapping categories: rule out, low risk (not described as rule out), discharge (not described as rule out), observation/grey zone, high risk either stated or implied (not described as rule in), and rule in.

In summary, ED length of stay increased and the proportion of patients discharged to the community decreased as risk categorization increased. All ADPs appear to successfully stratify patients based on their risks of 30-day MACE, 30-day MI, and 30-day death. In general, the proportion of patients who returned to the ED, cardiac testing, revascularization, and hospital length of stay increased in risk categorization.

### MACE

Five studies that evaluated 6 ADPs reported 30-day MACE by ADP disposition.^24,26,30,35,37^ Examples of the various MACE definitions used across studies included MI or cardiac death,^37^ MI or all-cause death,^30^ and MI, revascularization, ventricular arrhythmia, high degree atrioventricular block requiring intervention, cardiogenic shock requiring mechanical support, cardiac arrest with return of spontaneous circulation, and death.^35^ The proportion of patients with 30-day MACE mostly ranged from 0.4% to 5.8%, with an outlier study (Twernbold et al) reporting 10.1%.^37^

In general, the risk of 30-day MACE increased with increase in risk categorization. Three ADPs included 0/1 hs-cTn timing,^30,35,37^ 2 included 0/2 hs-cTn timing,^24^ and 1 included 0/3 hs-cTn timing.^26^ In 2 studies that used a 0/1 ADP, 30-day MACE defined as death (cardiovascular or all-cause) and MI was between 0.2% and 0.5% for ruled-out patients (Appendix Table J-2).^30,37^ In a second definition of MACE, Chew et al added unstable angina to the composite that resulted in 0.8% 30-day MACE for ruled-out patients. In 3 ADPs (ADP 0/2 EDACS, ADP 0/2 TIMI, and ADP 0/3 HEART), no occurrences of 30-day MACE were reported among low-risk patients (not described as rule out).^24,26^ In 2 0/1 based ADPs, 30-day MACE among discharged patients was ≤1%, and among patients in an observation or grey zone, 2.3% and 5.3%.^30,37^ The same 2 studies reported 30-day MACE of 3.7% and 66.8% among ruled-in patients.^30,37^ Three studies representing 4 ADPs reported outcomes for high-risk patients (not described as rule in).^24,35,37^ Twerenbold et al (high risk defined as patients admitted during index visit) reported 34% of patients had MACE at 30 days.^37^ A second study reported 8.9% (ADP 0/1 mHEART) of patients experienced 30-day MACE,^35^ and a third study reported 0.4% (ADP 0/2 TIMI) and 0.7% (ADP 0/2 EDACS) 30-day MACE among non-low risk patients.^24^

### ED Length of Stay

Six studies evaluating 8 ADPs reported ED length of stay by ADP disposition.^27,29,30,34,37,39^ All 6 studies reported ED length of stay for patients either ruled out, low risk (not described as rule out), or discharged. Among these studies, 3 ADPs incorporated 0/1 hs-cTn timing,^30,34,37^ 1 incorporated 0/3 timing,^39^ 1 incorporated 0/3/6 timing,^27^ and 1 incorporated 0/6/12 timing.^27^ There was no discernable pattern between hs-cTn timing and ED length of stay among ruled-out patients (range 2.5–4.6 hours),^30,37^ low-risk patients (range 2.9–4.05 hours),^27,34,39^ or discharged patients (range 2.5–3.8 hours; Appendix Table K-3).^29,30,34,37^ There was a wide range in median length of stay (2.5–12 hours) reported in 2 0/1 ADPs for patients in the observation or grey zone.^30,37^ The same 2 studies reported median length of stay for ruled-in patients of 51 hours (Chew et al)^30^ and 2.5 hours (Twerenbold et al).^37^ Finally, 3 studies evaluating 4 ADPs (ADP 0/1 HEART, ADP ESC 0/1, ADP 0/3/6, and ADP 0/6/12 GRACE) reported median ED length of stay for high-risk (not described as rule in) patients between 3 and 46.7 hours.^27,34,37^ ED length of stay was sensitive to the definition of high risk.

Two studies evaluating 4 ADPs (ADAPT ADP 0/2 TIMI, ADP 0/2 EDAC, ADP 0/3/6, and ADP 0/6/12 GRACE) reported the proportion of patients discharged from the ED within 4 or 6 hours by ADP disposition.^24,27^ As noted in the comparative ADP section, Than et al (2016) defined their outcome as proportion discharged within 6 hours and no 30-day MACE. The study reported 26.2% (ADP 0/2 EDACS) and 22.9% (ADAPT ADP 0/2 TIMI) of low-risk patients were discharged within 6 hours without 30-day MACE.^24^ Sandeman et al compared 2 ADPs (0/3/6 and 0/6/12 GRACE) and reported the proportion of low-risk patients discharged ≤4 hours was between 53% and 64% (Appendix Table K-4).^27^ The same study also reported ~13% of high-risk (not defined as rule in) patients (defined as first hs-cTn >14 ng/L) were discharged within 4 hours in both ADPs. No other study reported these discharge data by ADP disposition.

### Discharge from the ED to the Community

Three studies evaluating 3 ADPs (ADP ESC 0/1 and ADP 0/1 HEART) reported data on the proportion of patients discharged from the ED to the community by ADP disposition (Appendix Table L-2).^30,34,37^ One ESC 0/1 study reported 45.1% of patients were discharged to the community.^30^ In 2 other studies, 67.5% (ADP 0/1 HEART)^34^ and 71% (ESC 0/1)^37^ were discharged to the community. In 2 ESC 0/1 studies, 49.6%^30^ and 88%^37^ of ruled-out patients were discharged from the ED to the community. Similarly, the 0/1 HEART ADP was associated with 87.3% of low risk (not described as rule out) patients being discharged.^34^ The 2 ESC 0/1 studies reported 27.3%^30^ and 61%^37^ of observed group patients were discharged home.^30,37^ The same 2 studies reported 8% of ruled-in patients were discharged home. Finally, the ADP 0/1 HEART study reported 62.6% (HEART score ≥4) and 31.5% (initial hs-cTn >14) high-risk (not described as rule in) patients were discharged home.^34^

### Return to ED or Hospital

Two studies evaluating 2 ADPs (ADP ESC 0/1 and ADP 0/1 HEART) reported 30-day return to the ED by ADP disposition (Appendix Table M-2).^30,34^ Thirty-day return to the ED was low for patients ruled out (3.5%),^30^ low risk not described as rule out (5.2%),^34^ or discharged (10.7%).^34^ One study (ADP ESC 0/1) reported 3.6% and 7.1% of observe/grey zone patients returned to the ED for myocardial injury and chest pain, respectively.^30^ The same study reported 5.1% of ruled-in patients returned to the ED. Another study (ADP 0/1 HEART) reported return to ED among high-risk patients with proportions between 17.8% and 22.3% based on the definition of high risk.^34^

### Myocardial Infarction

Five studies evaluating 6 ADPs (ADP ESC 0/1,^30,37^ ADP 0/1 HEART,^34^ADP 0/2 EDACS,^24^ADAPT ADP 0/2 TIMI, ^24^ and ADP 0/3^39^) reported MI by ADP disposition (Appendix Table N-2). Thirty-day MI for patients ruled out, low risk, or discharged was between 0% and 0.8%. Thirty-day MI among patients in the observe or grey zone was reported for 2 0/1 ADPs (1.9%^30^ and 5.2%^37^). Among patients ruled in or high risk, 30-day MI varied between 0% and 67%.

### Mortality

Six studies evaluating 6 ADPs (ADP ESC 0/1,^30,37^ ADP 0/1 HEART,^34^ ADP 0/3,^39^ ADP 0/3/6,^27^ and ADP 0/6/12 GRACE^27^) reported mortality by ADP disposition (Appendix Table O-2). For patients ruled out, low risk (not described as rule out), or discharged, 30-day mortality was between 0% to 0.3%.^27,30,34,37,39^ Two ESC 0/1 studies reported 30-day morality for ruled-in patients from 0%^30^ to 1.7%.^37^ One study evaluating 2 ADPs reported 5.4% high-risk (not described as rule in) patients had 30-day cardiovascular mortality.^27^ The same study found ~9% of high-risk patients had 30-day all-cause mortality. Three studies evaluating 3 ADPs reported 0% to 1% of high-risk patients died within 30 days.^34,37,39^

### Cardiac Testing

Three studies evaluating 3 ADPs (ESC 0/1^30,37^ and ADP 0/1 HEART)^34^ reported any stress testing by ADP disposition (Appendix Table P-2). The proportion of patients who received any stress testing generally increased by risk categorization: rule out (5.1% and 8.8%),^30,37^ low risk not described as rule out (10.1%),^34^ observe/grey zone (10% and 13%),^30,37^ rule in (14%),^30,37^ and high risk not described as rule in (9.2% and 15.1%).^34^ Similar findings were reported among 3 studies evalauting 3 ADPs (ESC 0/1^28,30,37^ and ESC 0/3^28^) for stress ECG tests and angiograms and 2 studies evalauting ESC 0/1 ADPs^28,30^ for stress imaging. Limited angiogram imaging data were reported for studies evaluating ESC 0/1^30^ and ESC 0/3.^28^

### Revascularization

Two studies both evaluating ESC 0/1 ADPs reported revascularization by ADP disposition.^30,37^ In general, the proportion of patients who received any revascularization within 30 days increased by risk categorization. Between 0.6% and 4.4% of ruled-out or discharged patients received any revascularization (Appendix Table Q-2). Among patients in the observation zone, 5.8%^30^ and 11%^37^ received any revascularization, and 24%^30^ and 51%^37^ of ruled-in patients received any revascularization. Finally, in 1 study 40% of high-risk (not described as rule-in) patients received any revascularization.^40^

### Hospital Length of Stay

Only 1 study (ADP ESC 0/1) reported hospital length of stay (Appendix Table R-1).^37^ Patients in the observe, rule in, and high risk (not described as rule in) groups spent a median (IRQ) of 1 (0, 5), 5 (3, 9), and 5 (2, 8) nights in the hospital, respectively.