# METHODS

## TOPIC DEVELOPMENT

We worked with representatives from the VA Office of Emergency Medicine and our Technical Expert Panel (TEP) to refine the review scope and develop the key questions (KQ). In this review, we focus on studies that report on the real-world use of ADPs that incorporate a hs-cTn to rule in or rule out MI. We did not include studies that modeled ADPs using retrospective medical record data (ie, classifications made from medical record data that were not implemented while the patients were in the ED). We define ADPs as clinical decision-making tools that at a minimum include a clinical metric (eg, time since symptom onset) and incorporate hs-cTn to inform the diagnosis of MI. We evaluated the impact that use of the ADP(s) had on clinical outcomes (eg, MI diagnosis, mortality, and major adverse cardiac events) and health service use outcomes (eg, duration of emergency department stay, hospitalizations, and use of diagnostic testing such as echocardiography). We also evaluated whether patient sex and baseline clinical features may affect the performance of ADPs with hs-cTn and clinical and health service use outcomes.

## KEY QUESTIONS

KQ1 Among adults presenting to the emergency department with suspected acute coronary syndrome, what are the effectiveness and comparative effectiveness of accelerated diagnostic protocols that use high sensitivity cardiac troponin assays on:
  i) clinical outcomes (eg, myocardial infarction, mortality, and major adverse cardiac events) within 6 weeks?
  ii) health service use (eg, duration of emergency department stay, duration of hospitalization, readmission) within 6 weeks?
KQ1a Does effectiveness differ as a function of patient characteristics (eg, gender, chest pain duration, clinical risk score)?
KQ1b What is the performance of accelerated diagnostic protocols that use 1-hour delta troponin compared to accelerated diagnostic protocols that use 2-hour delta troponin?
KQ2 What are the clinical and health service use outcomes among adults presenting to the emergency department with suspected acute coronary syndrome who have indeterminant (“grey” or “observational” zone) results of accelerated diagnostic protocols that use high sensitivity cardiac troponin assays?
KQ2a Do clinical and health service outcomes differ as a function of patient characteristics (eg, gender, chest pain duration, clinical risk score)?

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42022343247).

## DATA SOURCES AND SEARCHES

We conducted a preliminary search in PubMed which was focused on Medical Subject Headings (MeSH) terms for acute coronary syndrome and related terms, troponins, and emergency services, together with a list of known relevant publications. As described next, these were screened, after which we expanded our searches and continued screening.

To identify articles relevant to the KQs for our final searches, we searched for peer-reviewed articles from January 2008 to May 2022 in Medline (via PubMed), Embase, ClinicalTrials.gov, and the Cochrane Database of Systematic Reviews. We used MeSH and title/abstract terms related to chest pain, accelerated diagnostic protocols, high-sensitivity cardiac troponin, and emergency department (see Appendix A for complete search strategies). Additional citations were identified from hand-searching reference lists of relevant systematic reviews and consultation with content experts.

## STUDY SELECTION

Citations were uploaded into the online abstract screening software Abstrackr (http://abstrackr.cebm.brown.edu) and duplicates were removed.^19^ To begin screening of the focused search, we used pilot rounds to train the research team during which all team members screened the same sets of abstracts and conflicts were discussed in conference. Subsequently, 2 independent reviewers screened titles and abstracts using the prespecified inclusion and exclusion criteria (Table1). Conflicts between screeners were resolved by a third senior researcher.

Abstrackr uses machine learning algorithms to predict the likelihood that unscreened abstracts are relevant. Based on empirical evidence, we stopped screening when all remaining unscreened abstracts had a prediction value of <0.40 (on a 0–1 scale) and subsequently 400 abstracts in a row were rejected.^19^ The initial focused search enabled quicker training of the team and quicker predictions by the machine learning algorithms.

Accepted abstracts underwent full-text review. During full-text review, 2 reviewers decided on inclusion and, when necessary, they consulted a third senior researcher. A list of studies excluded at full-text review, with rejection reasons, is provided in Appendix B.

Eligible populations were ≥18 years of age presenting to the ED with suspected acute coronary syndrome (excluding studies of patients with ST-elevation MI or drug-related ED admissions). Eligible articles addressed ADPs that were clinically applied (ie, the clinical team in the ED used the evaluated ADP(s) to manage patients). Studies were excluded if the ADP was not clinically applied in an ED (eg, observational studies that derived or validated decision rules without furnishing results to the ED clinical team for use in real time). Our focus was on evaluation ADPs when used with hs-cTn; we thus excluded studies of ADPs used with standard (non-hs) cTn. Studies had to report clinical or heath service use outcomes within 6 weeks of ED admission, as listed in Table 1. Comparative studies of interest had to compare alternative ADPs (both with hs-cTn) or ADP with hs-cTn versus no use of ADP. We did not include comparisons of an ADP with versus without hs-cTn. For studies that compared an ADP with hs-cTn versus a protocol that did not meet our criteria (eg, ADP with standard hs-cTn), we included the eligible study group as a single group cohort and omitted (ignored) the ineligible study group. For single group studies (including comparative studies with only a single eligible group), in which all patients were evaluated in the ED with a single defined ADP with hs-cTn, we analyzed only ED length of stay (or time to discharge/admission) and those outcomes that were reported by rule-in/rule-out category.

Table 1 Inclusion and Exclusion Criteria

| Inclusion Criteria | Exclusion Criteria
Population | Adults ≥18 years of age presenting to the emergency department with suspected acute coronary syndrome. | - People who present with ST-elevation myocardial infarction (STEMI); - Chest pain related to cocaine or other illicit drug use
Intervention | ADPs that use hs-cTn. ADP must at a minimum incorporate clinical history to risk stratify patients.; ADP must have been applied in real time during care of the patient in the ED. | - hs-cTn not within an ADP framework (eg, lab test alone); - ADP that included standard cTn; - ADP that included copeptin + hscTn; - ADP and/or hs-cTn that was derived based on medical record and was not available to the ED team for clinical care
Comparator | Alterative ADP, no use of ADP, no comparator | - Not alternative lab measures (eg, copeptin); - ADP with conventional troponin
Outcomes | - Clinical Outcomes; – MI; ▪ MI delayed or missed diagnosis; ▪ MI correct diagnosis; – Mortality; ▪ Cardiac; ▪ All-cause; – MACE (any definition); - Halth Service Use Outcomes; – Cardiac revascularization; – Delayed intervention (eg, revascularization); – Duration of emergency department stay; – Hospitalizations (full admission as opposed to emergency department observation); – Duration of hospitalization; – Emergency department or hospital readmission; – Further cardiac testing (eg, stress test, heart CT, heart MRI, echocardiography, coronary angiography) | - Components of MACE other than MI and mortality; - Chest X-ray; - Chest CT
Timing | - Upon arrival to the emergency department; - Follow-up within 6 weeks
Setting | ED or prior to arrival in ED (ie, by emergency medical technicians) | Inpatient and outpatient (non-ED) settings
Study Design | - RCT; - NRCS, prospective or retrospective; - Single group studies, prospective or retrospective; - N ≥ 30 per group | - Observational studies not evaluating the real-world use of an ADP; - Study protocols (without results); - Case reports and series; - Cross-sectional (no follow-up); - Qualitative research studies; - Conference abstracts; - Reviews, editorials, opinion
Other | No language restriction, no country restrictions | - Unable to translate within Center

Abbreviations. ADPs=accelerated diagnostic protocols; CT=a computerized tomography scan; cTn=cardiac troponin; ED=emergency department; hs-cTn=high sensitivity cardiac troponin; MACE=major adverse cardiac events; MI=myocardial infarction; MRI=magnetic resonance imaging; N=number of participants; NRCS=nonrandomized comparative studies; RCT=randomized controlled trials; STEMI=ST-elevation myocardial infarction.

## DATA EXTRACTION AND ASSESSMENT

We created a data extraction form in the Systematic Review Data Repository-Plus (SRDR+) online system (https://srdrplus.ahrq.gov). We extracted the following data from eligible studies: study design, setting, baseline population characteristics, ADP and hs-cTn characteristics, and clinical and health service use outcomes. All data extraction was first completed by 1 reviewer and then checked by a second reviewer. Disagreements were resolved by consensus or discussion with a third reviewer.

Study risk of bias was independently assessed by 2 reviewers using questions derived from the Cochrane Risk of Bias and the ROBINS-I tools (Appendix C).^20,21^ We assessed risk of bias separately for clinical and health service use outcomes. For comparative studies, we identified risks of bias that could influence the observed effect of an ADP on an eligible outcome. Single group studies were assessed for risks to the measurement of outcomes only.

RCTs had high risk of bias if there was 1) inadequate randomization method, 2) inadequate allocation concealment, or 3) not explicitly blinding outcome assessors (only a concern for clinical measures) and high attrition. RCTs with no concerns had low risk of bias. NRCSs had high risk of bias if they did not adjust for potential confounders (ie, conducted crude analyses). Medium risk of bias NRCSs adjusted for confounders but had at least 1 other concern. NRCS with no concerns had low risk of bias. Single group studies had high risk of bias if they had ≥2 concerns. Studies with only 1 concern had medium risk of bias. Single group studies with no concerns were rated as having low risk of bias.

Discrepancies were resolved by consensus between reviewers. Ratings for eligible studies are in Appendix D.

## SYNTHESIS AND CERTAINTY OF EVIDENCE

We conducted a narrative synthesis of the evidence. We aimed to meta-analyze quantitative data, but this was not feasible. We synthesized the certainty of evidence (CoE) following the GRADE (Grading of Recommendations Assessment, Development and Evaluation) approach.^22^ We compiled key study findings in Evidence Profiles, which provide the basis for determination of CoE and summarize conclusions for prioritized outcomes. Within each evaluated study comparison (eg, ADP vs no ADP) and priority outcome, we considered the study design, the number of studies (and participants), methodological limitations (ie, risk of bias), directness of the evidence, precision of the findings, consistency across studies, and other issues. Based on these, we determined CoE, which could be high, moderate, low, or very low. Where we found very low CoE, there is insufficient evidence to draw conclusions. For each outcome, we also provide a summary of the findings.