# INTRODUCTION

## PURPOSE

The VA Evidence Synthesis Program (ESP) was asked by the VA Office of Emergency Medicine for an evidence review on accelerated diagnostic protocols (ADPs) that use high-sensitivity cardiac troponins (hs-cTn) to rule in or rule out myocardial infarction (MI) in the emergency department (ED). The Greater Los Angeles VA ED is an early adopter of hs-cTn and is in the process of developing an ADP. The VA Office of Emergency Medicine indicates that most VA EDs still use conventional troponins, but the Office anticipates more VA EDs will transition to hs-cTn and will need guidance on how to interpret test results for this biomarker within the context of an ADP. This evidence review will be used by the VA Office of Emergency Medicine to provide guidance to local VA EDs that seek to implement hs-cTn with ADPs.

## BACKGROUND

In the United States (US), 7 million people annually visit the ED for chest pain, but only 4% of these patients are diagnosed with MI.^1^ MI is diagnosed when there is clinical evidence of myocardial ischemia, based on any combination of symptoms, history, and electrocardiogram (ECG) findings, together with either a rise or fall in laboratory biomarkers indicative of infarction.^2^ For patients with chest pain or symptoms suggestive of acute coronary syndrome (ACS, which also includes unstable angina without infarction), the 2014 American College of Cardiology/American Heart Association (ACC/AHA) guidelines recommend observation, the use of a 12-lead ECG, and serial cardiac troponin testing using conventional troponins over a 3- to 6-hour period.^3^ The evaluation of acute chest pain in the ED can be challenging and carries risks of over- and under-diagnosis of MI; it commonly requires a significant amount of hospital time and resources.^4,5^ Rapid rule out and rule in of MI should reduce time to correct patient diagnosis and can reduce clinician, staff, and other hospital resource needs, along with ED overcrowding, unnecessary testing, and unnecessary hospitalizations. However, the clinical implications of missing an MI may include mortality as well as medicolegal risk.^6^ In addition, incorrectly diagnosing an MI may put patients through unnecessary testing and treatment and may delay accurate diagnosis of their symptoms.

Cardiac troponin I and T are the primary diagnostic biomarkers used to diagnosis MI.^3^ Cardiac troponins have several features that make them useful for this purpose: they are highly concentrated in the myocardium, are not present in non-myocardial tissue, are released into the blood stream only in the presence of myocardial injury, and are relatively easy to quantify in routine clinical practice. In the appropriate clinical context, troponin concentrations in the blood above the 99^th^ percentile of the upper reference level identify myocardial injury.^7^ During an MI, troponin levels typically rise within 2 to 3 hours of symptom onset, peak within 18 to 24 hours, and then stay elevated for several days.^8^ While the 99^th^ percentile of the upper reference level is used to distinguish between normal and elevated troponin levels, the actual cut-off values vary by assay manufacturer and patient characteristics.

The newer hs-cTn assays entered the global market in 2010. Compared with conventional cardiac troponin assays, hs-cTn is 10 to 100 times more sensitive and provides more consistent results, which can shorten the time between assessments.^9^ The US Food and Drug Administration (FDA) first approved hs-cTn for clinical use in 2017.^10,11^ Subsequently, clinical guidelines, including the 2021 ACC/AHA Joint Committee on Clinical Practice Guidelines, have recommended hs-cTn as the preferred troponin biomarker for diagnosing MI.^12^

Despite regulatory and guideline support, there are challenges to implementing hs-cTn in clinical practice.^11^ Among these are the following: there are multiple assay manufacturers measuring different types of troponins (I and T) with unique performance characteristics, they are intended to be used in tandem with other clinical information, hs-cTn can be measured at different time points (eg, only on arrival or serially every 1, 2, 3, and/or 6 hours), and very rapid protocols (eg, within 1 hour of ED presentation) may be difficult to implement in low-resource EDs.^12^

Multiple ADPs that incorporate hs-cTn have been devised to help ED providers (eg, physicians and physician assistants) quickly rule out MI.^12,13^ In addition to hs-cTn, ADPs can incorporate risk scores and other clinical criteria (eg, patient history or ECG findings) to stratify patients into risk categories that inform clinical management. ADPs may include an intermediate or grey zone for patients who cannot be readily ruled out or ruled in, which can create uncertainty and challenges for clinical management. For example, the 2020 European Society of Cardiology (ESC) guidelines recommend the use of a 0/1-hour hs-cTn ADP,^14^ in which clinical history is combined with hs-cTn measurement at presentation to the ED and 1 hour later. Baseline hs-cTn values and 1-hour change in hs-cTn (assay-specific cut-offs are applied) are used to rule out, rule in, or place patients in the intermediate zone, which requires additional observation, repeat hs-cTn measurement(s), and echocardiography.^14^

Decision rules for most ADPs using hs-cTn were validated in large and well-described observational studies.^13,15–18^ These validation studies have demonstrated that various ADPs with hs-cTn likely rule out MI without increasing the risk of adverse events. Health systems, including the VA, now aim to implement ADPs with hs-cTn into routine clinical practice.

In ED settings, however, the effects of ADPs on clinical and health service utilization outcomes (eg, MI diagnoses, time to discharge) remain unclear. The aim of this systematic review was to identify and synthesize available evidence on VA-priority clinical and hospital resource utilization outcomes of ADPs using hs-cTn to rule in or rule out MI in ED settings.