# APPENDIX R HOSPITAL LENGTH OF STAY OUTCOMES

Appendix Table R-1 Hospital Length of Stay: Rule Out, Low Risk Not Described as Rule Out, Discharge or Grey Zone, and Rule In or High Risk

Study, Year, PMID | ADP | Follow-up Time (Days) | Outcome Definition | N | Median (IQR)
Rule Out
Twerenbold 2019 1345421 | ADP 0/1 | 30 | Nights | 1420 | 0 (0,0)
Discharge
Twerenbold 2019 1345421 | ADP 0/1 | 30 | Nights | 1619 | 0 (0,0)
Observe / Grey Zone
Twerenbold 2019 31345421 | ADP 0/1 | 30 | Nights | 581 | 1 (0,5)
Rule In
Twerenbold 2019 31345421 | ADP 0/1 | 30 | Nights | 295 | 5 (3,9)
High Risk Not Described as Rule In
Twerenbold 2019 31345421 | ADP 0/1 | 30 | Nights | 677 | 5 (2,8)

Abbreviations. ADP=accelerated diagnostic protocol; ESC=European Society of Cardiology; IQR=interquartile range; N=sample size; PMID=PubMed identifier.