# APPENDIX Q REVASCULARIZATION OUTCOMES

Appendix Table Q-1 Revascularization Comparative Studies

Study PMID, Study Design | FollOW-Up Time (days) | Outcome Definition | Subgroup | Arm | n/N (%) | OR (95% Cl)^*^ | Reported P Value
Overall Comparison: ADP vs hs-cTn without ADP
Hyams 2018 29478861 | 6 wk | CABG | | ADP 0/3 HEART; hs-cTn | 5/449 (1.1); 15/417 (3.6) | 0.3 (0.11,0.84); RD −2.5 (−4.5, −0.5)^*^ | NR
Hyams 2018 29478861 | 6 wk | PCI | | ADP 0/3 HEART | 13/449 (2.9) | 1.33 (0.53,3.84); RD 0.7 (−1.4, 2.8)^*^ | NR
Hyams 2018 29478861 | 6 wk | PCI | | hs-cTn | 9/417 (2.2) | 1.33 (0.53,3.84); RD 0.7 (−1.4, 2.8)^*^ | NR
Hyams 2018 29478861 | 6 wk | Any revascularization | | ADP 0/3 HEART | 18/449 (4.0) | RD −1.7 (−4.6, 1.1)^*^ | NR
Hyams 2018 29478861 | 6 wk | Any revascularization | | hs-cTn | 24/417 (5.8) | RD −1.7 (−4.6, 1.1)^*^
Subgroup Comparison
Stoyanov 2020 31298551 | 30 | PCI | Patients who received coronary angiography | ADP ESC 0/1 | 140/328 (42.7) | RD 0.2 (−7.2, 7.6)^*^ | NR
Stoyanov 2020 31298551 | 30 | PCI | Patients who received coronary angiography | ADP ESC 0/3 | 152/358 (42.5) | RD 0.2 (−7.2, 7.6)^*^ | NR

Notes.

* Calculated by research team.

Abbreviations. ADP=accelerated diagnostic protocol; CABG=coronary artery bypass graft; Cl=confidence interval; ESC=European Society of Cardiology; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; hs-cTn=high-sensitivity cardiac troponin; n/N %=(number of events/sample size) %; NR=not reported; OR=odds ratio; PCI=percutaneous coronary intervention; PMID=PubMed identifier; RD=risk difference; wk=week.

Appendix Table Q-2 Revascularization: Rule Out, Low Risk Not Described as Rule Out, Discharge or Grey Zone, and Rule In or High Risk

Study, Year, PMID | ADP | Follow-up Time (Days) | Outcome Definition | n/N (%)
Rule Out
Chew 2019 31478763 | ADP 0/1 | 30 | PCI | 11/1187 (0.9)
Chew 2019 31478763 | ADP 0/1 | 30 | CABG | 4/1187 (0.3)
Chew 2019 31478763 | ADP 0/1 | 30 | Any revascularization | 15/1187 (1.3)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | PCI | 49/1420 (3.5)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | CABG | 1/1420 (0.1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Any revascularization | 62/1420 (4.4)
Discharge
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | PCI | 1/1619 (0.1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | CABG | 0/1619 (0)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Any revascularization | 10/1619 (0.6)
Observe / Grey Zone
Chew 2019 31478763 | ADP 0/1 | 30 | PCI | 15/308 (4.9)
Chew 2019 31478763 | ADP 0/1 | 30 | CABG | 3/308 (1.0)
Chew 2019 31478763 | ADP 0/1 | 30 | Any revascularization | 18/308 (5.8)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | PCI | 53/581 (9.1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | CABG | 17/581 (2.9)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Any Revascularization | 69/581 (11.9)
Rule In
Chew 2019 31478763 | ADP 0/1 | 30 | PCI | 27/136 (19.9)
Chew 2019 31478763 | ADP 0/1 | 30 | CABG | 6/136 (4.4)
Chew 2019 31478763 | ADP 0/1 | 30 | Anv revascularization | 33/136 (24.3)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | PCI | 116/295 (39.3)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | CABG | 36/295 (12.2)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Any revascularization | 151/295 (51.2)
High Risk Not Described as Rule In
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | CABG (based on admitted) | 54/677 (8)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | PCI (based on admitted) | 217/677 (32.1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Any revascularization (based on admitted) | 272/677 (40.2)

Abbreviations. ADP=accelerated diagnostic protocol; CABG=coronary artery bypass graft; ESC=European Society of Cardiology; n/N %=(number of events/sample size) %; PCI=percutaneous coronary intervention; PMID=PubMed identifier.Appendix R. Hospital length of Stay outcomes