# APPENDIX P CARDIAC TESTING OUTCOMES

Appendix Table P-1 Cardiac Testing Comparative Studies

Study, Year, PMID | Test Category | Test | Subgroup | ADP | n/N (%) | OR (95% Cl)^*^
Overall Comparison: ADP vs ADP
Barnes 2021; 33436490 | Stress test, ECG | Stress ECG | - | STAT ADP 0/2/6 HEART | 90/1124 (8.0) | 1.2 (0.85, 1.57)^*^; RD 1 (−1.2, 3.2)^*^
Barnes 2021; 33436490 | Stress test, ECG | Stress ECG | - | ADP 0/(2 or 3)/6 TIMI | 79/1131 (7.0) | 1.2 (0.85, 1.57)^*^; RD 1 (−1.2, 3.2)^*^
Barnes 2021; 33436490 | Stress test, imaging | Myocardial perfusion scan | - | STAT ADP 0/2/6 HEART | 23/1124 (2.0) | 0.50 (0.30, 0.83)^*^; RD −2 (−3.4, −0.6)^*^
Barnes 2021; 33436490 | Stress test, imaging | Myocardial perfusion scan | - | ADP 0/(2 or 3)/6 TIMI | 45/1131 (4.0) | 0.50 (0.30, 0.83)^*^; RD −2 (−3.4, −0.6)^*^
Barnes 2021; 33436490 | Angiogram, standard | Angiogram | - | STAT ADP 0/2/6 HEART | 10/1124 (0.9) | 0.77 (0.34, 1.77)^*^; RD−0.2 (−1.0, 0.6)^*^
Barnes 2021; 33436490 | Angiogram, standard | Angiogram | - | ADP 0/(2 or 3)/6 TIMI | 13/1131 (1.1) | 0.77 (0.34, 1.77)^*^; RD−0.2 (−1.0, 0.6)^*^
Barnes 2021; 33436490 | Angiogram, imaging | CT angiogram | - | STAT ADP 0/2/6 HEART | 52/1124 (4.6) | 1.6 (1.04, 2.5)^*^; RD 1.7 (0.1, 3.3)^*^
Barnes 2021; 33436490 | Angiogram, imaging | CT angiogram | - | ADP 0/(2 or 3)/6 TIMI | 33/1131 (2.9) | 1.6 (1.04, 2.5)^*^; RD 1.7 (0.1, 3.3)^*^
Stoyanov 2020; 31298551 | Stress test, ECG | Stress ECG | Rule out and direct discharge | ADP ESC 0/1 | 89/806 (11) | 1.1 (0.77, 1.49)^*^; RD 0.6 (−2.6, 3.8)^*^
Stoyanov 2020; 31298551 | Stress test, ECG | Stress ECG | Rule out and direct discharge | ADP ESC 0/3 | 70/672 (10.4) | 1.1 (0.77, 1.49)^*^; RD 0.6 (−2.6, 3.8)^*^
Stoyanov 2020; 31298551 | Stress test, imaging | Myocardial perfusion scan | - | - | -
Stoyanov 2020; 31298551 | Stress test, imaging | Stress echocardiogram | Rule out and direct discharge | ADP ESC 0/1 | 5/806 (0.6) | 0.69 (0.21, 2.28)^*^; RD−0.3 (−1.2, 0.6)^*^
Stoyanov 2020; 31298551 | Stress test, imaging | Stress echocardiogram | Rule out and direct discharge | ADP ESC 0/3 | 6/672 (0.9) | 0.69 (0.21, 2.28)^*^; RD−0.3 (−1.2, 0.6)^*^
Stoyanov 2020; 31298551 | Stress test, imaging | Cardiac MRI stress test | Rule out and direct discharge | ADP ESC 0/1 | 7/806 (0.9) | 1.9 (0.50, 7.6)^*^; RD 0.5 (−0.3, 1.3)^*^
Stoyanov 2020; 31298551 | Stress test, imaging | Cardiac MRI stress test | Rule out and direct discharge | ADP ESC 0/3 | 3/672 (0.4) | 1.9 (0.50, 7.6)^*^; RD 0.5 (−0.3, 1.3)^*^
Stoyanov 2020; 31298551 | Angiogram, standard | Angiogram | - | ADP ESC 0/1 | 328/1282 (25.6) | 0.85 (0.73, 0.99)^*^; RD −3.2 (−6.7, 0.3)^*^
Stoyanov 2020; 31298551 | Angiogram, standard | Angiogram | - | ADP ESC 0/3 | 358/1243 (28.8) | 0.85 (0.73, 0.99)^*^; RD −3.2 (−6.7, 0.3)^*^
Stoyanov 2020; 31298551 | Angiogram, imaging | CT angiogram | Rule out and direct discharge | ADP ESC 0/1 | 9/806 (1.1) | 1.5 (0.50, 4.5)^*^; RD 0.4 (−0.6, 1.4)^*^
Stoyanov 2020; 31298551 | Angiogram, imaging | CT angiogram | Rule out and direct discharge | ADP ESC 0/3 | 5/672 (0.7) | 1.5 (0.50, 4.5)^*^; RD 0.4 (−0.6, 1.4)^*^

Notes.

* Calculated by research team.

Abbreviations. ADP=accelerated diagnostic protocol; Cl=confidence interval; CT=computerized tomography scan; ECG=electrocardiogram; ESC=European Society of Cardiology; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; MRI=magnetic resonance imaging; n/N %=(number of events/sample size) %; OR=odds ratio; PMID=PubMed identifier; RD=risk difference; STAT=single troponin accelerated triage; TIMI=Thrombolysis in Myocardial Infarction.

Appendix Table P-2 Cardiac Testing: Rule Out, Low Risk Not Described as Rule Out, Discharge or Grey Zone, and Rule In or High Risk

Outcome (Test) | Diagnosis Category | Study, Year, PMID | ADP | n/N | %
Stress test, any | Rule out | Chew 2019 31478763 | ADP 0/1 | 61/1187 | 5.1
Stress test, any | Rule out | Twerenbold 2019 31345421 | ADP ESC 0/1 | 125/1420 | 8.8
Stress test, any | Low risk | Ljung 2019 30661856 | ADP 0/1 HEART | 31/308 | 10.1
Stress test, any | Discharge | Twerenbold 2019 31345421 | ADP ESC 0/1 | 104/1619 | 6.4
Stress test, any | Observe/grey zone | Chew 2019 31478763 | ADP 0/1 | 41/308 | 13.2
Stress test, any | Observe/grey zone | Twerenbold 2019 31345421 | ADP ESC 0/1 | 58/581 | 10.0
Stress test, any | Rule in | Chew 2019 31478763 | ADP 0/1 | 19/136 | 14.0
Stress test, any | Rule in | Twerenbold 2019 31345421 | ADP ESC 0/1 | 92/677 | 13.6
Stress test, any | High risk | Ljung 2019 30661856^a^ | ADP 0/1 HEART | 21/139 | 15.1
Stress test, any | High risk | Ljung 2019 30661856^b^ | ADP 0/1 HEART | 12/130 | 9.2
Stress test, ECG | Rule out | Chew 2019 31478763 | ADP 0/1 | 17/1187 | 1.4
Stress test, ECG | Rule out | Twerenbold 2019 31345421 | ADP ESC 0/1 | 81/1420 | 5.7
Stress test, ECG | Rule out | Stoyanov 2020 31298551^c^ | ADP ESC 0/1 | 89/806 | 11
Stress test, ECG | Rule out | Stoyanov 2020 31298551^c^ | ADP ESC 0/3 | 70/672 | 10.4
Stress test, ECG | Discharge | Twerenbold 2019 31345421 | ADP ESC 0/1 | 61/1619 | 3.8
Stress test, ECG | Observe/grey zone | Chew 2019 31478763 | ADP 0/1 | 15/308 | 4.9
Stress test, ECG | Observe/grey zone | Twerenbold 2019 31345421 | ADP ESC 0/1 | 39/581 | 6.7
Stress test, ECG | Rule in | Chew 2019 31478763 | ADP 0/1 | 3/136 | 2.2
Stress test, ECG | Rule in | Twerenbold 2019 31345421^d^ | ADP ESC 0/1 | 11 /295 | 3.7
Stress test, ECG | Rule in | Twerenbold 2019 31345421^e^ | ADP ESC 0/1 | 70/677 | 10.3
Stress test, ECG | High risk | - | - | - | -
Stress test, imaging | Rule out | Chew 2019 31478763^f^ | ADP 0/1 | 40/1187 | 3.4
Stress test, imaging | Rule out | Chew 2019 31478763^g^ | ADP 0/1 | 4/1187 | 0.3
Stress test, imaging | Rule out | Stoyanov 2020 31298551^h^ | ADP ESC 0/1 | 5/806 | 0.6
Stress test, imaging | Rule out | Stoyanov 2020 31298551^h^ | ADP ESC 0/3 | 6/672 | 0.9
Stress test, imaging | Rule out | Stoyanov 2020 31298551^i^ | ADP ESC 0/1 | 7/806 | 0.9
Stress test, imaging | Rule out | Stoyanov 2020 31298551^i^ | ADP ESC 0/3 | 3/672 | 0.4
Stress test, imaging | Discharge | - | - | - | -
Stress test, imaging | Observe/grey zone | Chew 2019 31478763^f^ | ADP 0/1 | 25/308 | 8.1
Stress test, imaging | Observe/grey zone | Chew 2019 31478763^g^ | ADP 0/1 | 3/308 | 1.0
Stress test, imaging | Rule in | Chew 2019 31478763 | ADP 0/1 | 7/136 | 5.1
Stress test, imaging | High risk | - | - | - | -
Angiogram, Standard | Rule out | Chew 2019 31478763 | ADP 0/1 | 59/1187 | 5.0
Angiogram, Standard | Rule out | Twerenbold 2019 31345421 | ADP ESC 0/1 | 82/1420 | 5.8
Angiogram, Standard | Rule out | Stoyanov 2020 31298551 | ADP ESC 0/1 | 328/1282 | 25.6
Angiogram, Standard | Rule out | Stoyanov 2020 31298551 | ADP ESC 0/3 | 358/1243 | 28.8
Angiogram, Standard | Discharge | Twerenbold 2019 31345421 | ADP ESC 0/1 | 14/1619 | 0.9
Angiogram, Standard | Observe/grey zone | Chew 2019 31478763 | ADP 0/1 | 43/308 | 14.0
Angiogram, Standard | Observe/grey zone | Twerenbold 2019 31345421 | ADP ESC 0/1 | 109/581 | 18.8
Angiogram, Standard | Rule in | Chew 2019 31478763 | ADP 0/1 | 69/136 | 50.7
Angiogram, Standard | Rule in | Twerenbold 2019 31345421^d^ | ADP ESC 0/1 | 211/295 | 71.5
Angiogram, Standard | Rule in | Twerenbold 2019 31345421^e^ | ADP ESC 0/1 | 388/677 | 57.3
Angiogram, Standard | High risk | - | - | - | -
Angiogram, imaging | Rule out | Stoyanov 2020 31298551^c^ | ADP ESC 0/1 | 9/806 | 1.1
Angiogram, imaging | Rule out | Stoyanov 2020 31298551^c^ | ADP ESC 0/3 | 5/672 | 0.7
Angiogram, imaging | Discharge | - | - | - | -
Angiogram, imaging | Observe/grey zone | - | - | - | -
Angiogram, imaging | Rule in | Chew 2019 31478763 | ADP 0/1 | 0/136 | 0.0
Angiogram, imaging | High risk | - | - | - | -

Notes.

a High risk based on HEART score ≥4;

b High risk based on hs-TnT > 14 ng/L hs-cTnl ≥ 35 ng/L (♂) hs-cTnl ≥16 ng/L (♀);

c Rule out and discharge subgroup;

d Rule in subgroup;

e Admitted subgroup;

f Stress echocardiogram;

g Cardiac MRI stress test;

h Stress echocardiogram in rule out and direct discharge group;

i Stress MRI in rule out and direct discharge group.

Abbreviations. ADP=accelerated diagnostic protocol; ECG=electrocardiograph; ESC=European Society of Cardiology; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; n/N=number of events/sample size; PMID=PubMed identifier.