# APPENDIX O DEATH OUTCOMES

Appendix Table O-1 Death Comparative Studies

Study PMID, Study Design | Follow-up Time (Days) | Outcome Definition | Subgroup | Arm | n/N (%) | OR (95% Cl)^*^ | Reported P Value
Overall Comparison: ADP vs hs-cTn without ADP
Hyams 2018; 29478861 | 6 wk | All-cause | | ADP 0/3 HEART | 1/449 (0.2) | 0.23 (0.03,2.08); RD −0.8 (−1.8, 0.2)^*^ | NR
Hyams 2018; 29478861 | 6 wk | All-cause | | hs-cTn | 4/417 (1.0) | 0.23 (0.03,2.08); RD −0.8 (−1.8, 0.2)^*^ | NR
Overall Comparison: ADP vs ADP
Barnes 2021; 33436490 | 30 | All-cause | | STAT ADP 0/2/6 HEART | 0/1124 (0) | | NR
Barnes 2021; 33436490 | 30 | All-cause | | ADP 0/(2 or 3)/6 TIMI | 0/1131 (0) | | NR
Sandeman 2021; 34824100 | 30 | All-cause | | ADP 0/3/6 | 141/3673 (3.8) | RD0.1 (−0.7, 0.9)^*^ | NR
Sandeman 2021; 34824100 | 30 | All-cause | | ADP 0/6/12 GRACE | 245/6642 (3.7) | RD0.1 (−0.7, 0.9)^*^ | NR
Sandeman 2021; 34824100 | 30 | Cardiovascular | | ADP 0/3/6 | 82/3673 (2.2) | RD 0.1 (−0.5, 0.7)^*^ | NR
Sandeman 2021; 34824100 | 30 | Cardiovascular | | ADP 0/6/12 GRACE | 139/6642 (2.1) | RD 0.1 (−0.5, 0.7)^*^ | NR
Than 2016; 26947800 | ED Visit | All-cause | | ADP 0/2 ED ACS | 0/279 (0) | RD −0.4 (−0.7, 1.4)^*^ | NR
Than 2016; 26947800 | ED Visit | All-cause | | ADAPT ADP 0/2 TIMI | 1/279 (0.4) occurred in non-low risk patients | RD −0.4 (−0.7, 1.4)^*^ | NR
Subgroup Comparison
Sandeman 2021; 34824100 | 30 | All-cause | Patients with Toponin <5 ng/L | ADP 0/3/6 | 1/945 (0.1) | RD 0 (− 0.2, 0.2)^*^ | NR
Sandeman 2021; 34824100 | 30 | All-cause | Patients with Toponin <5 ng/L | ADP 0/6/12 GRACE | 1/2188 (0.1) | RD 0 (− 0.2, 0.2)^*^ | NR
Sandeman 2021; 34824100 | 30 | All-cause | Patients with roponin 5-14 ng/L | ADP 0/3/6 | 12/1380 (0.9) | RD 0.2 (− 0.4, 0.8)^*^ | NR
Sandeman 2021; 34824100 | 30 | All-cause | Patients with roponin 5-14 ng/L | ADP 0/6/12 GRACE | 14/1885 (0.7) | RD 0.2 (− 0.4, 0.8)^*^ | NR
Sandeman 2021; 34824100 | 30 | All-cause | Patients with troponin >14ng/L | ADP 0/3/6 | 128/1348 (9.5) | RD 0.5 (−1.4, 2.4)^*^ | NR
Sandeman 2021; 34824100 | 30 | All-cause | Patients with troponin >14ng/L | ADP 0/6/12 GRACE | 230/2569 (9) | RD 0.5 (−1.4, 2.4)^*^ | NR
Sandeman 2021; 34824100 | 30 | Cardiovascular | Patients with troponin <5 ng/L | ADP 0/3/6 | 1/945 (0.1) | RD 0 (− 0.2, 0.2)^*^ | NR
Sandeman 2021; 34824100 | 30 | Cardiovascular | Patients with troponin <5 ng/L | ADP 0/6/12 GRACE | 1/2188 (0.1) | RD 0 (− 0.2, 0.2)^*^ | NR
Sandeman 2021; 34824100 | 30 | Cardiovascular | Patients with troponin 5-14 ng/L | ADP 0/3/6 | 8/1380 (0.6) | RD 0.4 (−0.1, 0.9)^*^ | NR
Sandeman 2021; 34824100 | 30 | Cardiovascular | Patients with troponin 5-14 ng/L | ADP 0/6/12 GRACE | 4/1885 (0.2) | RD 0.4 (−0.1, 0.9)^*^ | NR
Sandeman 2021; 34824100 | 30 | Cardiovascular | Patients with troponin >14ng/L | ADP 0/3/6 | 73/1348 (5.4) | RD 0.2 (−1.3, 1.7)^*^ | NR
Sandeman 2021; 34824100 | 30 | Cardiovascular | Patients with troponin >14ng/L | ADP 0/6/12 GRACE | 134/2569 (5.2) | RD 0.2 (−1.3, 1.7)^*^ | NR

Notes.

* Calculated by research team.

Abbreviations. ADP=accelerated diagnostic protocol; Cl=confidence interval; ED=emergency department; EDACS=Emergency Department Assessment of Chest Pain Score; GRACE=Global Registry of Acute Coronary Events; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; hs-cTn=high-sensitivity cardiac troponin; n/N %=(number of events/sample size) %; NR=not reported; OR=odds ratio; PMID=PubMed identifier; RD=risk difference; STAT=single troponin accelerated triage; TIMI=Thrombolysis in Myocardial Infarction; wk=week.

Appendix Table O-2 Death: Rule Out, Low Risk Not Described as Rule-Out, Discharge or Grey Zone, and Rule In or High Risk

Study, Year, PMID | ADP | Follow-up Time (Days) | Outcome Definition | n/N (%)
Rule Out
Chew 2019 31478763 | ADP 0/1 | 30 | All-cause | 1/1187 (0.1)
Chew 2019 31478763 | ADP 0/1 | 30 | Cardiovascular | 1/1187 (0.1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | All-cause | 2/1420 (0.1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Cardiovascular | 1/1420 (0.1)
Low-Risk Not Described as Rule Out
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | All-cause after discharge (based on HEART score ≤3) | 0/308 (0)
Sandeman 202134824100 | ADP 0/3/6 | 30 | All-cause (based on hs-TnT < 5 ng/L) | 1/945 (0.1)
Sandeman 202134824100 | ADP 0/3/6 | 30 | Cardiovascular (based on hs-TnT < 5 ng/L) | 1/945 (0.1)
Sandeman 2021 34824100 | ADP 0/6/12 GRACE | 30 | All-cause (based on hs-TnT < 5 ng/L) | 1/2188 (0.1)
Sandeman 2021 34824100 | ADP 0/6/12 GRACE | 30 | Cardiovascular (based on hs-TnT < 5 ng/L) | 1/2188 (0.1)
Discharge
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | All-cause | 0/419 (0)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | All-cause | 1/1619 (0.1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Cardiovascular | 1/1619 (0.1)
Costable 2014 | ADP 0/3 | 30 | All-cause | 0/479 (0)
Observe / Grey Zone
Chew 2019 31478763 | ADP 0/1 | 30 | All-cause | 1/308 (0.3)
Chew 2019 31478763 | ADP 0/1 | 30 | Cardiovascular | 1/308 (0.3)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | All-cause | 1/581 (0.2)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Cardiovascular | 1/581 (0.2)
Rule In
Chew 2019 31478763 | ADP 0/1 | 30 | All-cause | 0/136 (0.0)
Chew 2019 31478763 | ADP 0/1 | 30 | Cardiovascular | 0/136 (0.0)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | All-cause | 5/295 (1.7)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Cardiovascular | 3/295 (1)
High Risk Not Described as Rule In
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | All-cause after discharge (based on admitted) | 0/202 (0)
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | All-cause after discharge (based on HEART score ≥4) | 0/139 (0)
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | All-cause after discharge (based on hs-TnT >14 ng/L hs-cTnl ≥35 ng/L (♂) hs-cTnl ≥16 ng/L (♀)) | 0/130 (0)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | All-cause (based on admitted) | 7/677 (1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Cardiovascular (based on admitted) | 4/677 (0.6)
Costable 2014 | ADP 0/3 | 30 | All-cause (based on admitted) | 0/49 (0)
Sandeman 2021 34824100 | ADP 0/3/6 | 30 | All-cause (based on hs-TnT >14 ng/L) | 128/1348 (9.5)
Sandeman 2021 34824100 | ADP 0/3/6 | 30 | Cardiovascular (based on hs-TnT >14 ng/L) | 73/1348 (5.4)
Sandeman 2021 34824100 | ADP 0/6/12 GRACE | 30 | All-cause (based on hs-TnT >14 ng/L) | 230/2569 (9)
Sandeman 2021 34824100 | ADP 0/6/12 GRACE | 30 | Cardiovascular (based on hs-TnT >14 ng/L) | 134/2569 (5.2)

Abbreviations. ADP=accelerated diagnostic protocol; ESC=European Society of Cardiology; GRACE=Global Registry of Acute Coronary Events; HEART=History, Electrocardiogram, Age, Risk factors, Troponin); hs-Tnl/T=high-sensitivity cardiac troponin I/T; n/N %=(number of events/sample size) %; PMID=PubMed identifier.