# APPENDIX N MI OUTCOMES

Appendix Table N-1 MI Comparative Studies

Study PMID, Study Design | Follow-up Time (days) | Outcome Definition | Subgroup | Arm | n/N (%) | OR (95% CI) | Reported P Value
Overall Comparison: ADP vs hs-cTn without ADP
Hyams 2018 29478861 | 6 wk | MI | | ADP 0/3 HEART | 21/449 (4.7) | 0.96 (0.52,1.81); RD −0.1 (−2.9, 2.7)^*^ | NR
Hyams 2018 29478861 | 6 wk | MI | | hs-cTn | 20/417 (4.8) | 0.96 (0.52,1.81); RD −0.1 (−2.9, 2.7)^*^ | NR
Overall Comparison: ADP vs ADP
Anand 2021 33752439 | 30 | Type 1/4b/4c | | High-STEACS ADP 0/3 | 38/16792 (0.2) | 0.76 (0.49, 1.17)^*^; RD −0.1 (−0.2, 0.01)^*^ | NR
Anand 2021 33752439 | 30 | Type 1/4b/4c | | ADP 0/6/12 | 44/14700 (0.3) | 0.76 (0.49, 1.17)^*^; RD −0.1 (−0.2, 0.01)^*^ | NR
Anand 2021 33752439 | 30 | Type 1/2/4b/4c | | High-STEACS ADP 0/3 | 50/16792 (0.3) | 0.75 (0.52, 1.10)^*^; RD −0.1 (−0.2,0.03)^*^ | NR
Anand 2021 33752439 | 30 | Type 1/2/4b/4c | | ADP 0/6/12 | 58/14700 (0.4) | 0.75 (0.52, 1.10)^*^; RD −0.1 (−0.2,0.03)^*^ | NR
Barnes 2021 33436490 | 30 | MI | | STAT ADP 0/2/6 HEART | 0/1124 (0) | | NR
Barnes 2021 33436490 | 30 | MI | | ADP 0/(2 or 3)NR/6 TIMI | 0/1131 (0.0) | | NR
Than 2016 26947800 | 30 | NSTEMI | | ADP 0/2 EDACS | 2/279 (0.7) | RD 0.7 (−2.1,0.6) | NR
Than 2016 26947800 | 30 | NSTEMI | | ADAPT ADP 0/2 TIMI | 0/279 (0) | RD 0.7 (−2.1,0.6) | NR
Than 2016 26947800 | 30 | STEMI | | ADP 0/2 EDACS | 0/279 (0) | RD −0.4 (−0.7,1.4) | NR
Than 2016 26947800 | 30 | STEMI | | ADAPT ADP 0/2 TIMI | 1/279 (0.4) all in non-low-risk patients | RD −0.4 (−0.7,1.4) | NR
Than 2016 26947800 | ED visit | STEMI | | ADP 0/2 EDACS | 2/279 (0.7) | RD −0.4 (−1.6,2.3) | NR
Than 2016 26947800 | ED visit | STEMI | | ADAPT ADP 0/2 TIMI | 3 /279 (1.1) | RD −0.4 (−1.6,2.3) | NR
Than 2016 26947800 | ED visit | NSTEMI | | ADP 0/2 EDACS | 34/279 (12.2) all in non-low-risk patients | RD 2.9 (−8.4,2.6) | NR
Than 2016 26947800 | ED visit | NSTEMI | | ADAPT ADP 0/2 TIMI | 26 /279 (9.3) all in non-low-risk patients | RD 2.9 (−8.4,2.6) | NR
Subgroup Comparison
Than 2016 26947800 | 30 | NSTEMI | Low-risk patients | ADP 0/2 EDACS | 0/116 (0) | | NR
Than 2016 26947800 | 30 | NSTEMI | Low-risk patients | ADAPT ADP 0/2 TIMI | 0/85 (0) | | NR
Than 2016 26947800 | 30 | STEMI | Low-risk patients | ADP 0/2 EDACS | 0/116 (0) | | NR
Than 2016 26947800 | 30 | STEMI | Low-risk patients | ADAPT ADP 0/2 TIMI | 0/85 (0) | | NR

Notes.

* Calculated by research team.

Abbreviations. ADP=accelerated diagnostic protocol; CI=confidence interval; ED=emergency department; EDACS=Emergency Department Assessment of Chest Pain Score; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; High-STEACS=High-Sensitivity Troponin in the Evaluation of Patients With Suspected Acute Coronary Syndrome; hs-cTn=high-sensitivity cardiac troponin; MI=myocardial infarction; n/N %=(number of events/sample size) %; NR=not reported; NSTEMI=non ST-elevation myocardial infarction; OR=odds ratio; PMID=PubMed identifier; RD=risk difference; STAT=single troponin accelerated triage; STEMI=ST-elevation myocardial infarction; TIMI=Thrombolysis in Myocardial Infarction; wk=week.

Appendix Table N-2 MI: Rule Out, Low Risk Not Described as Rule Out, Discharge or Grey Zone, and Rule In or High Risk

Study, Year, PMID | ADP | Follow-up Time (days) | Outcome Definition | n/N (%)
Rule Out
Chew 2019 31478763 | ADP 0/1 | 30 | Type 1/2/4a/5 | 5/1187 (0.4)
Chew 2019 31478763 | ADP 0/1 | 30 | MI or myocardial injury | 9/1187 (0.8)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | MI | 2/1420 (0.1)
Low Risk Not Described as Rule Out
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | MI (Based on HEART score ≤3) | 0/308 (0)
Than 2016 26947800 | ADP 0/2 EDACS | 30 | NSTEMI | 0/116 (0)
Than 2016 26947800 | ADP 0/2 EDACS | 30 | STEMI | 0/116 (0)
Than 2016 26947800 | ADAPT ADP 0/2 TIMI | 30 | NSTEMI | 0/85 (0)
Than 2016 26947800 | ADAPT ADP 0/2 TIMI | 30 | STEMI | 0/85 (0)
Discharge
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | MI | 2/419 (0.5)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | MI | 0 /1619 (0)
Costable 2014 | ADP 0/3 | 30 | MI | 0/479 (0)
Observe / Grey Zone
Chew 2019 31478763 | ADP 0/1 | 30 | Type 1/2/4a/5 | 6/308 (1.9)
Chew 2019 31478763 | ADP 0/1 | 30 | MI or myocardial injury | 9/308 (2.9)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | MI | 30/581 (5.2)
Rule In
Chew 2019 31478763 | ADP 0/1 | 30 | Type 1/2/4a/5 | 5/136 (3.7)
Chew 2019 31478763 | ADP 0/1 | 30 | MI or myocardial injury | 8/136 (5.9)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | MI | 195/295 (66.1)
High Risk Not Described as Rule In
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | MI after discharge (among those who admitted) | 1/202 (0.5)
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | MI (patients with HEART ≥4) | 0/139 (0)
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | MI (patients with hs-cTnT >14 ng/L hs-cTnI ≥35 ng/L (♂) hs-cTnI ≥16 ng/L (♀)) | 1/130 (0.8)
Ljung 2019 30661856 | ADP 0/1 HEART | In-hospital stay | MI (among those who admitted) | 44/202 (21.8)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | MI (based on admitted) | 227/677 (33.5)
Than 2016 26947800 | ADP 0/2 EDACS | 30 | NSTEMI | 2/279 (0.7)
Than 2016 26947800 | ADP 0/2 EDACS | 30 | STEMI | 0/279 (0)
Than 2016 26947800 | ADAPT ADP 0/2 TIMI | 30 | NSTEMI | 0/279 (0)
Than 2016 26947800 | ADAPT ADP 0/2 TIMI | 30 | STEMI | 1/279 (0.4)
Costable 2014 | ADP 0/3 | 30 | MI (based on admitted) | 33/49 (67.3)

Abbreviations. ADP=accelerated diagnostic protocol; EDACS=Emergency Department Assessment of Chest Pain Score; ESC=European Society of Cardiology; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; hs-cTnI/T=high-sensitivity cardiac troponin I/T; MI=myocardial infarction; n/N %=(number of events/sample size) %; NSTEMI=non ST-elevation myocardial infarction; PMID=PubMed identifier; STEMI=ST-elevation myocardial infarction; TIMI=Thrombolysis in Myocardial Infarction.