# APPENDIX M RETURN TO ED OR HOSPITAL OUTCOMES

Appendix Table M-1 Return to ED or Hospital Comparisons

Study PMID, Study | Follow-up Time (days) | Outcome Definition | Subgroup | Arm | n/N (%) | RD (95% CI)^*^ | Reported P Value
ADP Comparison
Barnes 2021; 33436490 | 30 | All cause | | STAT ADP 0/2/6 HEART | 107/1124 (9.5) | RD 1.1 (−1.3, 3.4)^*^ | NR
Barnes 2021; 33436490 | 30 | All cause | | ADP 0/(2 or 3)/6 TIMI | 95/1131 (8.4) | RD 1.1 (−1.3, 3.4)^*^ | NR
Subgroup Comparison
Barnes 2021; 33436490 | 30 | Chest pain | Patients who returned to ED | STAT ADP 0/2/6 HEART | 33/107 (31.0) | RD −2 (−14.9, 10.9)^*^ | NR
Barnes 2021; 33436490 | 30 | Chest pain | Patients who returned to ED | ADP 0/2 or 3/6 TIMI | 31/95 (33.0) | RD −2 (−14.9, 10.9)^*^ | NR

Notes.

* Calculated by research team.

Abbreviations. ADP=accelerated diagnostic protocol; CI=confidence interval; ED=emergency department; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; n/N %=(number of events/sample size) %; OR=odds ratio; PMID=PubMed identifier; RD=risk difference; STAT=single troponin accelerated triage; TIMI=Thrombolysis in Myocardial Infarction.

Appendix Table M-2 Return to ED or Hospital Comparisons: Rule Out, Low Risk Not Described as Rule Out, Discharge or Grey Zone, and Rule In or High Risk

Study, Year, PMID | ADP | Follow-up Time (Days) | Outcome Definition | n/N (%)
Rule Out
Chew 2019 31478763 | ADP 0/1 | 30 | Chest pain related | 41/1187 (3.5)
Low Risk Not Described as Rule Out
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | All-cause (Based on HEART score ≤3) | 16/308 (5.2)
Discharge
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | All-cause | 45/419 (10.7)
Observe / Grey Zone
Chew 2019 31478763 | ADP 0/1 | 30 | Myocardial injury related | 11/308 (3.6)
Chew 2019 31478763 | ADP 0/1 | 30 | Chest pain related | 22/308 (7.1)
Rule In
Chew 2019 31478763 | ADP 0/1 | 30 | Chest pain related | 7/136 (5.1)
High Risk Not Described as Rule In
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | All-cause (Based on admitted) | 36/202 (17.8)
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | All-cause (Based on HEART score ≥4) | 27 /139 (19.4)
Ljung 2019 30661856 | ADP 0/1 HEART | 30 | All-cause (Based on hs-TnT >14 ng/L hs-cTnI ≥35 ng/L (♂) hs-cTnI ≥16 ng/L (♀) | 29/130 (22.3)

Abbreviations. ADP=accelerated diagnostic protocol; ED=emergency department; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; hscTnI/T=high-sensitivity cardiac troponin I/T; n/N %=(number of events/sample size) %; PMID = PubMed identifier.