# APPENDIX L DISCHARGE OUTCOMES

Appendix Table L-1 ED Discharge to Community versus Hospital Admission Comparative Studies

Study PMID, Study Design | Follow-up Time (days) | Outcome Definition | Subgroup | Arm | n/N (%) | OR (95% CI)^*^ | Reported P Value
Overall Comparison: ADP vs hs-cTn without ADP
Hyams 2018; 29478861 | ED Visit | ED discharge^*^ | | ADP 0/3 HEART | 232/449 (51.7)^*^ | RD 15.2 (8.7, 21.7)^*^ | <0.001
Hyams 2018; 29478861 | ED Visit | ED discharge^*^ | | Hs-cTn | 152/417 (36.5)^*^ | RD 15.2 (8.7, 21.7)^*^ | <0.001
Overall Comparison: ADP vs ADP
Anand 2021; 33752439 | ED Visit | ED discharge | | High-STEACS ADP 0/3 | 11842/16792 (71) | aOR 1.59 (1.45, 1.75); RD 21 (20.0, 22.0)^*^ | <0.001
Anand 2021; 33752439 | ED Visit | ED discharge | | ADP 0/6/12 | 7407/14700 (50) | aOR 1.59 (1.45, 1.75); RD 21 (20.0, 22.0)^*^ | <0.001
Barnes 2021; 33436490 | ED Visit | ED discharge | | STAT ADP 0/2/6 HEART | 709/1124 (63) | aOR 2.75 (2.29, 3.29); RD 25 (21.0, 29.0)^*^ | <0.001
Barnes 2021; 33436490 | ED Visit | ED discharge | | ADP 0/2 or 3/6 TIMI | 430/1131 (38) | aOR 2.75 (2.29, 3.29); RD 25 (21.0, 29.0)^*^ | <0.001
Than 2021; 33753972 | ED visit | ED discharge for patients with chest pain presentation^*^ | | COVID-ADP 0/2 EDACS | 90.7%^*^ | RD 3 (0.5, 5.5)^*^ | NR
Than 2021; 33753972 | ED visit | ED discharge for patients with chest pain presentation^*^ | | ADP 0/2/6 EDACS | 87.7%^*^ | RD 3 (0.5, 5.5)^*^ | NR

Notes.

* Calculated by research team.

Abbreviations. ADP=accelerated diagnostic protocol; aOR=adjusted odds ratio; CI=confidence interval; ED=emergency department; EDACS=Emergency Department Assessment of Chest Pain Score; High-STEACS=High-sensitivity Troponin in the Evaluation of Patients With Suspected Acute Coronary Syndrome; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; hs-cTn=high-sensitivity cardiac troponin; n/N %=(number of events/sample size) %; NR=not reported; OR=odds ratio; PMID=PubMed identifier; RD=risk difference; STAT=single troponin accelerated triage; TIMI=Thrombolysis in Myocardial Infarction.

Appendix Table L-2 ED Discharge to Community versus Hospital Admission: Rule Out, Low Risk Not Described as Rule Out, Discharge or Grey Zone, and Rule In or High Risk

Study, Year, PMID | ADP | Outcome Definition | n/N (%)
Rule Out
Chew 2019 31478763 | ADP 0/1 | ED discharge to home | 589/1187 (49.6)
Twerenbold 2019 31345421 | ADP ESC 0/1 | ED discharge to home | 1243/1420 (88)
Low Risk Not Described as Rule Out
Ljung 2019 30661856 | ADP 0/1 HEART | ED discharge to home (based on HEART score ≤3) | 269/308 (87.3)
Observe / Grey Zone
Chew 2019 31478763 | ADP 0/1 | ED discharge to home | 84/308 (27.3)
Twerenbold 2019 31345421 | ADP ESC 0/1 | ED discharge to home | 352/581 (61)
Rule In
Chew 2019 31478763 | ADP 0/1 | ED discharge to home | 12/136 (8.8)
Twerenbold 2019 31345421 | ADP ESC 0/1 | ED discharge to home | 2/295 (8)
High Risk Not Described as Rule In
Ljung 2019 30661856 | ADP 0/1 HEART | ED discharge (based on HEART score ≥4) | 87/139 (62.6)
Ljung 2019 30661856 | ADP 0/1 HEART | ED discharge (based on hs-cTnT >14 ng/L hs-cTnI ≥35 ng/L (♂) hs-cTnI ≥16 ng/L (♀)) | 41/130 (31.5)

Abbreviations. ADP=accelerated diagnostic protocol; ED=emergency department; ESC=European Society of Cardiology; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; hs-cTnI/T=high-sensitivity cardiac troponin I/T; n/N %=(number of events/sample size) %; PMID=PubMed identifier.