# APPENDIX K ED LENGTH OF STAY OUTCOMES

Appendix Table K-1 ED Length of Stay (Continuous) Comparative Studies

Study, Year, PMID | Outcome Definition | Subgroup | Arm^*^ | N | Mean (SD) | MD (95% CI) | Reported P Value
Overall Comparison: ADP vs ADP
Anand 2021; 33752439 | LOS | | High-STEACS ADP 0/3 | 16792 | 6.8 (4.1) | Geometric Mean 0.78 (0.73, 0.83) | <0.001
Anand 2021; 33752439 | LOS | | ADP 0/6/12 | 14700 | 10 (4.1) | Geometric Mean 0.78 (0.73, 0.83) | <0.001
Barnes 2021; 33436490 | LOS | | STAT ADP 0/2/6 HEART | 1124 | Median (IQR) 3.6 (2.6, 5.4) | IRR 0.71 (0.65, 0.77) | <0.001
Barnes 2021; 33436490 | LOS | | ADP 0/(2 or 3)/6 TIMI | 1131 | Median (IQR) 4.3 (3.3, 7.1) | IRR 0.71 (0.65, 0.77) | <0.001
Sandeman 2021; 34824100 | LOS | | ADP 0/3/6 | 3673 | Median (IQR) 6.5 (6.3, 19.8) | 1.34% (−2.21%, −0.26%) reduction in LOS associated with early rule-out | <0.001
Sandeman 2021; 34824100 | LOS | | ADP 0/6/12 GRACE | 6642 | Median (IQR) 8.9 (3.7, 38.0) | 1.34% (−2.21%, −0.26%) reduction in LOS associated with early rule-out | <0.001
Stoyanov 2020; 31298551 | LOS | | ADP ESC 0/1 | 1282 | Median (IQR) 3.2 (2.7, 4.4) | Difference in median hours: −2.1^*^ | <0.001
Stoyanov 2020; 31298551 | LOS | | ADP ESC 0/3 | 1243 | Median (IQR) 5.3 (4.7, 6.5) | Difference in median hours: −2.1^*^ | <0.001
Than 2021; 33753972 | LOS | | COVID-ADP 0/2 EDACS | 1343 | Median (IQR) 3.4 (2.6, 4.6) | Difference in median hours: −0.4^*^ | <0.001
Than 2021; 33753972 | LOS | | ADP 0/2/6 EDACS | 1073 | Median (IQR) 3.8 (2.8, 4.9) | Difference in median hours: −0.4^*^ | <0.001
Subgroup Comparisons
Costable 2014 | LOS | CP >6h | ADP 0/3 | 264 | 2.9 (2) | | 0.352
Costable 2014 | LOS | CP >6h | ADP 0/3 | 264 | 5.1 (2.8) | | 0.352
Sandeman 2021; 34824100 | LOS | Patients with troponin <5 ng/L | ADP 0/3/6 | 945 | Median (IQR) 3.7 (170, 329) | 2.99% (−4.32, −1.64) reduction in LOS associated with early ruleout pathway | NR
Sandeman 2021; 34824100 | LOS | Patients with troponin <5 ng/L | ADP 0/6/12 GRACE | 2188 | Median (IQR) 3.9 (3, 8.1) | 2.99% (−4.32, −1.64) reduction in LOS associated with early ruleout pathway | NR
Sandeman 2021; 34824100 | LOS | Patients with troponin 5-14 ng/L | ADP 0/3/6 | 1380 | Median (IQR) 5.2 (3.6, 14.0) | 3.61% (−5.30%, −1.90%) reduction in LOS associated with early ruleout pathway with | NR
Sandeman 2021; 34824100 | LOS | Patients with troponin 5-14 ng/L | ADP 0/6/12 GRACE | 1885 | Median (IQR) 7 (3.6, 20.2) | 3.61% (−5.30%, −1.90%) reduction in LOS associated with early ruleout pathway with | NR
Sandeman 2021; 34824100 | LOS | Patients with troponin >14 ng/L | ADP 0/3/6 | 1348 | Median (IQR) 42.8 (11.3, 103.1) | 0.99% (−0.95%, 2.98%) reduction in LOS associated with early ruleout pathway with duration of stay | NR
Sandeman 2021; 34824100 | LOS | Patients with troponin >14 ng/L | ADP 0/6/12 GRACE | 2569 | Median (IQR) 37.7 (11.1, 100.1) | 0.99% (−0.95%, 2.98%) reduction in LOS associated with early ruleout pathway with duration of stay | NR
Than 2021; 33753972 | LOS | Discharged from ED | COVID-ADP 0/2 EDACS | NR | Mean 3.4 Median (IQR) 3.1 (2.4, 4.1) | Difference in median hours: −0.5 hours^*^ | NR
Than 2021; 33753972 | LOS | Discharged from ED | ADP 0/2/6 EDACS | NR | Mean 3.9 Median (IQR) 3.7 (2.7, 4.6) | Difference in median hours: −0.5 hours^*^ | NR

Notes.

* Calculated by research team.

Abbreviations. ADP=accelerated diagnostic protocol; CI=confidence interval; CP=chest pain; ED=emergency department; EDACS=Emergency Department Assessment of Chest Pain Score; ESC=European Society of Cardiology; GRACE=Global Registry of Acute Coronary Events; h=hour; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; High-STEACS=High-Sensitivity Troponin in the Evaluation of Patients With Suspected Acute Coronary Syndrome; IQR=interquartile range; IRR=incidence rate ratio; LOS=length of stay; MD=mean difference; N=sample size; NR=not reported; PMID=PubMed identifier; SD=standard deviation; STAT=single troponin accelerated triage; TIMI=Thrombolysis in Myocardial Infarction.

Appendix Table K-2 ED Length of Stay (Categorical) Comparative Studies

Study PMID, Study Design | Follow-up Time (days) | Outcome Definition | Subgroup | Arm | n/N (%) | OR (95% CI) | Reported P value
Overall Comparison: ADP vs ADP
Barnes 2021; 33436490 | ED visit | Discharge <3h | | STAT ADP 0/2/6 HEART | 425/1124 (37.8) | aOR 2.1 (1.73,2.55); RD 16.5 (12.8, 20.2)* | <0.001
Barnes 2021; 33436490 | ED visit | Discharge <3h | | ADP 0/(2 or 3)/6 TIMI | 241/1131 (21.3) | aOR 2.1 (1.73,2.55); RD 16.5 (12.8, 20.2)* | <0.001
Sandeman 2021; 34824100 | ED visit | Discharge ≤4h | | ADP 0/3/6 | 1281/3650 (34.9) | RD 2.3 (0.4, 4.2)* | NR
Sandeman 2021; 34824100 | ED visit | Discharge ≤4h | | ADP 0/6/12 GRACE | 2150/6597 (32.6) | RD 2.3 (0.4, 4.2)* | NR
Than 2016; 26947800 | ED visit | Discharge <6h^a^ | | ADP 0/2 EDACS | 90 /279 (32.3) | RD −2.1 (−10.3, 6) | 0.65
Than 2016; 26947800 | ED visit | Discharge <6h^a^ | | ADAPT ADP 0/2 TIMI | 96/279 (34.4) | RD −2.1 (−10.3, 6) | 0.65
Than 2021; 33753972 | ED visit | Discharge <2h | | COVID-ADP 0/2 EDACS | 109/1343 (8.1) | 44.6% increase | NR
Than 2021; 33753972 | ED visit | Discharge <2h | | ADP 0/2/6 EDACS | 60/1073 (5.6) | 44.6% increase | NR
Than 2021; 33753972 | ED Visit | Discharge <3h | | COVID-ADP 0/2 EDACS | 594/1343 (44.2) | 35.2% increase | NR
Than 2021; 33753972 | ED Visit | Discharge <3h | | ADP 0/2/6 EDACS | 351/1073 (32.7) | 35.2% increase | NR
Subgroup Comparison
Sandeman 2021; 34824100 | 30 | Discharge ≤4h | Patients with troponin <5 ng/L | ADP 0/3/6 | 604/945 (63.9) | RD 11.4 (7.7, 15.1)* | NR
Sandeman 2021; 34824100 | 30 | Discharge ≤4h | Patients with troponin <5 ng/L | ADP 0/6/12 GRACE | 1149/2188 (52.5) | RD 11.4 (7.7, 15.1)* | NR
Sandeman 2021; 34824100 | 30 | Discharge ≤4h | Patients with troponin 5-14 ng/L | ADP 0/3/6 | 512/1380 (37.1) | RD 2 (−1.3, 5.3)* | NR
Sandeman 2021; 34824100 | 30 | Discharge ≤4h | Patients with troponin 5-14 ng/L | ADP 0/6/12 GRACE | 661/1885 (35.1) | RD 2 (−1.3, 5.3)* | NR
Sandeman 2021; 34824100 | 30 | Discharge ≤4h | Patients with troponin >14 ng/L | ADP 0/3/6 | 165/1348 (12.2) | RD* −1 (−3.2, 1.2) | NR
Sandeman 2021; 34824100 | 30 | Discharge ≤4h | Patients with troponin >14 ng/L | ADP 0/6/12 GRACE | 340/2569 (13.2) | RD* −1 (−3.2, 1.2) | NR
Than 2016; 26947800 | ED visit | Discharge <6h^a^ | Low-risk patients | ADP 0/2 EDACS | 73/279 (26.2) | RD 3.2 (−4.3,10.7) | NR
Than 2016; 26947800 | ED visit | Discharge <6h^a^ | Low-risk patients | ADAPT ADP 0/2 TIMI | 64/279 (22.9) | RD 3.2 (−4.3,10.7) | NR

Notes.

a Discharge <6h and no MACE defined as death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI.

Abbreviations. ADP=accelerated diagnostic protocol; aOR=adjusted odds ratio; CI=confidence interval; ED=emergency department; EDACS=Emergency Department Assessment of Chest Pain Score; GRACE=Global Registry of Acute Coronary Events; h=hour; HEART=History, Electrocardiogram, Age, Risk factors, Troponin); n/N%=(number of events/sample size)%; NR=not reported; OR=odds ratio; PMID=PubMed identifier; RD=risk difference; STAT=single troponin accelerated triage; TIMI=Thrombolysis in Myocardial Infarction.

Appendix Table K-3 ED Length of Stay (Continuous): Rule Out, Low Risk Not Described as Rule Out, Discharge or Grey Zone, and Rule In or High-Risk

Study, Year, PMID | ADP | N | Median (IQR) Length of Stay
Rule Out
Chew 2019 31478763 | ADP 0/1 | 1187 | 4.6 (3.5, 7.5)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 1420 | 2.5 (2.2, 3.6)
Low Risk Not Described as Rule Out
Ljung 2019 30661856 | ADP 0/1 HEART | 308 | 4.05 (3.3,5.4)
Costable 2014 | ADP 0/3 | 264 | Mean (SD) 2.9 (2)
Sandeman 2021 34824100 | ADP 0/3/6 | 945 | 3.65 (2.8, 5.5)
Sandeman 2021 34824100 | ADP 0/6/12 GRACE | 2188 | 3.9 (3, 8.1)
Discharge
Lambrakis 2021 33998255 Chew 2019 31478763 | ADP 0/1 | 737 | 3.8 (3.1,4.7)
Ljung 2019 30661856 | ADP 0/1 HEART | 419 | 3.8 (3.1,4.9)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 1619 | 2.5 (2.2,3.4)
Than 2021 33753972 | COVID-ADP 0/2 EDACS | NR | 3.1 (2.4, 4.1)
Than 2021 33753972 | ADP 0/2/6 EDACS | NR | 3.7 (2.7, 4.6)
Observe / Grey Zone
Chew 2019 31478763 | ADP 0/1 | 308 | 12.0 (5.1,34.4)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 581 | 2.6 (2.4, 4.6)
Rule In
Chew 2019 31478763 | ADP 0/1 | 270 | 51 (27.6, 77.6)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 295 | 2.5 (2.3, 4.4)
High Risk Not Described as Rule In
Ljung 2019 30661856 | ADP 0/1 HEART (based on admitted) | 202 | 46.7 (24.4,73.6)
Ljung 2019 30661856 | ADP 0/1 HEART (based on HEART score ≥4) | 139 | 4.53 (3.4,24.7)
Ljung 2019 30661856 | ADP 0/1 HEART (based on hs-TnT>14 ng/L hs-cTnI ≥35 ng/L (♂) hs-cTnI ≥16 ng/L (♀)) | 130 | 45.2 (5.1,74.1)
Twerenbold 2019 31345421 | ADP ESC 0/1 (based on admitted) | 677 | 3 (2.3,5.3)
Sandeman 2021 34824100 | ADP 0/3/6 (based on hs-TnT >14 ng/L) | 1384 | 42.8 (11.3,103.1)
Sandeman 2021 34824100 | ADP 0/6/12 GRACE (based on hs-TnT >14 ng/L) | 2569 | 37.6 (11.2,100.9)

Abbreviations. ADP=accelerated diagnostic protocol; ED=emergency department; EDACS=Emergency Department Assessment of Chest Pain Score; ESC=European Society of Cardiology; GRACE=Global Registry of Acute Coronary Events; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; hscTnI/T=highly-sensitive cardiac troponin I/T; IQR=interquartile range; N=sample size; NR=not reported; PMID=PubMed identifier; SD=standard deviation.

Appendix Table K-4 ED Length of Stay (Categorical): Rule Out, Low Risk Not Described as Rule Out, Discharge or Grey Zone, and Rule In or High Risk

Study, Year, PMID | ADP | ADPOutcome Definition | ADPn/N (%)
Low Risk Not Described as Rule Out
Than 2016 26947800 | ADP 0/2 EDACS | Discharge <6h and no MACE within 30 days^a^ | 73/279 (26.2)
Than 2016 26947800 | ADAPT ADP 0/2 TIMI | Discharge <6h and no MACE within 30 days^a^ | 64/279 (22.9)
Sandeman 202134824100 | ADP 0/3/6 | Discharge ≤4h (based on hs-TnT <5 ng/L) | 604/945 (63.9)
Sandeman 202134824100 | ADP 0/6/12 GRACE | Discharge ≤4h (based on hs-TnT <5 ng/L) | 1149/2188 (52.5)
High Risk Not Described as Rule In
Sandeman 2021 34824100 | ADP 0/3/6 | Discharge ≤4h (based on hs-TnT >14 ng/L) | 165/1348 (12.2)
Sandeman 2021 34824100 | ADP 0/6/12 GRACE | Discharge ≤4h (based on hs-TnT >14 ng/L) | 340/2569 (13.2)

Notes.

a Discharge <6h and no MACE defined as death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI.

Abbreviations. ADP=accelerated diagnostic protocol; ED=emergency department; EDACS=Emergency Department Assessment of Chest Pain Score; GRACE=Global Registry of Acute Coronary Events; h=hour; hs-cTnT=high-sensitivity cardiac troponin T; MACE=major adverse cardiac events; n/N %=(number of events/sample size) %; PMID=PubMed identifier; TIMI=Thrombolysis in Myocardial Infarction.