# APPENDIX J MACE OUTCOMES

Appendix Table J-1 MACE Comparative Studies

Study PMID, Study | Follow-up Time (days) | Outcome Definition | Subgroup | Arm | n/N (%) | OR (95% CI)^*^ | Reported P value
Overall Comparison: ADP vs hs-cTn without ADP
Hyams 2018; 29478861 | 6 wk | Mortality, nonfatal MI, revascularization | | ADP 0/3 HEART | 25/449 (5.6) | 0.73 (0.42,1.24); RD −1.8 (−5.1,1.5)^*^ | NR
Hyams 2018; 29478861 | 6 wk | Mortality, nonfatal MI, revascularization | | Hs-cTn | 31/417 (7.4) | 0.73 (0.42,1.24); RD −1.8 (−5.1,1.5)^*^ | NR
Overall Comparison: ADP vs ADP
Anand 2021; 33752439 | 30 | MI (type 1/4b/4c) or cardiac death | | High-STEACS ADP 0/3 | 56/16792 (0.3) | 0.86 (0.59, 1.24); RD −0.1 (−0.2, 0.03)^*^ | 0.068
Anand 2021; 33752439 | 30 | MI (type 1/4b/4c) or cardiac death | | ADP 0/6/12 | 57/14700 (0.4) | 0.86 (0.59, 1.24); RD −0.1 (−0.2, 0.03)^*^ | 0.068
Anand 2021; 33752439 | 30 | MI (type 1/2/4b/4c) or cardiac death | | High-STEACS ADP 0/3 | 68/16792 (0.4) | 0.84 (0.60, 1.17)^*^; RD −0.1 (−0.2, 0.05)^*^ | NR
Anand 2021; 33752439 | 30 | MI (type 1/2/4b/4c) or cardiac death | | ADP 0/6/12 | 71/14700 (0.5) | 0.84 (0.60, 1.17)^*^; RD −0.1 (−0.2, 0.05)^*^ | NR
Than 2016; 26947800 | 30 | Death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI | | ADP 0/2 EDACS | 2/279 (0.7) (all events occurred in non-low risk patients) | RD 0.3 ( −0.9, 1.5)^*^ | NR
Than 2016; 26947800 | 30 | Death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI | | ADPAT ADP 0/2 TIMI | 1/279 (0.4) (all events occurred in non-low risk patients) | RD 0.3 ( −0.9, 1.5)^*^ | NR
Subgroup Comparison
Hyams 2018; 29478861 | 6 wk | Mortality, nonfatal MI, revascularization | HEART score ≤3 | ADP 0/3 HEART | 0/denominator NR (0) | | NR
Hyams 2018; 29478861 | 6 wk | Mortality, nonfatal MI, revascularization | HEART score ≤3 | Hs-cTn | 0/denominator NR (0) | | NR
Than 2016; 26947800 | 30 | Death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI | Low risk patients | ADP 0/2 EDACS | 0/116 (0) | | NR
Than 2016; 26947800 | 30 | Death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI | Low risk patients | ADAPT ADP 0/2 TIMI | 0/85 (0) | | NR
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | CP ≤3h and rule-out group | ADP ESC 0/1 | 0/655 (0.0) | RD −0.3 (−0.6, 0.04)^*^ | 0.171
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | CP >3h and rule-out group | ADP ESC 0/1 | 3/1063 (0.3) | RD −0.3 (−0.6, 0.04)^*^ | 0.171
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | Female and rule-out group | ADP ESC 0/1 | 2/663 (0.3) | RD 0.2 (−0.3, 0.7)^*^ | 0.372
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | Male and rule-out group | ADP ESC 0/1 | 1/1049 (0.1) | RD 0.2 (−0.3, 0.7)^*^ | 0.372
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | Age >65 years and rule-out group | ADP ESC 0/1 | 2/500 (0.3) | RD 0.1 (−0.4, 0.6)^*^ | 0.688
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | Age ≤65 years and rule-out group | ADP ESC 0/1 | 3/1219 (0.2) | RD 0.1 (−0.4, 0.6)^*^ | 0.688
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | CP ≤3h and discharge | ADP ESC 0/1 | 0/614 (0) | RD −0.1 (−0.3, 0.1)^*^ | 0.435
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | CP >3h and discharge | ADP ESC 0/1 | 1/1004 (0.1) | RD −0.1 (−0.3, 0.1)^*^ | 0.435
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | Female and discharge | ADP ESC 0/1 | 1/614 (0.2) | RD 0.2 (− 0.2, 0.5)^*^ | 0.202
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | Male and discharge | ADP ESC 0/1 | 0/1004 (0) | RD 0.2 (− 0.2, 0.5)^*^ | 0.202
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | Age >65 years and discharge | ADP ESC 0/1 | 0/509 (0) | RD −0.1 (− 0.3, 0.1)^*^ | 0.501
Twerenbold 2019; 31345421 | 30 | Cardiovascular death and MI | Age ≥65 years and discharge | ADP ESC 0/1 | 1/1120 (0.1) | RD −0.1 (− 0.3, 0.1)^*^ | 0.501

Notes.

* Calculated by research team.

Abbreviations. ADP=accelerated diagnostic protocol; CI=confidence interval; CP=chest pain; EDACS=Emergency Department Assessment of Chest Pain Score; ESC=European Society of Cardiology; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; High-STEACS=High-Sensitivity Troponin in the Evaluation of Patients With Suspected Acute Coronary Syndrome; hs-cTn=high-sensitivity cardiac troponin; MACE=major adverse cardiac events; MI= myocardial infarction, n/N%=(number of events/sample size)%; NR=not reported; OR=odds ratio; PMID=PubMed identifier; RD=risk difference; TIMI=Thrombolysis in Myocardial Infarction; wk=week.

Appendix Table J-2 MACE: Rule Out, Low Risk Not Described as Rule Out, Discharge or Grey Zone, and Rule In or High Risk

Study, Year, PMID | ADP | Follow-up Time (days) | Outcome Definition | n/N (%)
Rule Out
Chew 2019 31478763 | ADP 0/1 | 30 | Death and MI | 6/1187 (0.5)
Chew 2019 31478763 | ADP 0/1 | 30 | Death, MI, and unstable angina | 10/1187 (0.8)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Cardiovascular death and MI | 3/1420 (0.2)
Low Risk Not Described as Rule Out
Than 2016 26947800 | ADP 0/2 EDACS | 30 | Death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI | 0/116 (0)
Than 2016 26947800 | ADAPT ADP 0/2 TIMI | 30 | Death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI | 0/85 (0)
Hyams 2018 29478861 | ADP 0/3 HEART | 6 wk | Death, nonfatal MI, revascularization (based on HEART score ≤3) | 0/denominator NR (0)
Discharge
Suh 2022 35571147 | ADP 0/1 mHEART | 30 | MI, revascularization, ventricular arrhythmia, high degree atrioventricular block requiring intervention, cardiogenic shock requiring mechanical support, cardiac arrest with return of spontaneous circulation, and death | 4/381 (1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Cardiovascular death and MI | 1/1619 (0.06)
Observe / Grey Zone
Chew 2019 31478763 | ADP 0/1 | 30 | Death and MI | 7/308 (2.3)
Chew 2019 31478763 | ADP 0/1 | 30 | Death, MI, and unstable angina | 9 /308 (2.9)
Chew 2019 31478763 | ADP 0/1 | 30 | MI with or without revascularization | 3/308 (1)
Twerenbold 2019 31345421 | ADP ESC 0/1 | 30 | Cardiovascular death and MI | 31/581 (5.3)
Rule In
Chew 2019 31478763 | ADP 0/1 | 30 | Death and MI | 5/136 (3.7)
Twerenbold 2019 1345421 | ADP ESC 0/1 | 30 | Cardiovascular death and MI | 197/295 (66.8)
High Risk Not Described as Rule In
Suh 2022 35571147 | ADP 0/1 mHEART | 30 | MI, revascularization, ventricular arrhythmia, high degree atrioventricular block requiring intervention, cardiogenic shock requiring mechanical support, cardiac arrest with return of spontaneous circulation, and death | 35/395 (8.9)
Twerenbold 2019 1345421 | ADP ESC 0/1 | 30 | Cardiovascular death and MI (Based on admitted) | 230/677 (34)
Than 2016 26947800 | ADP 0/2 EDACS | 30 | Death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI | 2/279 (0.7)
Than 2016 26947800 | ADAPT ADP 0/2 TIMI | 30 | Death, cardiac arrest, emergency revascularization, cardiogenic shock, ventricular arrhythmia needing intervention, high-degree atrioventricular block needing intervention, and MI | 1 /279 (0.4)

Abbreviations. ADP=accelerated diagnostic protocol; EDACS=Emergency Department Assessment of Chest Pain Score; ESC=European Society of Cardiology; HEART=History, Electrocardiogram, Age, Risk factors, Troponin; MACE=major adverse cardiac events; mHEART=modified HEART; MI=myocardial infarction; n/N%=(number of events/sample size)%; NR=not reported; PMID=PubMed identifier; TIMI=Thrombolysis in Myocardial Infarction; wk=week.