# APPENDIX I BASELINES

Author, Year, PMID | N Enrolled | Race/Ethnicity, % | Age, Mean (SD) or % | Male, % | History of CVD, % | CVD Risk Factors, %
Anand 2021; 33752439 | 31492 | NR | 59 (17) | 55% | Prior MI; 8%; Prior revascularization; 10.4%; History CVD; NR; Stroke/TIA; NR; PAD; NR; MI 30 days: 0.3% | Hypertension; NR; Diabetes; 6%; Smoking; NR; BMI; NR; FHx; NR; Hyperlipidemia; NR
Barnes 2021; 33436490 | 2255 | NR | 54 (17) | 53% | Prior MI; 10%; Prior revascularization; 10%; History CVD; NR; Stroke/TIA; 4%; PAD; 2%; MI 30 days: 0.0% | Hypertension; 35%; Diabetes; 14%; Smoker, current; 19%; BMI; 13%; FHx CAD; 9%; Hyperlipidemia; 29%
Chew 2019; 31478763; Lambrakis 2021; 33998255 | 1646 | NR | Median (IQR) 58.7 (48.6,69.4) | 53.2% | Prior MI; 10.3%; Prior revascularization; 10.4%; Stroke/TIA; 3.2%; History CVD; 27.8%; PAD; NR; MI 30 days: 1% | Hypertension; 19.7%; Diabetes; 15.8%; Smoking; 34.6%; BMI; NR; FHx; 61.2%; Hyperlipidemia; 43.3%
Conde 2013; 23810070 | 300 | NR | 65 | 51% | Prior MI; 1%; Prior revascularization; 23%; History CVD; 3%; Stroke/TIA; NR; PAD; NR; MI 30 days: NR | Hypertension; 58%; Diabetes; 15%; Smoking; 50%; BMI; NR; FHx; NR; Hyperlipidemia; 64%
Costable 2014 | 528 | NR | 58 (13) | 58% | Prior MI; 8%; Prior revascularization; 16.8%; History CVD; 3.6%; Stroke/TIA; NR; PAD; NR; MI 30 days: 6.3% | Hypertension; 38%; Diabetes; 12%; Smoking; 39%; BMI; NR; FHx; NR; Hyperlipidemia; 45%
Crowder 2015; 26387473 | 5754 | NR | 61.4 | 49.9% | Prior MI; NR; Prior revascularization; NR; History CVD; NR; Stroke/TIA; NR; PAD; NR; MI 30 days: NR | Hypertension; NR; Diabetes; NR; Smoking; NR; BMI; NR; FHx; NR; Hyperlipidemia; NR
Ford 2021; 33662739 | 1616 | NR | Median (IQR) 55 (41, 66) | 51% | Prior MI; NR; Prior revascularization; NR; History CVD; NR; Stroke/TIA; NR; PAD; NR; MI 30 days: NR | Hypertension; NR; Diabetes; NR; Smoking; NR; BMI; NR; FHx; NR; Hyperlipidemia; NR
Hyams 2018; 29478861 | 866 | NR | 54.7 | 50.1% | Prior MI; 11.8%; Prior revascularization; 15.4%; History CVD; NR; Stroke/TIA; 2.2%; PAD; NR; MI 6 weeks: 4.8% | Hypertension; 50.5%; Diabetes;22.5%; Smoking; 22.6%; BMI; 46.4%; FHx; 31.3%; Hyperlipidemia; 32%
Ljung 2019; 30661856 | 621 | NR | 63 (53, 71) | 54% | Prior MI; 19%; Prior revascularization; 19%; History CVD; 21%; Stroke/TIA; 8%; PAD; 2%; MI 30 days: 0.5% | Hypertension; 43%; Diabetes; 12%; Smoking; 52%; BMI (≥ 30 kg/m2); 19%; FHx; 29%; Hyperlipidemia; NR
Sandeman 2021; 34824100 | 10315 | NR | 63.6 (16.4) | 54% | Prior MI; 6.4%; Prior revascularization; NR; History CVD; 4.2%; Stroke/TIA; NR; PAD; NR; MI 30 days: NR | Hypertension; NR; Diabetes; 17.7%; Smoking; NR; BMI; NR; FHx; NR; Hyperlipidemia; NR
Stoyanov 2020; 31298551 | 2525 | NR | 62 (18) | 58% | Prior MI; 17%; Prior revascularization; 6.6%; History CVD; NR; Stroke/TIA; NR; PAD; NR; MI 30 days: NR | Hypertension; 65.4%; Diabetes; 21.2%; Smoking; 21.8%; BMI; NR; FHx; 26.3%; Hyperlipidemia; 44.9%
Suh 2022; 35571147 | 821 | White (Non-Hispanic) 13.4%; Black 25.5%; Hispanic/Latino 60.4%; Asian (Any) 2.6%; Other1 53.7%; Other2 1.1% | 60.4 (15.9) | 45.6% | Prior MI; NR; Prior revascularization; NR; History CVD; 25.9%; Stroke/TIA; NR; PAD; 32.9%; MI 30 days: 2.6% | Hypertension; 68.6%; Diabetes; 36.2%; Smoking; 11.2%; BMI; 41.2%; FHx; 15.4%; Hyperlipidemia; 44.7%
Sweeney 2020; 32104767 | 15882 | NR | 49.9 (14.2) | NR | Prior MI; NR; Prior revascularization; NR; History CVD; NR; Stroke/TIA; NR; PAD; NR; MI 30 days: NR | Hypertension; NR; Diabetes; NR; Smoking; NR; BMI; NR; FHx; NR; Hyperlipidemia; NR
Than 2021; 33753972 | 2416 | White 72.2%; Other1 Pacific 0.9%; Other2 New Zealand Maori 3.5%; Other3 11.1% | 63 (13) | 61.8% | Prior MI; NR; Prior revascularization; NR; History CVD; 35.3%; Stroke/TIA; NR; PAD; NR; MI 30 days: NR | Hypertension; 55%; Diabetes; 15%; Smoking; 15.2%; BMI; NR; FHx; 54.3%; Hyperlipidemia; 55.6%
Than 2016; 26947800 | 558 | Asian (Any) 2.5%; Other1 Maori; 3.8%; Other2 Pacific Islander; 1.6%; Other3 (New Zealand European + Other European); 84.0% | 58.7 (11.9) | 60.9% | Prior MI; 23.3%; Prior revascularization; 27.4%; History CVD; NR; Stroke/TIA; 5.9%; PAD; 5.7%; MI 30 days: NR | Hypertension; 52%; Diabetes; 14%; Smoking; 15.1%; BMI; NR; FHx; 35.7%; Hyperlipidemia; 50.9%
Twerenbold 2019; 31345421 | 2296 | NR | Median 60 | 64% | Prior MI; 17%; Prior revascularization; 30%; History CVD; 29%; Stroke/TIA; 2%; PAD; 3%; MI 30 days: 9.9% | Hypertension; 51%; Diabetes; 13%; Smoking; 19%; BMI; NR; FHx; 16%; Hyperlipidemia; 41%
Vigen 2020; 32320036 | 14552 | White 55%; Black 41.9%; Hispanic/Latino 38.2%; Non-Hispanic 61.8%; Other1 3% | 54.2 (14.6) | 53% | Prior MI; NR; Prior revascularization; NR; History CVD; NR; Stroke/TIA; NR; PAD; NR; MI 30 days: NR | Hypertension; NR; Diabetes; NR; Smoking; NR; BMI; NR; FHx; NR; Hyperlipidemia; NR

Abbreviations. BMI=body mass index; CVD=cardiovascular disease; FHx=family history; IQR=interquartile range; MI=myocadiac infarction; N=sample size; NR=not reported; PAD=peripheral arterial disease; PMID=PubMed identifier; SD=standard deviation; TIA=transient ischemic attack.