# APPENDIX H SUMMARY OF HS-CTN

Author, Year, PMID | Arm | Test Manufacturer & Name | Troponin Var (I or T) | Limit of Detection | 99^th^ Percentile
Anand 2021; 33752439 | Early rule-out pathway (High-STEACS): High-STEACS ADP 0/3 | Abbott Architect STAT | hs-cTnI | NR | Women; 16 ng/L; Men; 34 ng/L
Anand 2021; 33752439 | Standard rule-out pathway: ADP 0/6/12 | | | Same
Barnes 2021; 33436490 | Single Troponin Accelerated Triage (STAT)-Chest Pain: STAT ADP 0/2/6 HEART | Abbott Architect | hs-cTnI | 1.2 ng/L (reported as <2 ng/L) | Women upper limit of normal; <16 ng/L;; Men upper limit of normal; <26 ng/L
Barnes 2021; 33436490 | Standard pathway: ADP 0/(2 or 3)/6 TIMI | | | Same
Chew 2019; 31478763; Lambrakis 2021; 33998255 | ADP 0/1 | 5^th^ generation Roche Elecys | hs-cTnT | 5 ng/L | 14 ng/L
Chew 2019; 31478763; Lambrakis 2021; 33998255 | ADP 0/3 [arm excluded from analysis due to hs-cTnT being blinded] | | | Same
Conde 2013; 23810070 | Post-implementation: ADP 0/3 | NR | hs-cTnT | NR | NR
Conde 2013; 23810070 | Pre-implementation [arm excluded from analysis due to standard troponin] | 4^th^ generation troponin | cTnT | NR | NR
Costable 2014 | hs-cTn Chest Pain Protocol: ADP 0/3 | NR | hs-cTnT | NR | NR
Crowder 2015; 26387473 | Post-implementation: ADP 0/2-4 | Roche | hs-cTnT | NR | 14 ng/L
Crowder 2015; 26387473 | Pre-implementation [arm excluded from analysis due to standard troponin] | 4^th^ generation Roche | cTnT | NR | NR
Crowder 2015; 26387473 | Historical control [arm excluded from analysis due to standard troponin] | NA | NA | NA | NA
Ford 2021; 33662739 | Post-implementation: ADP 0/1/3 HEART | 5^th^ generation Roche | hs-cTnT | NR | 19 ng/L
Ford 2021; 33662739 | Pre-implementation [arm excluded from analysis due to standard troponin] | TnI-Ultra Siemens | cTnI | NR | 40 ng/L
Hyams 2018; 29478861 | HEART Pathway Post-implementation: ADP 0/3 HEART | Roche | hs-TnT | NR | NR
Hyams 2018; 29478861 | Pre-implementation hs-cTn alone | | | Same
Ljung 2019; 30661856 | Post-implementation: ADP 0/1 HEART | Roche and Abbott | hs-cTnT, hscTnI | Roche; 5 ng/L; Abbott; 1.2-1.9 ng/L | Roche; 14 ng/L; Abbott; Women; 15.6 ng/L; Abbott; Men; 34.2 ng/L
Ljung 2019; 30661856 | Pre-implementation [arm excluded from analysis due to standard troponin] | Roche, Abbott, Siemens-Stratus | hs-cTnT, hscTnI, cTn | Roche; 5 ng/L; Abbott; 1.2-1.9 ng/L; Siemens-Stratus; 30 ng/L | Roche; 14 ng/L; Abbott; Women; 15.6 ng/L; Abbott; Men; 34.2 ng/L; Stratus; 70 ng/L
Sandeman 2021; 34824100 | Post-implementation: ADP 0/3/6 | Roche Cobas e602 platform | hs-TnT | 3 ng/L | 14 ng/L
Sandeman 2021; 34824100 | Pre-implementation: ADP 0/6/12 GRACE | | | Same
Stoyanov 2020; 31298551 | ESC 0/1 Post-implementation: ADP ESC 0/1 | Roche Cobas e411 | hs-TnT | 5 ng/L | NR
Stoyanov 2020; 31298551 | ESC 0/3 Pre-implementation: ADP ESC 0//3 | | | Same
Suh 2022; 35571147 | Post-implementation: ADP 0/1 mHEART | 5^th^ generation Roche Elecsys | hs-TnT | 6 ng/L | Women; 14 ng/L; Men; 22 ng/L (the US (FDA)-approved sexspecific 99th percentile values)
Suh 2022; 35571147 | Pre-implementation [arm excluded from analysis due to standard troponin] | Abbott i-STAT and 4^th^ generation Roche | POC cTnI or cTnT | NR | NR
Sweeney 2020; 32104767 | Post-implementation chest pain algorithm: ADP 0/3 TIMI & GRACE | Abbott Architect STAT cTnI | hs-cTnI | NR | NR
Sweeney 2020; 32104767 | Pre-implementation [arm excluded from analysis due to standard troponin] | NR | cTn | NR | NR
Than 2021; 33753972 | COVID-ADP: COVID-ADP 0/2 EDACS | Abbott Architect i2000 | hs-TnI | 1.9 ng/L | Women; 16 ng/L; Men; 34 ng/L; Overall; 26 ng/L
Than 2021; 33753972 | EDACS: ADP 0/2/6 EDACS | | | Same
| EDACS-ADP: ADP 0/2 EDACS | Abbot Architect | hs-cTnI | NR | Women; 16 ng/L; Men; 34 ng/L
Than 2016; 26947800 | ADAPT-ADP: ADP 0/2 TIMI | | | Same
Twerenbold 2019; 31345421 | ADP ESC 0/1 | Roche Elecsys 2010 | hs-cTnT | 5 ng/L | 14 ng/L
Vigen 2020; 32320036 | Post-implementation: ADP 0/1/3 mHEART | NR | hs-cTnT | NR | NR
Vigen 2020; 32320036 | Pre-implementation [arm excluded from analysis due to standard troponin] | 4^th^ generation Roche | cTnT | 0.01 ng/L | NR