# APPENDIX G SUMMARY OF RISK SCORES

Risk Score [Key Reference] | Items
HEART (History, Electrocardiogram, Age, Risk factors, Troponin), [ Hyams 2018 29478861] | - History; - Electrocardiogram; - Age; - Risk factors; - Troponin; Each item is scored 0, 1, or 2.; High risk = 7-10; Medium risk = 4-6; Low risk = 0-3
TIMI (Thrombolysis in Myocardial Infarction), [Than 2016 26947800] | - Age ≥65 y; - Coronary artery disease (CAD) risk factor ≥3 (family history of premature coronary artery disease (CAD), dyslipidemia, diabetes, hypertension, current smoker); - Known coronary artery disease (CAD) (stenosis ≥50%); - Acetylsalicylic acid/aspirin use in the last 7 days; - Recent severe angina (eg, ≥2 events in last 24 h); Each item is score 0 or 1.; Not low risk ≥1; Low risk = 0
EDACS (the Emergency Department Assessment of Chest Pain Score), [Than 2016 26947800] | - Age (classified by predefined age ranges: ≤30, 30-39, 40-49, 50-59, 60-69, 70-79, 80-89, ≥90); scored 2-20 [even numbers only];; - If age 18-50 ys then coronary artery disease event (CAD) or coronary artery disease risk factors; scored 3, 4 or 5; - Symptoms (diaphoresis, pain radiates to arm or shoulder, pain occurs or worsened with inspiration, pain reproduced by palpation); scored 3, 5, −4, or −6.; - Male; scored 6; Not low risk ≥16; Low risk <16
GRACE (Global Registry of Acute Coronary Events), [Fox 2006 17032691] | - Killip class (4 classes: I, II, III, IV); scored 0, 20, 39, or 59; - SBP mm Hg; scored 58, 53, 43, 34, 24, 10, 0; - Heart rate beats/min; scored 0, 3, 9, 15, 24, 38, or 46; - Age; scored 0, 8, 25, 41, 58, 75, 91, or 100; - Creatinine level mg/dL; scored 1, 4, 7, 10, 13, 21, or 28; - Cardiac arrest at admission; scored 39; - ST-segment deviation; scored 28; - Elevated cardiac enzyme levels; scored 14; High risk >140; intermediate risk 109-140; low risk <109.