# APPENDIX F DESIGN DETAILS

Author, Year, PMID, Cohort Name, Protocol Number, Country, Funder | Study Design | Study Dates | Study Location Details | Inclusion Criteria | Exclusion Criteria
Anand 2021; 33752439; HiSTORIC; NCT03005158; Scotland; Non-industry | RCT | 2014-16 | Multiple EDs | Sites able to implement rule-out pathway and submitted data to national registry.; ED or acute medical patients with suspected ACS and a hs-cTnI < sexspecific 99th percentile url | STEMI, out-of-hospital cardiac arrest, admitted previously during the trial
Barnes 2021; 33436490; STAT-Chest Pain; ACTRN12618000797279; Australia; Non-industry | Pre-Post comparison | 2018-19 | Single ED | ED patients with potential ACS, ≥18 yo | STEMI, myocardial revascularization within the preceding 6 mo, admission to hospital for other reasons, a clear non-cardiac cause of the symptoms, or prior enrolment in the study
Chew 2019; 31478763; Lambrakis 2021; 33998255; RAPID-TnT; ACTRN12615001379505; Australia; Industry and nonindustry | RCT [analyzed as single group] | 2015-2019 | Multiple EDs | Chest pain or suspected ACS as the principal cause for investigation and a baseline ECG interpreted as not definitive for coronary ischemia, ≥18 yo, intention to undertake troponin testing, willing to give written consent | STEMI, comorbidity that precludes completing the clinical history questionnaire, non-cardiac chest pain, transfer from another hospital, presented for suspected ACS within 30 days of last presentation, required permanent dialysis
Conde 2013; 23810070; NA; Argentina; NR | Pre-post comparison [analyzed as single group] | 2011-2012 | Single ED | ED patients with probable ACS, >18 yo | Unstable angina or MI without STEMI, angina equivalent.
Costable 2014; NA; Argentina; NR | Single group | 2013 | Single ED | ED patients with suspected ACS and who were evaluated according to the chest pain unit protocol, > 18 yo. | STEMI, non-cardiac chest pain, admission indicated by another physician, transfer of patient due to lack of beds, patient refusal to stay for observation, impossibility of follow-up
Crowder 2015; 26387473; NR; NR; Canada; NR | Pre-post comparison [analyzed as single group] | 2011-2012 | Multiple EDs | Patients with chest pain or potential ACS and who had a troponin assay performed during the study periods. | STEMI
Ford 2021; 33662739; NR; NR; US; None | Pre-post comparison [analyzed as single group] | 2017-2018 | Single ED | ED patients with a chief complaint of chest pain, ≥ 18 yo. | NR
Hyams 2018; 29478861; NR; NR; US; NR | Pre-post comparison | 2014-2016 | Single ED | ED patients with a chief complaint of “chest pain,” “chest tightness,” or “chest pressure, >18 yo | STEMI, patients with nonpainful ACS presentations such as shortness of breath unless accompanied by symptoms related to chest discomfort. Patients without a documented followup at least 6 wks after the ED visit, without adequate information (such as ECG or troponin) documented in their electronic medical record to calculate a HEART score
Ljung 2019; 30661856; FASTEST; NR; Sweden; Industry and non-industry | Pre-post comparison [analyzed as single group] | 2013-2016 | Multiple EDs | Chest pain suggestive of ACS with a duration ≥10 minutes and an onset of last episode ≤12 hours. ≥18 yo, willing to have blood samples taken according to the study protocol, a signed written informed consent in Swedish | STEMI, new left bundle branch block on ECG at presentation or previous participation in the study
Sandeman 2021; 34824100; NR; NR; Scotland; Industry and non-industry | Pre-post comparison | 2014-2017 | Single ED | Patients with suspected ACS presenting to a secondary care hospital, all patients who had an hs-cTnT measurement on presentation to hospital since the introduction of the assay | STEMI, patient were not residents in Scotland, had a previous presentation during the study period
Stoyanov 2020; 31298551; RAPID-CPU; NCT03111862; Germany; Industry | Pre-post comparison | 2016-2017 | Single ED | Initial presentation of clinically suspected ACS (based on a broad spectrum of symptoms including atypical symptoms and dyspnea) | STEMI, patients on chronic haemodialysis, repeated presentations beyond the index admission (‘frequent flyer’); patients referred from other hospitals for early or primary PCI without receiving a standard diagnostic work-up; diagnostic set of hsTnT samples not available (eg, missing initial or consecutive blood sample). Patients with atrioventricular nodal re-entrant tachycardia. Inappropriate command of the English/German language or permanent residence in a foreign country.
Suh 2022; 35571147; NR; NCT03590535; US; Industry | Pre-post comparison [analyzed as single group] | 2018-2020 | Single ED | Patients with ACS and received troponin testing as part of their evaluation, ≥19 yo | STEMI, pre-heart transplant, without capacity to consent, left ventricular assist device, who were presenting after a cardiac arrest, lacked fluency in either English or Spanish, or were otherwise unable to participate in telephone follow-up
Sweeney 2020; 32104767; NR; NR; UK; NR | Pre-post comparison [analyzed as single group] | 2015-2018 | Multiple EDs | ED patients with a triage diagnosis of chest pain | NR
Than 2021; 33753972; NR; NR; New Zealand; NR | QIP and Pre-post comparison | 2020-2020 | Single ED | Patients presenting with symptoms of chest pain and symptoms of MI, ≥18 yo | STEMI, <18 yo, a clear cause of symptoms other than MI; transfer from another hospital; pregnancy; unable to be followed-up; or staff considered recruitment inappropriate (eg, receiving palliative care), unable or unwilling to consent
Than 2016; 26947800; NR; ACTRN12613000745741; New Zealand; Non-industry | RCT | 2013-2014 | Single ED | Possible cardiac symptoms suggestive of MI and for which serial cTn analysis were performed, ≥18 yo | STEMI, noncoronary pathology of symptoms; transfer from another hospital; pregnancy; unable to be followed-up; or staff considered recruitment inappropriate (eg, receiving palliative care); need for admission because of other medical conditions regardless of a negative cTn result; previously enrolled in this study; unable to consent.
Twerenbold 2019; 31345421; NR; NR; Switzerland, Argentina; Industry and nonindustry | Single group | 2015-2017 | Multiple EDs | Adult ED patients with symptoms suggestive of MI | STEMI
Vigen 2020; 32320036; NR; NR; US; Non-industry | Pre-post comparison, [analyzed as single group] | 2017-2018 | Single ED | Patients had both ECG and troponin testing obtained within 3 hr of arrival and prior to the disposition decision, did not undergo hemodialysis in the ED. | Patients undergoing emergent hemodialysis, testing was done on an outpatient basis or in day surgery, missing values for time from cTn draw to disposition time, disposition decision time was recorded prior to a cTn draw time, redundant encounters.