# APPENDIX E PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 3 | Yes | Thank you.
4 | 5 | Yes | Thank you.
5 | 6 | Yes | Thank you.
6 | 11 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
7 | 1 | No | Thank you.
8 | 2 | No | Thank you.
9 | 3 | No | Thank you.
10 | 5 | No | Thank you.
11 | 6 | No | Thank you.
12 | 11 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
13 | 1 | Yes - references to consider are included in comments | Thank you. Please see our response to Comment #19.
14 | 2 | No | Thank you.
15 | 3 | No | Thank you.
16 | 5 | No | Thank you.
17 | 6 | No | Thank you.
18 | 11 | No | Thank you.
Additional suggestions or comments can be provided below.
19 | 1 | This report from the ESP seeks to summarize current available knowledge on the topic of using high-sensitivity troponin (HSTN) assays in combination with accelerated diagnostic protocols. A variety of important clinical comparisons are made with appropriate notation on the confidence of each comparison. The implications of adopting the findings to clinical practices could result in fewer hospital admissions without any appreciable increase in adverse cardiovascular events.; The executive summary provides concise, understandable statements of key findings that should be easy for clinicians in the field to understand and adopt.; The Key Questions are well reasoned and applicable to clinical care in the ED.; The methods are thoroughly described and readily reproducible. Inclusion/exclusion criteria are appropriate for the intended analysis. ROBINS-I, PROSPERO, and appropriate online software options were applied. Studies are organized in a thoughtful manner based on the clinical importance of the reported outcomes.; The tables supplement the text by providing greater detail in a format that is digestible to the reader, the tables also help demonstrate the heterogeneity of the literature.; The limitations section adequately reflects the fact that most of the work on hstn, ADPs, and implementation has been done internationally and very little in the VA. As noted, the international work, often done in countries with integrated health care systems, may actually have good overlap with the VA due to similar infrastructures.; The authors identify one of the more important gaps in the literature as being the documentation of best practices for implementation. The authors express optimism in what the widespread adoption of HSTN/ADP could mean for the VA, but acknowledge that local practices groups are often difficult to convince into a change in practice. | Thank you.
| | If the authors wish to expand on the discussion about implementation, some references to consider are (PMIDs): 36328155, 35604774, 34224384 And the following description of implementation in a VAMC: https://vpjournal.net/article/view/3867 | Thank you. The Discussion now comments on the potential implementation challenges associated with hscTn in the US and VA. Per the suggested references, we highlight the experience of one large VA’s transition to hs-cTn.
20 | 2 | Thorough | Thank you.
21 | 3 | I appreciate the authors’ thoroughness and skill in navigating a challenging set of evidence on an important topic that is highly relevant to an emergency department clinical scenario that is common, costly, and will benefit from this synthesis. I think the manuscript could be improved in a few areas, primarily around the framing of some of the discussion points. | Thank you.
| | Major; - Title: Need to include some reference to “emergency department” in the title given the focus of the literature review was restricted to that care setting. | We revised the title to reference the Emergency Department.
| | - Discussion: Generally agree with statement that given the state of available evidence regarding ADPs that individual EDs should have freedom to create their own approach (page 5, line 8; page 38, line 9). However, I think it is important to caveat that this should still be based on the available evidence. The way this is currently worded, it implies that there are no limits, when, in fact, it should be about adopting and adapting what is supported by the evidence (risk tools, troponin timing, etc) to their local requirements. I think this should be the overall message and main take-home points from the evidence review: (1) importance of standardizing practice to avoid overuse of health services and testing; but, (2) no clear and obvious best in choice from the evidence; with (3) support for a variety of approaches; therefore, (4) importance of factoring in local structural needs and preferences in adopting a tailored but still standardized approach. | We agree that EDs should implement evidence-based ADPs, and we do not want to give the impression that there are no limits. We revised the Discussion and Conclusion to note the importance of adopting evidencebased interventions and EDs may need to tailor an evidence-based ADP to fit within their local context.; We also revised the Discussion and Conclusions to highlight the helpful key messages proposed by the reviewer.
| | - Discussion: Really liked the last paragraph under “Implications for VA Policy” (page 6, lines 6-16). These are excellent points and describes many of the features of an integrated health system that could be leveraged and are ripe for adopting and standardizing into routine practice. This approach seems like a natural and obvious next step in implementing this evidence synthesis. Recognize the focus of this review was not on implementation, but still wondering if there is a way to elevate this point within the manuscript?—could it even go in the Executive Summary? | We revised the Discussion to provide additional context on potential implementation challenges (see response to Comment 19, Reviewer 1). The Discussion now highlights the experience of one large VA during their transition to hs-cTn. We also revised the Executive Summary to elevate the importance of implementation.
| | Minor; - Introduction: In general, probably better to use a more general term than “ED physicians” when referencing providers who may be drawing on this evidence for incorporation in ED care (page 2, line 18). For example, there are increasingly advance practice providers (PAs, NPs) being used in this role. Options could include “ED provider” or “ED clinicians”—I tend to lean toward the latter in my work. | Thank you. We revised the text to be more inclusive in our definition of individuals who provide care in an ED setting.
| | - Results: When introducing ADPs, I think worth referencing the table on clinical risk tools (Appendix C, page 93) that summarizes those evaluated in this evidence review (page 3, lines 12). Given ADPs are the major focus of this review, readers will quickly want to understand which chest pain risk scores (beyond just the abbreviations) were being evaluated and the references for these. | The text referenced by the reviewer is in the Executive Summary. Per ESP style, we do reference appendices in the Executive Summary.
| | - Discussion: “administers” should be “administrators” (page 5, line 6) | Thank you.
| | - Discussion: Definitely a minor point, but I don’t agree with this statement: “Studies, and by extension ADPs, should categorize patients as rule-in, rule-out, grey zone rule-out and grey zone rule-in and avoid terms that do not correspond to clinical diagnosis (e.g., low risk, discharge) which only muddy interpretation of results” (page 6, lines 33-36). Agree with need to approach with a standard language, but disagree with need to correspond these to categories of clinical diagnoses. That later approach is not consistent with how emergency providers approach these clinical scenario—their heuristic is more consistent with the process of stratifying patients into categories of risk rather than arriving at definitive diagnoses. Even if a patient is “ruled-out” for acute MI in that moment, most emergency providers would still consider that patient to be in a low risk category because their heuristic is simultaneously both excluding MI and also assessing the patient’s risk for having MACE within the short term (studies usually assess this to be a 4-6 week horizon). | The intent of our comment was for the need for standardized language in the literature. We clarified the text to note terms like low or high risk should be clearly defined.
| | - Limitations: Agree with the point regarding effect rather than implementation. Also seems this section should reinforce some of the limitations noted throughout the rest of the manuscript: heterogeneity of studies with respect to populations, locations, methods, outcomes, etc. | The objective of the Limitations section is to describe the limitations of the review (e.g., methods or focus) and not the limitations identified literature. As noted, we describe in other sections the limitations of the scientific literature.
22 | 5 | Congratulations on an amazing job of organizing this complicated report in a clinically meaningful way. Despite the lack of clarity within the literature on defining ADP’s the criteria used in the quality assessment distilled the studies to a more manageable number for the readers to digest. There is enough confidence in the ADPs to answer meaningful questions as well as highlight area where further studies are needed.; Although no “best protocol” for ADP plus hs-TN with low MACE risk stood out, this report provides a foundation which will help subsequent pilots and research to narrow the scope of questions that will provide meaningful clinical answers for the VA. This work will save a lot of time for groups that wish to use this report for future meta-analysis when more studies are completed. I appreciate the complexity and the challenge that it took to create, distill, and synthesize this data. The information is descriptive which adds to its length which appears to be necessary to provide adequate understanding of the protocols as medical definitions and terminology variability was notable. The inconsistent descriptions proved to be difficult to combine studies in a typical meta-analytic approach.; It provides information on which source trials are most informative. A reader can find relevant information pertinent to their interest in the tables (Table 3. Description of Accelerated Diagnostic Protocol on pg 22) that categorize the accelerated diagnostic protocol with the more descriptive information in the body of the report. The prioritization presents the more important data of MACE, LOS, admit status and ED revisits as well as cardiac testing and revascularization.; Overall, the report does not have enough comparable data to support new VA protocols and highlights the need for further investigation to attempt to single out an ADP + hs TN with low risk for the VA emergency Departments. As there are not uniformity in terms and uniformity in ADPs to supply comparable data, the report supplies the data needed for the additional work required. If future studies present similar metrics and comparable ADPs, even underpowered studies could be combined though the cumulative reporting to gain power across studies. As noted in the Research Gaps/Future Research on page 6, it will continue to be important to understand whether hscTN ADPs can be successfully and safely implemented in US EDs that may not be part of large integrated health systems.; On page 3, last paragraph is meaningful as direct comparisons of shorter vs longer duration ADPS as noted with a moderate confidence, the studies reported “no evidence of difference between shorter and longer duration ADPs in 30 day MACE (RD – 0.1%, 95% CI – 0.2 – 0.03) or 30 day MI (RD – 0.1%, 95% CI – 0.2 to 0.01), but shorter ADPs probably reduce ED length of stay (by 2 to 4 hours in each study, mostly reporting as statistically significant and probably increase discharge to the community from the ED (in two studies, by either 3% or 21% both statistically significant)”. Summarizing across different ADPs studies using common risk scores adds meaningful information that the 01 vs 03 vs 06 appears not to make a difference in outcomes. This supports the metric concerns of ED LOS does not impact negatively on quality of care and may actually improve quality by reducing crowding and provides supports to narrow future studies to use ADPs with 02 or possibly 01 analysis. | Thank you.
| | Page 15 Synthesis and Certainty of evidence fourth paragraph, it would be important to comment that CIs can be used in place of P values to test hypotheses, so studies using CIs in place of p values is using statistics correctly. In Appendix Table J-5 in Appendix F, if a confidence interval (CI) is reported statistical significance can be inferred. | Thank you. We edited for clarity and revised the text that describes the method for conducting synthesis & certainty of evidence. Edits also included removing language around the specific GRADE domains (e.g., precision and the role of p-values / 95% CI) and instead we reference the interested reader to the relevant GRADE publication (ref 22).
| | This sentence it the last paragraph is unclear: “In both studies, the novel ADP was associated with a significantly shorter length of stay (mean [SD] High-STEACS 0/3 ADP 6.8 [4.1] vs. 0/6/12 ADP 10 [4.1]; p<0.001;21 and median [inter quartile range] 0/3/6 ADP 6.5 [6.3 to 19.8] vs. 0/6/12 GRACE ADP 8.9 [3.7 to 38]; p<0.001); Appendix Table K-1).” The p values suggest the medians are different in the two groups, but when you look at the IQR they do not seem that different. So maybe the p values are testing each median? Perhaps comment on the lack of clarity? How were these p values interpreted? | We revised the sentence to clarify the findings.
| | In Appendix Table K-6 pg 102, I’m not sure what the p values are testing. What is the “Beta” parameter in the MD (95% CI) column. In appendix table K-6 should it note what the parameters are for column MD (95% CI) and what is the P value testing in the column Reported P value? | We revised the Appendix table to clarify the interpretation of the beta coefficient. Specifically, the coefficient is the association of the novel ADP compared to standard ADP and the outcome is log-transformed duration of stay. The coefficient is adjusted by age, sex, diabetes, creatinine, and history of MI, heart failure or cerebrovascular disease. For example, the coefficient −0.0135 is interpreted as the novel ADP results in a −1.34% reduction in ED length of stay.
| | Page 36 minor spelling error on mortality as “morality” in paragraph three and disposition as “disposotion” in paragraph four. | Thank you.
23 | 6 | This was a very much needed report, at the least to describe the current state of literature and evidence for clinical use of hs-cTn in risk-stratifying chest pain. | Thank you.
24 | 11 | This is an excellent synthesis of review on the topic of use of HsTn in the clinical evaluation of patients. It fairly summarizes the literature on this topic, which is indeed a bit over-interpreted by the field. The suggestions for further study and for VA implications are fair and in line with what is actually published on the subject. | Thank you.
| | My only suggestion is to add one element in the Discussion sections. There is little to no discussion in the review on the natural variation between hsTroponin I and hsTroponin T. TnT is only marketed by Roche, but we have a lot of Roche labs in the VA system (and thus will have both markers in use in VA longitudinally). The two troponin markers are not exactly the same and cannot necessarily be protocolized interchangeably. A note to this effect in the discussion is likely sufficient at this juncture, as I’m not aware of any literature that addresses the impact of marker variation on the specifics of protocol synthesis and validation. Bottom-line: Any VA-wide protocols or studies will need to account for the inherent differences between these two markers. | Thank you. We revised the Discussion to comment that troponin I and T are not interchangeable. Any ED that aims to implement a protocol will need to account for these inherit differences.