# APPENDIX D QUALITY RATINGS FOR ALL ELIGIBLE STUDIES

Appendix Table D-1 Quality Rating for Comparative Studies

Author, Year, PMID | Free of Discrepancies | Eligibility Clear | ADP Clear | Outcomes Adequately Defined | Setting Clearly Defined | Missing Results | Outcome Assessment Blind / Independent | RCT | | Observational study | | Effect on Clinical Measures Overall | Effect on Health Service Use Measures Overall
Author, Year, PMID | Free of Discrepancies | Eligibility Clear | ADP Clear | Outcomes Adequately Defined | Setting Clearly Defined | Missing Results | Outcome Assessment Blind / Independent | Adequate Randomization and Allocation Concealment | Patients Selected at Random | Comparator Group Similar | Adjustment for Confounders | Effect on Clinical Measures Overall | Effect on Health Service Use Measures Overall
RCT
Anand 2021; 33752439; RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | Yes (low RoB) | Yes (low RoB) | | | | Low RoB (RCT) | Low RoB (RCT)
Than 2016; 26947800; RCT | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (high RoB) | Yes (low RoB) | Yes (low RoB) | | | | Low RoB (RCT) | Low RoB (RCT)
NRCS
Barnes 2021; 33436490; NRCS | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | No or inadequate description (unclear RoB) | | Yes (low RoB) | Yes (low RoB) | Yes regression adjustment (low RoB) | Medium RoB (NRCS) | Low RoB (NRCS)
Hyams 2018; 29478861; NRCS | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | No (moderate RoB) | | Yes (low RoB) | Yes (low RoB) | Yes regression adjustment (low RoB) | Medium RoB (NRCS) | Low RoB (NRCS)
Sandeman 2021; 34824100; NRCS | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | Record linkage (moderate RoB) | | Yes (low RoB) | Yes (low RoB) | Yes regression adjustment (low RoB) | Medium RoB (NRCS) | Low RoB (NRCS)
Stoyanov 2020; 31298551; NRCS | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | Yes (low RoB) | | Yes (low RoB) | No (high RoB) | Yes regression adjustment (low RoB) | Medium RoB (NRCS) | Low RoB (NRCS)
Than 2021; 33753972; NRCS | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | No or inadequate description (unclear RoB) | | Yes (low RoB) | No or inadequate description (unclear RoB) | Crude analysis (high RoB) | High RoB (NRCS) | High RoB (NRCS)

Appendix Table D-2 Quality Rating for Single Group Studies

Author, Year, PMID | Free of Discrepancies | Eligibility Clear | ADP Clear | Outcomes Adequately Defined | Setting Clearly Defined | Missing Results | Outcome Assessment Blind / Independent | RCT | | Observational study | | Measurement of Clinical Measures Overall | Measurement of Health Service Use Measures Overall
Author, Year, PMID | Free of Discrepancies | Eligibility Clear | ADP Clear | Outcomes Adequately Defined | Setting Clearly Defined | Missing Results | Outcome Assessment Blind / Independent | Adequate Randomization and Allocation Concealment | Patients Selected at Random | Comparator Group Similar | Adjustment for Confounders | Measurement of Clinical Measures Overall | Measurement of Health Service Use Measures Overall
Single Group
Chew 2019; 31478763; Lambrakis 2021; 33998255; RCT (analyzed as single group) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | Yes (low RoB) | | Yes (low RoB) | | | Low RoB (single) | Low RoB (single)
Conde 2013; 23810070; NRCS (analyzed as single group) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | No or inadequate description (unclear RoB) | | Yes (low RoB) | | | Medium RoB (single) | Low RoB (single)
Costable 2014; NA; Single group | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern | No (low RoB) | No or inadequate description (unclear RoB) | | Yes (low RoB) | | | Medium RoB (single) | Low RoB (single)
Crowder 2015; 26387473; NRCS (analyzed as single group) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | No or inadequate description (unclear RoB) | | Yes (low RoB) | | | Low RoB (single) | Low RoB (single)
Ford 2021; 33662739; NRCS (analyzed as single group) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | Record linkage (moderate RoB) | | Yes (low RoB) | | | Medium RoB (single) | Low RoB (single)
Ljung 2019; 30661856; NRCS (analyzed as single group) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | Yes (low RoB) | | Yes (low RoB) | | | Low RoB (single) | Low RoB (single)
Suh 2022; 35571147; NRCS (analyzed as single group) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (Low concern) | No (low RoB) | Yes (low RoB) | | Yes (low RoB) | | | Low RoB (single) | Low RoB (single)
Sweeney 2020; 32104767; NRCS (analyzed as single group) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | No or inadequate description (unclear RoB) | | Yes (low RoB) | | | n/a | Low RoB (single)
Twerenbold 2019; 31345421; Single group | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (l ow concern) | No (low RoB) | Yes (low RoB) | | Yes (low RoB) | | | Low RoB (single) | Low RoB (single)
Vigen 2020; 32320036; NRCS (analyzed as single group) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | Yes (low concern) | No (low RoB) | Record linkage (Moderate RoB) | | Yes (low RoB) | | | Medium RoB (single) | Medium RoB (single)