# APPENDIX C CRITERIA USED IN QUALITY ASSESSMENT

Question | | Yes | No | Unclear
1. | Design; a. Randomized control trial; b. Nonrandomized comparison of interventions; c. Single group
2. | Was the article free of discrepancies (eg, between text and tables)? Add note if No (High concern)?
3. | Were patient eligibility criteria sufficiently clear? Add note if No (High concern).
4. | Were the ADP (and comparator) sufficiently clear? Add note if No (High concern)
5. | Were outcomes adequately defined without problem? Add note if No (High concern). Not every outcome requires an explicit definition (eg, duration of ED stay).
6. | Was the setting sufficiently clearly defined? (eg,, do we know the hospital (and ED) type?) Add note if No (High concern).
7. | Were there missing results data for ANY patients for outcomes that occurred in ED or hospital? Were there missing results data for >20% of patients (or imbalance between study groups) for outcomes that occurred after ED/hospital discharge? Add Note if Yes
8. | Outcome assessment; a. No (or inadequate) description of how final determination of MI was diagnosed [Unclear RoB]; b. Independent or blind adjudication of MI for each patient by reference to secure medical records [Low RoB]; c. Record linkage (eg identified through ICD codes on database records) [Moderate RoB]; d. Self report (by patient or family) with no reference to original structured injury data or imaging [High RoB]
9. | If RCT, was there inadequate randomization method or allocation concealment? Whether randomization was done at the level of the ED or the patient, answer No (low RoB), unless there’s an obvious flaw.
10. | If observational study, eligible patients having ADP were all selected or a random selection was selected. No concerns about biased selection of ADP patients. Add note if No (high RoB)
11. | If observational study, comparator group (or ED) was sufficiently similar (and selected patients were all included or a random sample were included). Add note if No (high RoB)
12. | If observational study, Adjustment for confounders.; a. Crude analysis (unadjusted comparison between ADP and no ADP) [High RoB]; b. Regression adjustment or patient-matching (accounting for at least age, sex, and symptom duration OR a risk score) [Low RoB]; c. Regression adjustment or patient-matching (not accounting at least one of for age, sex, symptom duration, or risk score) [Moderate RoB]; d. Propensity score analysis (or equivalent) [Low RoB]