# APPENDIX B EXCLUDED STUDIES

1 Agrawal AVS, Rupesh; Singh, Manbir. Validation of 0 -2 hour algorithm for rule in and rule out myocardial infarction based on highly sensitive troponin I assay. Indian Heart Journal. 2018;70:S27–S44. Abstract, no PDF.
2 Aloe R, Lippi G, Di Pietro M, . Improved efficiency and cost reduction in the emergency department by replacing contemporary sensitive with high-sensitivity cardiac troponin immunoassay. Acta Biomed. Dec 23 2019;90(4):614–620. doi:10.23750/abm.v90i4.8769. No defined ADP.31910198
3 Aldous SJ, Richards AM, Cullen L, Than MP. Early dynamic change in high-sensitivity cardiac troponin T in the investigation of acute myocardial infarction. Clin Chem. Aug 2011;57(8):1154–60. doi:10.1373/clinchem.2010.161166. No defined ADP.21784766
4 Aldous S, Pemberton C, Richards AM, Troughton R, Than M. High-sensitivity troponin T for early rule-out of myocardial infarction in recent onset chest pain. Emerg Med J. Oct 2012;29(10):805–10. doi:10.1136/emermed-2011-200222. No defined ADP.22109535
5 Allen BR, Christenson RH, Cohen SA, . Diagnostic Performance of High-Sensitivity Cardiac Troponin T Strategies and Clinical Variables in a Multisite US Cohort. Circulation. Apr 27 2021;143(17):1659–1672. doi:10.1161/circulationaha.120.049298. Not prospective.33474976
6 Allen BR, Simpson GG, Zeinali I, . Incorporation of the HEART Score Into a Low-risk Chest Pain Pathway to Safely Decrease Admissions. Crit Pathw Cardiol. Dec 2018;17(4):184–190. doi:10.1097/hpc.0000000000000155. Not high-sensitivity Tn.30418248
7 Ambavane A, Lindahl B, Giannitsis E, . Economic evaluation of the one-hour rule-out and rule-in algorithm for acute myocardial infarction using the high-sensitivity cardiac troponin T assay in the emergency department. PLoS One. 2017;12(11):e0187662. doi:10.1371/journal.pone.0187662. Not prospective.29121105
8 Ambavane A, Lindahl B, Giannitsis E, . Correction: Economic evaluation of the one-hour rule-out and rule-in algorithm for acute myocardial infarction using the high-sensitivity cardiac troponin T assay in the emergency department. PLoS One. 2018;13(1):e0191348. doi:10.1371/journal.pone.0191348. Not published/peer reviewed.29324828
9 Amsterdam EA, Wenger NK, Brindis RG, . 2014 AHA/ACC guideline for the management of patients with non-ST-elevation acute coronary syndromes: executive summary: a report of the American College of Cardiology/American Heart Association Task Force on Practice Guidelines. Circulation. Dec 23 2014;130(25):2354–94. doi:10.1161/cir.0000000000000133. No defined ADP.25249586
10 Anand A, Shah ASV, Strachan FE, . P3593Improving the performance of high-sensitivity cardiac troponin for the diagnosis of myocardial infarction. European Heart Journal. 2019;40(Supplement_1)doi:10.1093/eurheartj/ehz745.0453. No defined ADP.
11 Andersen CF, Bang C, Lauridsen KG, . Single troponin measurement to rule-out acute myocardial infarction in early presenters. Int J Cardiol. Oct 15 2021;341:15–21. doi:10.1016/j.ijcard.2021.08.005. Not prospective.34391791
12 Andruchow JE, Boyne T, Innes G, . Low High-Sensitivity Troponin Thresholds Identify Low-Risk Patients With Chest Pain Unlikely to Benefit From Further Risk Stratification. CJC Open. Nov 2019;1(6):289–296. doi:10.1016/j.cjco.2019.08.002. Not prospective.32159123
13 Andruchow JE, Boyne T, Seiden-Long I, . Prospective comparative evaluation of the European Society of Cardiology (ESC) 1-hour and a 2-hour rapid diagnostic algorithm for myocardial infarction using high-sensitivity troponin-T. Cjem. Sep 2020;22(5):712–720. doi:10.1017/cem.2020.349. Not prospective.32624061
14 Arslan M, Dedic A, Boersma E, Dubois EA. Serial high-sensitivity cardiac troponin T measurements to rule out acute myocardial infarction and a single high baseline measurement for swift rule-in: A systematic review and meta-analysis. Eur Heart J Acute Cardiovasc Care. Feb 2020;9(1):14–22. doi:10.1177/2048872618819421. No defined ADP.30618277
15 Arslan M, Schaap J, Rood PPM, . HEART score improves efficiency of coronary computed tomography angiography in patients suspected of acute coronary syndrome in the emergency department. European Heart Journal Acute Cardiovascular Care. 2020;9(1):23–29. doi:10.1177/2048872619882424. Secondary analysis study.31647305
16 Astley CM, Beltrame JF, Zeitz C, . Study design of embracing high-sensitivity troponin effectively: the value of more information: a randomized comparison. Contemp Clin Trials. Nov 2014;39(2):183–90. doi:10.1016/j.cct.2014.08.012. This is a study design with no results.25195084
17 Aurora L, McCord J, Nowak R, . Prognostic Utility of a Modified HEART Score When Different Troponin Cut Points Are Used. Crit Pathw Cardiol. Sep 1 2021;20(3):134–139. doi:10.1097/hpc.0000000000000262. Not prospective.33988541
18 Avigni N, Ippoliti M, Muccinelli M, . Chest pain in the emergency department: benefits of a management model modified from the ANMCO-SIMEU recommendations. Giornale Italiano di Cardiologia (2006). 2011;12(5):365–373. No PDF found.21593956
19 Badertscher P, Boeddinghaus J, Nestelberger T, . Effect of Acute Coronary Syndrome Probability on Diagnostic and Prognostic Performance of High-Sensitivity Cardiac Troponin. Clin Chem. Mar 2018;64(3):515–525. doi:10.1373/clinchem.2017.279513. No defined ADP.29343534
20 Badertscher P, Boeddinghaus J, Twerenbold R, . Direct Comparison of the 0/1h and 0/3h Algorithms for Early Rule-Out of Acute Myocardial Infarction. Circulation. Jun 5 2018;137(23):2536–2538. doi:10.1161/circulationaha.118.034260. Not prospective.29866778
21 Bahrmann P, Christ M, Bahrmann A, . A 3-hour diagnostic algorithm for non-ST-elevation myocardial infarction using high-sensitivity cardiac troponin T in unselected older patients presenting to the emergency department. J Am Med Dir Assoc. Jun 2013;14(6):409–16. doi:10.1016/j.jamda.2012.12.005. No defined ADP.23375478
22 Bandstein N, Ljung R, Johansson M, Holzmann MJ. Undetectable high-sensitivity cardiac troponin T level in the emergency department and risk of myocardial infarction. J Am Coll Cardiol. Jun 17 2014;63(23):2569–2578. doi:10.1016/j.jacc.2014.03.017. No defined ADP.24694529
23 Bang C, Andersen CF, Lauridsen KG, . Rapid Rule-Out of Myocardial Infarction After 30 Minutes as an Alternative to 1 Hour: The RACING-MI Cohort Study. Ann Emerg Med. Feb 2022;79(2):102–112. doi:10.1016/j.annemergmed.2021.08.024. Not prospective.34969529
24 Bang C, Hansen C, Lauridsen KG, . Rapid use of high-sensitive cardiac troponin I for ruling-in and ruling-out of acute myocardial infarction (RACING-MI): study protocol. Open Heart. 2019;6(1):e000995. doi:10.1136/openhrt-2018-000995. Protocol itself has no results, and the results were published in a different study (Bang-2022-34969529).31168384
25 Bank IE, Dekker MS, Hoes AW, . Suspected acute coronary syndrome in the emergency room: Limited added value of heart type fatty acid binding protein point of care or ELISA tests: The FAME-ER (Fatty Acid binding protein in Myocardial infarction Evaluation in the Emergency Room) study. Eur Heart J Acute Cardiovasc Care. Aug 2016;5(4):364–74. doi:10.1177/2048872615584077. Not prospective.25906779
26 Baugh CW, Scirica BM, Januzzi JL, . Implementation of an Emergency Department High-Sensitivity Troponin Chest Pain Pathway in the United States. Crit Pathw Cardiol. Mar 2019;18(1):1–4. doi:10.1097/hpc.0000000000000164. Neither primary study nor SR.30747757
27 Beaune G, Yayehd K, Rocher T, . [Evaluation of rule out strategy for patients with non-ST-elevation acute coronary syndrome with single measurement of high-sensitivity cardiac troponin I from one sample tested beetween 3 and 6 hours after chest pain onset]. Ann Cardiol Angeiol (Paris). Nov 2021;70(5):270–274. Évaluation d’une stratégie d’exclusion d’un syndrome coronarien aigu non ST+ basé sur une unique mesure de troponine de haute sensibilité à partir d’un prélèvement effectué entre 3 et 6 heures après le début de la douleur. doi:10.1016/j.ancard.2021.07.006. Only r/out MI (others excluded).34517977
28 Bellini C, Cinci F, Bova G, . Methodology to Evaluate Clinical Impact of 0/3 Hour High-Sensitivity Cardiac Troponin T Protocol on Managing Acute Coronary Syndrome in Daily Emergency Department Practice. Lab Med. Sep 1 2021;52(5):452–459. doi:10.1093/labmed/lmaa118. No defined ADP.33511991
29 Bevins NJ, Chae H, Hubbard JA, . Emergency Department Management of Chest Pain With a High-Sensitivity Troponin-Enabled 0/1-Hour Rule-Out Algorithm. Am J Clin Pathol. May 4 2022;157(5):774–780. doi:10.1093/ajcp/aqab192. No defined ADP.34893795
30 Bhatti Y, Stevenson A, Weerasuriya S, Khan S. Reducing avoidable chest pain admissions and implementing high-sensitivity troponin testing. BMJ Open Qual. 2019;8(4):e000629. doi:10.1136/bmjoq-2019-000629. ADP cannot be replicated.
31 Biener M, Mueller M, Vafaie M, . Comparison of a 3-hour versus a 6-hour sampling-protocol using high-sensitivity cardiac troponin T for rule-out and rule-in of non-STEMI in an unselected emergency department population. Int J Cardiol. Aug 20 2013;167(4):1134–40. doi:10.1016/j.ijcard.2012.09.122. Not prospective.23063209
32 Björkelund A, Ohlsson M, Lundager Forberg J, . Machine learning compared with rule-in/rule-out algorithms and logistic regression to predict acute myocardial infarction based on troponin T concentrations. J Am Coll Emerg Physicians Open. Apr 2021;2(2):e12363. doi:10.1002/emp2.12363. Retrospective cross-sectional with no follow-up and ML.33778804
33 Bjurman C, Zywczyk M, Zangana S, . Patients discharged with elevated baseline high-sensitive cardiac troponin T from the emergency department. Biomarkers. Jul 2021;26(5):410–416. doi:10.1080/1354750x.2021.1917662. No outcomes within 6 weeks reported.33906551
34 Body R, Burrows G, Carley S, Lewis PS. The Manchester Acute Coronary Syndromes (MACS) decision rule: validation with a new automated assay for heart-type fatty acid binding protein. Emerg Med J. Oct 2015;32(10):769–74. doi:10.1136/emermed-2014-204235. Not high-sensitivity Tn.25539884
35 Body R, Carley S, McDowell G, . The Manchester Acute Coronary Syndromes (MACS) decision rule for suspected cardiac chest pain: derivation and external validation. Heart. Sep 15 2014;100(18):1462–8. doi:10.1136/heartjnl-2014-305564. Not prospective.24780911
36 Body R, Carlton E, Sperrin M, . Troponin-only Manchester Acute Coronary Syndromes (T-MACS) decision aid: single biomarker re-derivation and external validation in three cohorts. Emerg Med J. Jun 2017;34(6):349–356. doi:10.1136/emermed-2016-205983. Not prospective.27565197
37 Body R, Morris N, Collinson P. Single test rule-out of acute myocardial infarction using the limit of detection of a new high-sensitivity troponin I assay. Clin Biochem. Apr 2020;78:4–9. doi:10.1016/j.clinbiochem.2020.02.014. Not prospective.32135083
38 Body R, Morris N, Reynard C, Collinson PO. Comparison of four decision aids for the early diagnosis of acute coronary syndromes in the emergency department. Emerg Med J. Jan 2020;37(1):8–13. doi:10.1136/emermed-2019-208898. No defined ADP.31767674
39 Body R, Mueller C, Giannitsis E, . The Use of Very Low Concentrations of High-sensitivity Troponin T to Rule Out Acute Myocardial Infarction Using a Single Blood Test. Acad Emerg Med. Sep 2016;23(9):1004–13. doi:10.1111/acem.13012. No defined ADP.27178492
40 Body R, Twerenbold R, Austin C, . Diagnostic Accuracy of a High-Sensitivity Cardiac Troponin Assay with a Single Serum Test in the Emergency Department. Clin Chem. Aug 2019;65(8):1006–1014. doi:10.1373/clinchem.2018.294272. Not prospective.31118187
41 Boeddinghaus J, Lopez-Ayala P, Nestelberger T, . Prospective Validation of the ESC 0/1h-Algorithm Using High-Sensitivity Cardiac Troponin I. Am J Cardiol. Nov 1 2021;158:152–153. doi:10.1016/j.amjcard.2021.08.007. Not prospective.34470703
42 Boeddinghaus J, Nestelberger T, Badertscher P, . Predicting Acute Myocardial Infarction with a Single Blood Draw. Clin Chem. Mar 2019;65(3):437–450. doi:10.1373/clinchem.2018.294124. No defined ADP.30626633
43 Boeddinghaus J, Nestelberger T, Koechlin L, . Early Diagnosis of Myocardial Infarction With Point-of-Care High-Sensitivity Cardiac Troponin I. J Am Coll Cardiol. Mar 17 2020;75(10):1111–1124. doi:10.1016/j.jacc.2019.12.065. Not prospective.32164884
44 Boeddinghaus J, Nestelberger T, Twerenbold R, . High-Sensitivity Cardiac Troponin I Assay for Early Diagnosis of Acute Myocardial Infarction. Clin Chem. Jul 2019;65(7):893–904. doi:10.1373/clinchem.2018.300061. Not prospective.30988172
45 Boeddinghaus J, Nestelberger T, Twerenbold R, . Impact of age on the performance of the ESC 0/1h-algorithms for early diagnosis of myocardial infarction. Eur Heart J. Nov 7 2018;39(42):3780–3794. doi:10.1093/eurheartj/ehy514. Not prospective.30169752
46 Boeddinghaus J, Nestelberger T, Twerenbold R, . Direct Comparison of 4 Very Early Rule-Out Strategies for Acute Myocardial Infarction Using High-Sensitivity Cardiac Troponin I. Circulation. Apr 25 2017;135(17):1597–1611. doi:10.1161/circulationaha.116.025661. Retrospective applied cutofffs to compare 4 strategies.28283497
47 Boeddinghaus J, Reichlin T, Cullen L, . Two-Hour Algorithm for Triage toward Rule-Out and Rule-In of Acute Myocardial Infarction by Use of High-Sensitivity Cardiac Troponin I. Clin Chem. Mar 2016;62(3):494–504. doi:10.1373/clinchem.2015.249508. Not prospective.26797687
48 Boeddinghaus J, Twerenbold R, Nestelberger T, . Clinical Validation of a Novel High-Sensitivity Cardiac Troponin I Assay for Early Diagnosis of Acute Myocardial Infarction. Clin Chem. Sep 2018;64(9):1347–1360. doi:10.1373/clinchem.2018.286906. Not prospective.29941469
49 Boeddinghaus J, Twerenbold R, Nestelberger T, . Clinical Use of a New High-Sensitivity Cardiac Troponin I Assay in Patients with Suspected Myocardial Infarction. Clin Chem. Nov 2019;65(11):1426–1436. doi:10.1373/clinchem.2019.304725. Validiating hs-cTnI-VITROS.31570633
50 Bohyn E, Dubie E, Lebrun C, . Expeditious exclusion of acute coronary syndrome diagnosis by combined measurements of copeptin, high-sensitivity troponin, and GRACE score. Am J Emerg Med. Apr 2014;32(4):293–6. doi:10.1016/j.ajem.2013.11.043. Not prospective.24480311
51 Borna C, Frostred KL, Ekelund U. Predictive role of high sensitivity troponin T within four hours from presentation of acute coronary syndrome in elderly patients. BMC Emerg Med. Jan 4 2016;16:1. doi:10.1186/s12873-015-0064-z. Retrospective applied cutofffs to compare 4 strategies.26728878
52 Borna C, Kollberg K, Larsson D, Mokhtari A, Ekelund U. The objective CORE score allows early rule out in acute chest pain patients. Scand Cardiovasc J. Dec 2018;52(6):308–314. doi:10.1080/14017431.2018.1546891. Retrospective applied cutofffs to compare 4 strategies.30444442
53 Boyle RSJ, Body R. The Diagnostic Accuracy of the Emergency Department Assessment of Chest Pain (EDACS) Score: A Systematic Review and Meta-analysis. Ann Emerg Med. Apr 2021;77(4):433–441. doi:10.1016/j.annemergmed.2020.10.020. SR, not primary study.33461885
54 Bozdereli Berikol G, Aydın H, Doğan H. Early discharging patients with chest pain using EDACS-ADP and COMPASS-MI risk predictors. Heart Vessels. Feb 8 2022:1–10. doi:10.1007/s00380-022-02036-9. Not prospective.
55 Braga F, Dolci A, Cavallero A, Ghezzi A, Infusino I, Milano M, Rubino M, Marenzi G, Panteghini M. Evaluation of the sensitivity of two highly sensitive troponin assays for early detection of non ST-elevation myocardial infarction (NSTEMI). Biochimica Clinica. 35(3):186–189. Not English.
56 Brophy J. In adults with chest pain, a troponin limit of detection strategy did not increase early discharge rate. Ann Intern Med. Oct 20 2020;173(8):Jc45. doi:10.7326/acpj202010200-045. Neither primary study nor SR.33075263
57 Buccelletti F, Galiuto L, Marsiliani D, . Comparison of diagnostic accuracy between three different rules of interpreting high sensitivity troponin T results. Intern Emerg Med. Aug 2012;7(4):365–70. doi:10.1007/s11739-012-0787-8. Not prospective.22618889
58 Bularga A, Lee KK, Stewart S, . High-Sensitivity Troponin and the Application of Risk Stratification Thresholds in Patients With Suspected Acute Coronary Syndrome. Circulation. Nov 5 2019;140(19):1557–1568. doi:10.1161/circulationaha.119.042866. Not prospective.31475856
59 Burgio MA, Marino G, Di Maria D. Troponin cTnT-hs: a matter of gender and age? Evaluation of differentiated cut-offs by gender and age in an Emergency Department population. La Rivista Italiana della Medicina di Laboratorio - Italian Journal of Laboratory Medicine. 2018/03/01 2018;14(1):41–49. doi:10.1007/s13631-018-0184-z. Not Prospective.
60 Burgos LM, Trivi M, Costabel JP. Performance of the European Society of Cardiology 0/1-hour algorithm in the diagnosis of myocardial infarction with high-sensitivity cardiac troponin: Systematic review and meta-analysis. Eur Heart J Acute Cardiovasc Care. Jun 29 2020;doi:10.1177/2048872620935399. Systematic Review.
61 Burgstaller JM, Held U, Gravestock I, . Impact of the Introduction of High-Sensitive Troponin Assay in the Emergency Department: A Retrospective Study. Am J Med. Aug 2020;133(8):976–985. doi:10.1016/j.amjmed.2019.12.029. No defined ADP.31987803
62 CADTH Optimal Use Reports. High-Sensitivity Cardiac Troponin for the Rapid Diagnosis of Acute Coronary Syndrome in the Emergency Department: A Clinical and Cost-Effectiveness Evaluation. Canadian Agency for Drugs and Technologies in Health. Copyright © 2013 Canadian Agency for Drugs and Technologies in Health.; 2013. Systematic Review.
63 Cappellini F, Falbo R, Saltafossi D, . Development of an algorithm for ruling-out non-ST elevation myocardial infarction in the emergency department using high sensitivity troponin T assay. Clin Chim Acta. Aug 2019;495:1–7. doi:10.1016/j.cca.2019.03.1625. Not prospective.30910596
64 Carlton E, Body R, Greaves K. External Validation of the Manchester Acute Coronary Syndromes Decision Rule. Acad Emerg Med. Feb 2016;23(2):136–43. doi:10.1111/acem.12860. Not prospective.26802433
65 Carlton E, Campbell S, Ingram J, . Randomised controlled trial of the Limit of Detection of Troponin and ECG Discharge (LoDED) strategy versus usual care in adult patients with chest pain attending the emergency department: study protocol. BMJ Open. Oct 2 2018;8(10):e025339. doi:10.1136/bmjopen-2018-025339. No data were included in the main paper.
66 Carlton EW, Cullen L, Than M, Gamble J, Khattab A, Greaves K. A novel diagnostic protocol to identify patients suitable for discharge after a single high-sensitivity troponin. Heart. Jul 2015;101(13):1041–6. doi:10.1136/heartjnl-2014-307288. Not prospective.25691511
67 Carlton EW, Ingram J, Taylor H, . Limit of detection of troponin discharge strategy versus usual care: randomised controlled trial. Heart. Oct 2020;106(20):1586–1594. doi:10.1136/heartjnl-2020-316692. No defined ADP.32371401
68 Carlton EW, Khattab A, Greaves K. Identifying Patients Suitable for Discharge After a Single-Presentation High-Sensitivity Troponin Result: A Comparison of Five Established Risk Scores and Two High-Sensitivity Assays. Ann Emerg Med. Dec 2015;66(6):635–645.e1. doi:10.1016/j.annemergmed.2015.07.006. Not prospective.26260100
69 Carlton EW, Khattab A, Greaves K. Beyond triage: the diagnostic accuracy of emergency department nursing staff risk assessment in patients with suspected acute coronary syndromes. Emerg Med J. Feb 2016;33(2):99–104. doi:10.1136/emermed-2015-204780. Not prospective.26362581
70 Carlton EW, Pickering JW, Greenslade J, . Assessment of the 2016 National Institute for Health and Care Excellence high-sensitivity troponin rule-out strategy. Heart. Apr 2018;104(8):665–672. doi:10.1136/heartjnl-2017-311983. Not prospective.28864718
71 Chacón-Diaz M, Salinas J, Doig R. Stratification of thoracic pain with modified HEART score and its relationship to short term cardiovascular events. Archivos de cardiología de México. 2018;88(5):333–338. Unclear how modified HEART used by physician in ED to stratify patients. Not English language.28712683
72 Chapman AR, Adamson PD, Shah ASV, . High-Sensitivity Cardiac Troponin and the Universal Definition of Myocardial Infarction. Circulation. Jan 21 2020;141(3):161–171. doi:10.1161/circulationaha.119.042960. No defined ADP.31587565
73 Chapman AR, Anand A, Boeddinghaus J, . Comparison of the Efficacy and Safety of Early Rule-Out Pathways for Acute Myocardial Infarction. Circulation. Apr 25 2017;135(17):1586–1596. doi:10.1161/circulationaha.116.025021. Not prospective.28034899
74 Chapman AR, Fujisawa T, Lee KK, . Novel high-sensitivity cardiac troponin I assay in patients with suspected acute coronary syndrome. Heart. Apr 2019;105(8):616–622. doi:10.1136/heartjnl-2018-314093. Not prospective.30442743
75 Chapman AR, Hesse K, Andrews J, . High-Sensitivity Cardiac Troponin I and Clinical Risk Scores in Patients With Suspected Acute Coronary Syndrome. Circulation. Oct 16 2018;138(16):1654–1665. doi:10.1161/circulationaha.118.036426. Not prospective.30354460
76 Chapman AR, Lee KK, McAllister DA, . Association of High-Sensitivity Cardiac Troponin I Concentration With Cardiac Outcomes in Patients With Suspected Acute Coronary Syndrome. Jama. Nov 21 2017;318(19):1913–1924. doi:10.1001/jama.2017.17488. Systematic Review.29127948
77 Charpentier S, Chenevier-Gobeaux C. [2015 ESC guidelines: 1-hour rule-out and rule-in of acute myocardial infarction with high-sensitive troponin T]. Presse Med. Oct 2016;45(10):859–864. Recommandations ESC 2015 : exclure ou confirmer le diagnostic d’infarctus du myocarde en 1 heure avec la troponine T hypersensible. doi:10.1016/j.lpm.2016.05.023. Neither primary study nor SR.27374265
78 Chenevier-Gobeaux C, Meune C, Lefevre G, . A single value of high-sensitive troponin T below the limit of detection is not enough for ruling out non ST elevation myocardial infarction in the emergency department. Clin Biochem. Oct 2016;49(15):1113–1117. doi:10.1016/j.clinbiochem.2016.05.021. No defined ADP.27234598
79 Chew DP, Zeitz C, Worthley M, . Randomized Comparison of High-Sensitivity Troponin Reporting in Undifferentiated Chest Pain Assessment. Circ Cardiovasc Qual Outcomes. Sep 2016;9(5):542–53. doi:10.1161/circoutcomes.115.002488. No defined ADP.27506926
80 Chew PG, Frost F, Mullen L, . A direct comparison of decision rules for early discharge of suspected acute coronary syndromes in the era of high sensitivity troponin. Eur Heart J Acute Cardiovasc Care. Aug 2019;8(5):421–431. doi:10.1177/2048872618755369. Not prospective.29480016
81 Chiang CH, Chiang CH, Lee GH, . Safety and efficacy of the European Society of Cardiology 0/1-hour algorithm for diagnosis of myocardial infarction: systematic review and meta-analysis. Heart. Jul 2020;106(13):985–991. doi:10.1136/heartjnl-2019-316343. Systematic Review.32245882
82 Chiang CH, Chiang CH, Pickering JW, . Performance of the European Society of Cardiology 0/1-Hour, 0/2-Hour, and 0/3-Hour Algorithms for Rapid Triage of Acute Myocardial Infarction : An International Collaborative Meta-analysis. Ann Intern Med. Jan 2022;175(1):101–113. doi:10.7326/m21-1499. Systematic Review.34807719
83 Chiang CH, Chiang CH, Ruangsomboon O. Utilizing the European Society of Cardiology 0/3-h algorithm to triage the 0/1-h algorithm observe-zone. Eur Heart J Acute Cardiovasc Care. Mar 29 2022;doi:10.1093/ehjacc/zuac025. Not prospective.
84 Christ M, Popp S, Pohlmann H, . Implementation of high sensitivity cardiac troponin T measurement in the emergency department. Am J Med. Dec 2010;123(12):1134–42. doi:10.1016/j.amjmed.2010.07.015. No defined ADP.20932502
85 Chuang A, Gnanamanickam E, Lambrakis K, . Cost Effectiveness of a 1-Hour High-Sensitivity Troponin-t Protocol in Suspected Acute Coronary Syndrome: A Trial-Based Analysis of the Rapid-tnt Randomised Trial. Circulation. 2021;144(Suppl_1):A6984–A6984. Abstract of Chuang-2022-Cost effectiveness of a 1-hour hig.
86 Chuang MA, Gnanamanickam ES, Karnon J, . Cost effectiveness of a 1-hour high-sensitivity troponin-T protocol: An analysis of the RAPID-TnT trial. Int J Cardiol Heart Vasc. Feb 2022;38:100933. doi:10.1016/j.ijcha.2021.100933. No outcomes within 6 weeks reported.35024428
87 Clerico A, Ripoli A, Masotti S, . Evaluation of 99th percentile and reference change values of a high-sensitivity cTnI method: A multicenter study. Clin Chim Acta. Jun 2019;493:156–161. doi:10.1016/j.cca.2019.02.029. Not non-STEMI ACS.30826369
88 Collinson P, Gaze D, Goodacre S. Evaluation of the European Society of Cardiology recommended rapid diagnostic algorithms in a challenging low risk cohort. European Heart Journal. 2017;38(Suppl 1):998–998. Not published/peer reviewed.
89 Collinson PO GD, Goodacre S. Decision limits, delta troponin or both for the confirmation and exclusion of myocardial infarction using contemporary and high sensitive assays. Clinical Chemistry. 2018;64:S32. Abstract, no PDF.
90 Consuegra-Sánchez L, Martínez-Díaz JJ, de Guadiana-Romualdo LG, . No additional value of conventional and high-sensitivity cardiac troponin over clinical scoring systems in the differential diagnosis of type 1 vs. type 2 myocardial infarction. Clin Chem Lab Med. Apr 25 2018;56(5):857–864. doi:10.1515/cclm-2017-0609. No defined ADP.29303766
91 Cooper JG, Ferguson J, Donaldson LA, . Could High-Sensitivity Cardiac Troponin Testing Rule Out Acute Myocardial Infarction in the Prehospital Setting? J Am Coll Cardiol. Dec 7 2021;78(23):2392–2394. doi:10.1016/j.jacc.2021.10.004. Neither primary study nor SR.34857100
92 Corsini A, Vagnarelli F, Bugani G, . Impact of high-sensitivity Troponin T on hospital admission, resources utilization, and outcomes. Eur Heart J Acute Cardiovasc Care. Apr 2015;4(2):148–57. doi:10.1177/2048872614547687. No defined ADP.25124535
93 Cortés M, Haseeb S, Lambardi F, . The HEART score in the era of the European Society of Cardiology 0/1-hour algorithm. Eur Heart J Acute Cardiovasc Care. Feb 2020;9(1):30–38. doi:10.1177/2048872619883619. Not prospective.31657616
94 Cortés MM, Lambardi F, Ariznavarreta P, . Usefulness of the HEART score with high-sensitivity troponin T for the evaluation of patients with chest pain. Revista Argentina de Cardiologia. 2018;86(5):317–321. Not prospective.
95 Costabel JP, Campos R, Ariznavarreta P, . Results of the first patients with suspected acute coronary syndrome evaluated with the 1-hour algorithm proposed by the European Society of Cardiology. Revista Argentina de Cardiología. 2019;87(3):197–202. Only hs-cTN.
96 Croce A, Brunati P, Colzani C, . A Rational Adoption of the High Sensitive Assay for Cardiac Troponin I in Diagnostic Routine. Dis Markers. 2017;2017:4523096. doi:10.1155/2017/4523096. Not prospective.28588346
97 Cuda G, Lentini M, Gallo L, . High sensitive troponin T in individuals with chest pain of presumed ischemic origin. Front Biosci (Elite Ed). Jun 1 2012;4(7):2322–7. doi:10.2741/e544. No defined ADP.22652639
98 Cullen L, Aldous S, Than M, . Comparison of high sensitivity troponin T and I assays in the diagnosis of non-ST elevation acute myocardial infarction in emergency patients with chest pain. Clin Biochem. Apr 2014;47(6):321–6. doi:10.1016/j.clinbiochem.2013.11.019. This is a secondary analysis, not clear if hs-TnT was combine with other components in a pre-defined protocol.24316100
99 Cullen L, Greenslade J, Than M, . Performance of risk stratification for acute coronary syndrome with two-hour sensitive troponin assay results. Heart Lung Circ. May 2014;23(5):428–34. doi:10.1016/j.hlc.2013.11.003. Not high-sensitivity Tn.24321648
100 Cullen L, Greenslade JH, Carlton EW, . Sex-specific versus overall cut points for a high sensitivity troponin I assay in predicting 1-year outcomes in emergency patients presenting with chest pain. Heart. Jan 2016;102(2):120–6. doi:10.1136/heartjnl-2015-308506. No outcomes within 6 weeks reported.26729608
101 Cullen L, Greenslade JH, Than M, . The new Vancouver Chest Pain Rule using troponin as the only biomarker: an external validation study. Am J Emerg Med. Feb 2014;32(2):129–34. doi:10.1016/j.ajem.2013.10.021. Not prospective.24238485
102 Cullen L, Mueller C, Parsonage WA, . Validation of high-sensitivity troponin I in a 2-hour diagnostic strategy to assess 30-day outcomes in emergency department patients with possible acute coronary syndrome. J Am Coll Cardiol. Oct 1 2013;62(14):1242–1249. doi:10.1016/j.jacc.2013.02.078. Not prospective.23583250
103 Dadkhah S, Almuwaqqat Z, Sulaiman S, . Sensitive Troponin I and Stress Testing in the Emergency Department for the Early Management of Chest Pain Using 2-Hour Protocol. Crit Pathw Cardiol. Sep 2017;16(3):89–92. doi:10.1097/hpc.0000000000000115. Not high-sensitivity Tn.28742643
104 Dawson C, Benger JR, Bayly G. Serial high-sensitivity troponin measurements for the rapid exclusion of acute myocardial infarction in low-risk patients. Emerg Med J. Jul 2013;30(7):593–4. doi:10.1136/emermed-2012-201574. Not prospective.22851671
105 Dedic A, Lubbers MM, Schaap J, . Coronary CT Angiography for Suspected ACS in the Era of High-Sensitivity Troponins: Randomized Multicenter Study. J Am Coll Cardiol. Jan 5 2016;67(1):16–26. doi:10.1016/j.jacc.2015.10.045. No defined ADP.26764061
106 Dongxu C, Yannan Z, Yilin Y, . Evaluation of the 0 h/1 h high-sensitivity cardiac troponin T algorithm in diagnosis of non-ST-segment elevation myocardial infarction (NSTEMI) in Han population. Clin Chem Lab Med. Mar 26 2021;59(4):757–764. doi:10.1515/cclm-2020-0367. No defined ADP.33554576
107 Doudesis D, Lee KK, Yang J, . Validation of the myocardial-ischaemic-injury-index machine learning algorithm to guide the diagnosis of myocardial infarction in a heterogenous population: a prespecified exploratory analysis. Lancet Digit Health. May 2022;4(5):e300–e308. doi:10.1016/s2589-7500(22)00025-5. Not prospective.35461689
108 Druey S, Wildi K, Twerenbold R, . Early rule-out and rule-in of myocardial infarction using sensitive cardiac Troponin I. Int J Cardiol. Sep 15 2015;195:163–70. doi:10.1016/j.ijcard.2015.05.079. Not high-sensitivity Tn.26043151
109 Dupuy AM, Pasquier G, Thiebaut L, Roubille F, Sebbane M, Cristol JP. Additive value of bioclinical risk scores to high sensitivity troponins-only strategy in acute coronary syndrome. Clin Chim Acta. Dec 2021;523:273–284. doi:10.1016/j.cca.2021.10.008. Not prospective.34648808
110 Eggers KM, Aldous S, Greenslade JH, . Two-hour diagnostic algorithms for early assessment of patients with acute chest pain--Implications of lowering the cardiac troponin I cut-off to the 97.5th percentile. Clin Chim Acta. May 20 2015;445:19–24. doi:10.1016/j.cca.2015.03.002. Not prospective.25771107
111 Etaher A, Chew DP, Frost S, . Prognostic Implications of High-Sensitivity Troponin T Levels Among Patients Attending Emergency Departments and Evaluated for an Acute Coronary Syndrome. Am J Med. Aug 2021;134(8):1019–1028.e1. doi:10.1016/j.amjmed.2021.03.005. No defined ADP.33812862
112 Ezekowitz JA, Welsh RC, Weiss D, . Providing Rapid Out of Hospital Acute Cardiovascular Treatment 4 (PROACT-4). J Am Heart Assoc. Dec 1 2015;4(12)doi:10.1161/jaha.115.002859. Not high-sensitivity Tn.
113 Farook N, Cochon L, Bode AD, Langer BP, Baez AA. HEART Score and Stress Test Emergency Department Bayesian Decision Scheme: Results from the Acute Care Diagnostic Collaboration. J Emerg Med. Feb 2018;54(2):147–155. doi:10.1016/j.jemermed.2017.10.021. Not high-sensitivity Tn.29428052
114 Ferencik M, Liu T, Mayrhofer T, . hs-Troponin I Followed by CT Angiography Improves Acute Coronary Syndrome Risk Stratification Accuracy and Work-Up in Acute Chest Pain Patients: Results From ROMICAT II Trial. JACC Cardiovasc Imaging. Nov 2015;8(11):1272–1281. doi:10.1016/j.jcmg.2015.06.016. hs-cTn portion of the trial not prospective.26476506
115 Ferencik M, Mayrhofer T, Lu MT, . High-Sensitivity Cardiac Troponin I as a Gatekeeper for Coronary Computed Tomography Angiography and Stress Testing in Patients with Acute Chest Pain. Clin Chem. Nov 2017;63(11):1724–1733. doi:10.1373/clinchem.2017.275552. Not prospective.28923845
116 Ferry AV, Anand A, Strachan FE, . Presenting Symptoms in Men and Women Diagnosed With Myocardial Infarction Using Sex-Specific Criteria. J Am Heart Assoc. Sep 3 2019;8(17):e012307. doi:10.1161/jaha.119.012307. No defined ADP.31431112
117 Ferry AV, Strachan FE, Stewart SD, . Exploring Patient Experience of Chest Pain Before and After Implementation of an Early Rule-Out Pathway for Myocardial Infarction: A Qualitative Study. Ann Emerg Med. Apr 2020;75(4):502–513. doi:10.1016/j.annemergmed.2019.11.012. Qualitative study.31983496
118 Freund Y, Chenevier-Gobeaux C, Bonnet P, . High-sensitivity versus conventional troponin in the emergency department for the diagnosis of acute myocardial infarction. Crit Care. Jun 10 2011;15(3):R147. doi:10.1186/cc10270. No defined ADP.21663627
119 Gallacher PJ, Miller-Hodges E, Shah ASV, . High-sensitivity cardiac troponin and the diagnosis of myocardial infarction in patients with kidney impairment. Kidney Int. Jul 2022;102(1):149–159. doi:10.1016/j.kint.2022.02.019. No defined ADP.35271932
120 Gelber A, Drescher M, Shiber S. Sex Differences in Identifying Chest Pain as Being of Cardiac Origin Using the HEART Pathway in the Emergency Department. J Womens Health (Larchmt). May 2 2022;doi:10.1089/jwh.2021.0453. No outcomes within 6 weeks reported.
121 Giannitsis E, Clifford P, Slagman A, . Multicentre cross-sectional observational registry to monitor the safety of early discharge after rule-out of acute myocardial infarction by copeptin and troponin: the Pro-Core registry. BMJ Open. Jul 23 2019;9(7):e028311. doi:10.1136/bmjopen-2018-028311. Combination with other lab (only).
122 Giannitsis E, Kehayova T, Vafaie M, Katus HA. Combined testing of high-sensitivity troponin T and copeptin on presentation at prespecified cutoffs improves rapid rule-out of non-ST-segment elevation myocardial infarction. Clin Chem. Oct 2011;57(10):1452–5. doi:10.1373/clinchem.2010.161265. The algorithm combined copeptin, conventional and hs-TnT, and GRACE score. No separate analysis or subgroup was done.21807867
123 Gibbs J, deFilippi C, Peacock F, . The utility of risk scores when evaluating for acute myocardial infarction using high-sensitivity cardiac troponin I. Am Heart J. Sep 2020;227:1–8. doi:10.1016/j.ahj.2020.05.014. Not prospective.32634671
124 Graven T, Klykken B, Kleinau O, Skjetne K, Andersen G, Dalen H. Measurement of high-sensitivity troponin-I in suspected coronary-related chest pain in Emergency Departments. Tidsskr Nor Laegeforen. Sep 7 2021;141(2021-12)Høysensitiv troponin I-måling ved koronarsuspekte brystsmerter i akuttmottak. doi:10.4045/tidsskr.21.0037. No defined ADP.
125 Gray A. 011 High-sensitivity cardiac troponin on presentation to rule out myocardial infarction (HiSTORIC): a stepped-wedge cluster randomised controlled trial. BMJ Publishing Group Ltd and the British Association for Accident …; 2019. Not published/peer reviewed.
126 Gray AJ, Roobottom C, Smith JE, . The RAPID-CTCA trial (Rapid Assessment of Potential Ischaemic Heart Disease with CTCA) - a multicentre parallel-group randomised trial to compare early computerised tomography coronary angiography versus standard care in patients presenting with suspected or confirmed acute coronary syndrome: study protocol for a randomised controlled trial. Trials. Dec 7 2016;17(1):579. doi:10.1186/s13063-016-1717-2. Not non-STEMI ACS.27923390
127 Greenslade JH, Carlton EW, Van Hise C, . Diagnostic Accuracy of a New High-Sensitivity Troponin I Assay and Five Accelerated Diagnostic Pathways for Ruling Out Acute Myocardial Infarction and Acute Coronary Syndrome. Ann Emerg Med. Apr 2018;71(4):439–451.e3. doi:10.1016/j.annemergmed.2017.10.030. Not prospective.29248334
128 Greenslade JH, Chung K, Parsonage WA, . Modification of the Thrombolysis in Myocardial Infarction risk score for patients presenting with chest pain to the emergency department. Emerg Med Australas. Feb 2018;30(1):47–54. doi:10.1111/1742-6723.12913. Not prospective.29232768
129 Greenslade JH, Cullen L, Than M, . Validation of the Vancouver Chest Pain Rule using troponin as the only biomarker: a prospective cohort study. Am J Emerg Med. Jul 2013;31(7):1103–7. doi:10.1016/j.ajem.2013.04.016. Not prospective.23702078
130 Greenslade JH, Nayer R, Parsonage W, . Validating the Manchester Acute Coronary Syndromes (MACS) and Troponin-only Manchester Acute Coronary Syndromes (T-MACS) rules for the prediction of acute myocardial infarction in patients presenting to the emergency department with chest pain. Emerg Med J. Aug 2017;34(8):517–523. doi:10.1136/emermed-2016-206366. Not prospective.28363994
131 Greenslade JH, Parsonage W, Foran L, . Widespread Introduction of a High-Sensitivity Troponin Assay: Assessing the Impact on Patients and Health Services. J Clin Med. Jun 16 2020;9(6)doi:10.3390/jcm9061883. No defined ADP.
132 Gulati M, Levy PD, Mukherjee D, . 2021 AHA/ACC/ASE/CHEST/SAEM/SCCT/SCMR Guideline for the Evaluation and Diagnosis of Chest Pain: A Report of the American College of Cardiology/American Heart Association Joint Committee on Clinical Practice Guidelines. Circulation. Nov 30 2021;144(22):e368–e454. doi:10.1161/cir.0000000000001029. This is a report on multiple guidelines for the evaluation and diagnosis of chest pain.
133 Gunsolus I, Smith S, Herzog C, Sexter A, Apple F. 24 Influence of Renal Dysfunction on High-Sensitivity Cardiac Troponin I for Diagnostic Accuracy of Myocardial Infarction and Outcomes Assessment. American Journal of Clinical Pathology. 2018;149:S176. Not published/peer reviewed.
134 Hillinger P, Twerenbold R, Jaeger C, . Optimizing Early Rule-Out Strategies for Acute Myocardial Infarction: Utility of 1-Hour Copeptin. Clin Chem. Dec 2015;61(12):1466–74. doi:10.1373/clinchem.2015.242743. Patients were followed for 3, 12, and 24 months. Combination of copeptin and hs-TnT.26323282
135 Hochholzer W, Reichlin T, Twerenbold R, . Incremental value of high-sensitivity cardiac troponin T for risk prediction in patients with suspected acute myocardial infarction. Clinical chemistry. 2011;57(9):1318–1326. No defined ADP.21771945
136 Hrecko J, Dokoupil J, Pudil R. The use of T-MACS algorithm in elderly patients in acute cardiac care. Health & Environmental Research Online. 2020;19(3):149–154. doi:10.36290/kar.2020.038. No defined ADP.
137 Hrecko J, Dokoupil J, Pudil R. Comparison of six decision aid rules for diagnosis of acute myocardial infarction in elderly patients presenting to the emergency department with acute chest pain. Bratisl Lek Listy. 2022;123(4):282–290. doi:10.4149//bll_2022_045. Not prospective.35294215
138 Inoue K, Shiozaki M, Suwa S, Sumiyoshi M, Daida H. A 0/1-Hour Algorithm Using High-Sensitivity Cardiac Troponin. J Acute Med. Jun 1 2018;8(2):47–52. doi:10.6705/j.jacme.201806_8(2).0002. Review article, not primary study.32995203
139 Ishak M, Ali D, Fokkert MJ, . Fast assessment and management of chest pain without ST-elevation in the pre-hospital gateway: rationale and design. Eur Heart J Acute Cardiovasc Care. Apr 2015;4(2):129–36. doi:10.1177/2048872614549738. Not prospective.25202026
140 Ishak M, Ali D, Fokkert MJ, . Fast assessment and management of chest pain patients without ST-elevation in the pre-hospital gateway (FamouS Triage): ruling out a myocardial infarction at home with the modified HEART score. Eur Heart J Acute Cardiovasc Care. Mar 2018;7(2):102–110. doi:10.1177/2048872616687116. Not prospective.28084079
141 Jaeger C, Wildi K, Twerenbold R, . One-hour rule-in and rule-out of acute myocardial infarction using high-sensitivity cardiac troponin I. Am Heart J. Jan 2016;171(1):92–102.e1-5. doi:10.1016/j.ahj.2015.07.022. Not prospective.26699605
142 Januzzi JL, Jr., Bamberg F, Lee H, . High-sensitivity troponin T concentrations in acute chest pain patients evaluated with cardiac computed tomography. Circulation. Mar 16 2010;121(10):1227–34. doi:10.1161/circulationaha.109.893826. No outcomes within 6 weeks reported.20194879
143 Johannessen TR, Atar D, Vallersnes OM, Larstorp ACK, Mdala I, Halvorsen S. Comparison of a single high-sensitivity cardiac troponin T measurement with the HEART score for rapid rule-out of acute myocardial infarction in a primary care emergency setting: a cohort study. BMJ Open. Feb 24 2021;11(2):e046024. doi:10.1136/bmjopen-2020-046024. Not prospective.
144 Johannessen TR, Halvorsen S, Atar D, Vallersnes OM. Performance of the Novel Observation Group Criteria of the European Society of Cardiology (ESC) 0/1-Hour Algorithm in a Low-Risk Population. J Am Heart Assoc. Apr 5 2022;11(7):e024927. doi:10.1161/jaha.121.024927. Not prospective.35352564
145 Johannessen TR, Vallersnes OM, Halvorsen S, Larstorp ACK, Mdala I, Atar D. Pre-hospital One-Hour Troponin in a Low-Prevalence Population of Acute Coronary Syndrome: OUT-ACS study. Open Heart. Jul 2020;7(2)doi:10.1136/openhrt-2020-001296. hs-cTn result given to MD but not in the context of the algo.
146 Jülicher P, Greenslade JH, Parsonage WA, Cullen L. The organisational value of diagnostic strategies using high-sensitivity troponin for patients with possible acute coronary syndromes: a trial-based cost-effectiveness analysis. BMJ Open. Jun 9 2017;7(6):e013653. doi:10.1136/bmjopen-2016-013653. Neither primary study nor SR.
147 Kaambwa B, Ratcliffe J, Horsfall M, . Cost effectiveness of high-sensitivity troponin compared to conventional troponin among patients presenting with undifferentiated chest pain: A trial based analysis. Int J Cardiol. Jul 1 2017;238:144–150. doi:10.1016/j.ijcard.2017.02.141. No outcomes within 6 weeks reported.28325612
148 Kaier TE, Twerenbold R, Lopez-Ayala P, . A 0/1h-algorithm using cardiac myosin-binding protein C for early diagnosis of myocardial infarction. Eur Heart J Acute Cardiovasc Care. Jun 7 2022;11(4):325–335. doi:10.1093/ehjacc/zuac007. Not high-sensitivity Tn.35149868
149 Kang T, Kim GS, Byun YS, . An Algorithmic Approach Is Superior to the 99th Percentile Upper Reference Limits of High Sensitivity Troponin as a Threshold for Safe Discharge from the Emergency Department. Medicina (Kaunas). Oct 12 2021;57(10)doi:10.3390/medicina57101083. No outcomes within 6 weeks reported.
150 Kankra M, Mehta A, Sawhney J, . Improving the ACS Triage—Using High Sensitivity TroponinI and Copeptin for Early ‘Rule-Out’of AMI. Indian Journal of Clinical Biochemistry. 2022:1–9. Combination with other lab (only).
151 Karakas M, Januzzi JL, Jr., Meyer J, . Copeptin does not add diagnostic information to high-sensitivity troponin T in low- to intermediate-risk patients with acute chest pain: results from the rule out myocardial infarction by computed tomography (ROMICAT) study. Clin Chem. Aug 2011;57(8):1137–45. doi:10.1373/clinchem.2010.160192. Combination with other lab (only).21673277
152 Kavsak PA, Cerasuolo JO, Mondoux SE, . Risk Stratification for Patients with Chest Pain Discharged Home from the Emergency Department. J Clin Med. Sep 12 2020;9(9)doi:10.3390/jcm9092948. No defined ADP.
153 Kavsak PA, Hewitt MK, Mondoux SE, . Diagnostic Performance of Serial High-Sensitivity Cardiac Troponin Measurements in the Emergency Setting. J Cardiovasc Dev Dis. Aug 13 2021;8(8)doi:10.3390/jcdd8080097. Not prospective.
154 Kavsak PA, Mondoux SE, Ma J, . Comparison of two biomarker only algorithms for early risk stratification in patients with suspected acute coronary syndrome. Int J Cardiol. Nov 15 2020;319:140–143. doi:10.1016/j.ijcard.2020.06.066. Neither primary study nor SR.32634494
155 Kavsak PA, Mondoux SE, Sherbino J, . Clinical evaluation of Ortho Clinical Diagnostics high-sensitivity cardiac Troponin I assay in patients with symptoms suggestive of acute coronary syndrome. Clin Biochem. Jun 2020;80:48–51. doi:10.1016/j.clinbiochem.2020.04.003. Neither primary study nor SR.32304695
156 Kelly A-M. What is the incidence of major adverse cardiac events in emergency department chest pain patients with a normal ECG, Thrombolysis in Myocardial Infarction score of zero and initial troponin≤ 99th centile: an observational study? Emergency Medicine Journal. 2013;30(1):15–18. Not high-sensitivity Tn.22328637
157 Kelly AM. Performance of a sensitive troponin assay in the early diagnosis of acute myocardial infarction in the emergency department. Emerg Med Australas. Apr 2011;23(2):181–5. doi:10.1111/j.1742-6723.2011.01388.x. Not high-sensitivity Tn.21489165
158 Khan A, Engineer R, Wang S, Jaber WA, Menon V, Cremer PC. Initial experience regarding the safety and yield of rest-stress myocardial perfusion imaging in emergency department patients with mildly abnormal high-sensitivity cardiac troponins. J Nucl Cardiol. Dec 2021;28(6):2941–2948. doi:10.1007/s12350-020-02145-w. This study about MPI safety and not ADP performance/efficacy, not population of interest or outcomes (assessed adverse events attributable to stress testing).32557148
159 Khan DA, Sharif MS, Khan FA. Diagnostic performance of high-sensitivity troponin T, myeloperoxidase, and pregnancy-associated plasma protein A assays for triage of patients with acute myocardial infarction. Korean J Lab Med. Jul 2011;31(3):172–8. doi:10.3343/kjlm.2011.31.3.172. No defined ADP.21779191
160 Khan E, Lambrakis K, Blyth A, . Classification performance of clinical risk scoring in suspected acute coronary syndrome beyond a rule-out troponin profile. Eur Heart J Acute Cardiovasc Care. Dec 6 2021;10(9):1038–1047. doi:10.1093/ehjacc/zuab040. Not prospective.34195809
161 Khand A, Frost F, Grainger R, . Identification of high-risk non-ST elevation myocardial infarction at presentation to emergency department. A prospective observational cohort study in North West England. BMJ Open. Jun 8 2020;10(6):e030128. doi:10.1136/bmjopen-2019-030128. Not prospective.
162 Khoshnood A, Erlandsson M, Isma N, Yndigegn T, Mokhtari A. Diagnostic accuracy of troponin T measured ≥6h after symptom onset for ruling out myocardial infarction. Scand Cardiovasc J. Jun 2020;54(3):153–161. doi:10.1080/14017431.2019.1699248. Not prospective.31814475
163 Kienbacher CL, Fuhrmann V, van Tulder R, . Impact of more conservative European Society of Cardiology guidelines on the management of patients with acute chest pain. Int J Clin Pract. Jun 2021;75(6):e14133. doi:10.1111/ijcp.14133. No outcomes within 6 weeks reported.33683805
164 Kim JW, Kim H, Yun YM, Lee KR, Kim HJ. Absolute Change in High-Sensitivity Cardiac Troponin I at Three Hours After Presentation is Useful for Diagnosing Acute Myocardial Infarction in the Emergency Department. Ann Lab Med. Nov 2020;40(6):474–480. doi:10.3343/alm.2020.40.6.474. No outcomes within 6 weeks reported.32539303
165 Kim KS, Suh GJ, Song SH, . Copeptin with high-sensitivity troponin at presentation is not inferior to serial troponin measurements for ruling out acute myocardial infarction. Clin Exp Emerg Med. Mar 2020;7(1):35–42. doi:10.15441/ceem.19.013. No outcomes within 6 weeks reported.32252132
166 King G, Nicholls GM, Jones P. Impact of a decision rule on duration of continuous cardiac monitoring of patients with suspected acute coronary syndrome in an emergency department. Intern Med J. Oct 2013;43(10):1088–95. doi:10.1111/imj.12250. No defined ADP.23869547
167 Koechlin L, Boeddinghaus J, Nestelberger T, . Lower diagnostic accuracy of hs-cTnI in patients with prior coronary artery bypass grafting. Int J Cardiol. May 1 2022;354:1–6. doi:10.1016/j.ijcard.2022.02.025. Not prospective.35189168
168 Koechlin L, Boeddinghaus J, Nestelberger T, . Performance of the ESC 0/2h-algorithm using high-sensitivity cardiac troponin I in the early diagnosis of myocardial infarction. Am Heart J. Dec 2021;242:132–137. doi:10.1016/j.ahj.2021.08.008. Not prospective.34508692
169 Koper LH, Frenk LDS, Meeder JG, . URGENT 1.5: diagnostic accuracy of the modified HEART score, with fingerstick point-of-care troponin testing, in ruling out acute coronary syndrome. Neth Heart J. Nov 24 2021;doi:10.1007/s12471-021-01646-8. Not high-sensitivity Tn.
170 Lau G, Koh M, Kavsak PA, . Clinical outcomes for chest pain patients discharged home from emergency departments using high-sensitivity versus conventional cardiac troponin assays. Am Heart J. Mar 2020;221:84–94. doi:10.1016/j.ahj.2019.12.007. No defined ADP.31954328
171 Laureano-Phillips J, Robinson RD, Aryal S, . HEART Score Risk Stratification of Low-Risk Chest Pain Patients in the Emergency Department: A Systematic Review and Meta-Analysis. Ann Emerg Med. Aug 2019;74(2):187–203. doi:10.1016/j.annemergmed.2018.12.010. Not prospective.30718010
172 Lee CC, Huang SS, Yeo YH, . High-sensitivity-cardiac troponin for accelerated diagnosis of acute myocardial infarction: A systematic review and meta-analysis. Am J Emerg Med. Jul 2020;38(7):1402–1407. doi:10.1016/j.ajem.2019.11.035. Not prospective.31932131
173 Lee KK, Ferry AV, Anand A, . Sex-Specific Thresholds of High-Sensitivity Troponin in Patients With Suspected Acute Coronary Syndrome. J Am Coll Cardiol. Oct 22 2019;74(16):2032–2043. doi:10.1016/j.jacc.2019.07.082. No defined ADP.31623760
174 Leung YK, Cheng NM, Chan CP, . Early Exclusion of Major Adverse Cardiac Events in Emergency Department Chest Pain Patients: A Prospective Observational Study. J Emerg Med. Sep 2017;53(3):287–294. doi:10.1016/j.jemermed.2017.05.006. Not prospective.28992867
175 Lin Z, Lim SH, Chua SJT, Tai ES, Chan YH, Richards AM. High-sensitivity troponin T and long-term adverse cardiac events among patients presenting with suspected acute coronary syndrome in Singapore. Singapore Med J. Aug 2019;60(8):418–426. doi:10.11622/smedj.2019013. No defined ADP.30773602
176 Lindahl B, Jernberg T, Badertscher P, . An algorithm for rule-in and rule-out of acute myocardial infarction using a novel troponin I assay. Heart. Jan 15 2017;103(2):125–131. doi:10.1136/heartjnl-2016-309951. Not prospective.27486143
177 Liu T, Wang G, Li P, Dai X. Risk classification of highly sensitive troponin I predict presence of vulnerable plaque assessed by dual source coronary computed tomography angiography. Int J Cardiovasc Imaging. Nov 2017;33(11):1831–1839. doi:10.1007/s10554-017-1174-3. No defined ADP.28528430
178 Liu TY, Tsai MT, Chen FC, . Impact of coronary risk scores on disposition decision in emergency patients with chest pain. Am J Emerg Med. Oct 2021;48:165–169. doi:10.1016/j.ajem.2021.04.029. Heart score provided but no defined rules on how to rule in /out.33957340
179 Ljung L, Reichard C, Hagerman P, . Sensitivity of undetectable level of high-sensitivity troponin T at presentation in a large non-ST-segment elevation myocardial infarction cohort of early presenters. Int J Cardiol. Jun 1 2019;284:6–11. doi:10.1016/j.ijcard.2018.10.088. Not prospective.30413299
180 Lopez-Ayala P, Boeddinghaus J, Koechlin L, Nestelberger T, Mueller C. Early Rule-Out Strategies in the Emergency Department Utilizing High-Sensitivity Cardiac Troponin Assays. Clin Chem. Jan 8 2021;67(1):114–123. doi:10.1093/clinchem/hvaa226. Neither primary study nor SR.33279982
181 Lopez-Ayala P, Nestelberger T, Boeddinghaus J, . Novel Criteria for the Observe-Zone of the ESC 0/1h-hs-cTnT Algorithm. Circulation. Sep 7 2021;144(10):773–787. doi:10.1161/circulationaha.120.052982. No outcomes within 6 weeks reported.34376064
182 Lordet V, Lesbordes M, Garcia R, . Prevalence and outcome of patients referred for chest pain with high-sensitivity troponin elevation and no diagnosis at discharge. Clin Cardiol. Jul 2018;41(7):953–958. doi:10.1002/clc.22984. No defined ADP.29802723
183 Ma CP, Wang X, Wang QS, Liu XL, He XN, Nie SP. A modified HEART risk score in chest pain patients with suspected non-ST-segment elevation acute coronary syndrome. J Geriatr Cardiol. Jan 2016;13(1):64–9. doi:10.11909/j.issn.1671-5411.2016.01.013. Not prospective.26918015
184 Mahler SA, Riley RF, Russell GB, . Adherence to an Accelerated Diagnostic Protocol for Chest Pain: Secondary Analysis of the HEART Pathway Randomized Trial. Acad Emerg Med. Jan 2016;23(1):70–7. doi:10.1111/acem.12835. Not high-sensitivity Tn.26720295
185 Mahler SA, Stopyra JP, Apple FS, . Use of the HEART Pathway with high sensitivity cardiac troponins: A secondary analysis. Clin Biochem. May 2017;50(7–8):401–407. doi:10.1016/j.clinbiochem.2017.01.003. Combination with other lab (only).28087371
186 Mahmoud O, Mahmaljy H, Elias H, . A comparative 30-day outcome analysis of inpatient evaluation vs outpatient testing in patients presenting with chest pain in the high-sensitivity troponin era. A propensity score matched case-control retrospective study. Clin Cardiol. Nov 2020;43(11):1248–1254. doi:10.1002/clc.23435. No defined ADP.32748994
187 Málek J, Živný P, Vojtíšek P, Matějka J. Application of 0/1-h high sensitivity cardiac troponin algorithm in the cardiology outpatient department. Cor et Vasa. 2019;61(6):584–587. Not ED or pre-ED presentation.
188 Marcusohn E, Epstein D, Roguin A, Zukermann R. Rapid rule out for suspected myocardial infarction: is the algorithm appropriate for all? Eur Heart J Qual Care Clin Outcomes. Jul 1 2020;6(3):193–198. doi:10.1093/ehjqcco/qcaa005. Specific population.31965160
189 Marjot J, Kaier TE, Henderson K, Hunter L, Marber MS, Perera D. A single centre prospective cohort study addressing the effect of a rule-in/rule-out troponin algorithm on routine clinical practice. Eur Heart J Acute Cardiovasc Care. Aug 2019;8(5):404–411. doi:10.1177/2048872617746850. No defined ADP.29199434
190 McCord J, Aurora L, Lindahl B, . Symptoms Predictive of Acute Myocardial Infarction in the Troponin Era: Analysis From the TRAPID-AMI Study. Crit Pathw Cardiol. Mar 2019;18(1):10–15. doi:10.1097/hpc.0000000000000163. Substudy analysis of the TRAPID-AMI, no outcome of interest.30747759
191 McCord J, Cabrera R, Lindahl B, . Prognostic Utility of a Modified HEART Score in Chest Pain Patients in the Emergency Department. Circ Cardiovasc Qual Outcomes. Feb 2017;10(2)doi:10.1161/circoutcomes.116.003101. Not ED or pre-ED presentation.
192 McCord J, Hana A, Cook B, . The role of cardiac testing with the 0/1-hour high-sensitivity cardiac troponin algorithm evaluating for acute myocardial infarction. Am Heart J. Mar 2021;233:68–77. doi:10.1016/j.ahj.2020.12.015. Not prospective.33373603
193 McCord JK, Cook B, Gandolfo C, . Race-it-rapid myocardial infarction exclusion using an accelerated high-sensitivity cardiac troponin I protocol: a prospective trail. Journal of the American College of Cardiology. 2022;79(9_Supplement):951–951. Abstract, no PDF.35272799
194 McRae A, Graham M, Abedin T, . Sex-specific, high-sensitivity cardiac troponin T cut-off concentrations for ruling out acute myocardial infarction with a single measurement. Cjem. Jan 2019;21(1):26–33. doi:10.1017/cem.2018.435. Not prospective.30261938
195 McRae AD, Andruchow JE. Highly-sensitive troponin T algorithm facilitates early discharge of low-risk chest pain patients within 1 h of emergency department arrival. Evid Based Med. Aug 2015;20(4):144. doi:10.1136/ebmed-2015-110224. Abstract, no PDF.26088057
196 McRae AD, Innes G, Graham M, . Undetectable Concentrations of a Food and Drug Administration-approved High-sensitivity Cardiac Troponin T Assay to Rule Out Acute Myocardial Infarction at Emergency Department Arrival. Acad Emerg Med. Oct 2017;24(10):1267–1277. doi:10.1111/acem.13229. No defined ADP.28544100
197 McRae AD, Innes G, Graham M, . Comparative Evaluation of 2-Hour Rapid Diagnostic Algorithms for Acute Myocardial Infarction Using High-Sensitivity Cardiac Troponin T. Can J Cardiol. Aug 2017;33(8):1006–1012. doi:10.1016/j.cjca.2017.04.010. Not prospective.28669701
198 Meller B, Cullen L, Parsonage WA, . Accelerated diagnostic protocol using high-sensitivity cardiac troponin T in acute chest pain patients. Int J Cardiol. Apr 1 2015;184:208–215. doi:10.1016/j.ijcard.2015.02.006. Not prospective.25710784
199 Meune C, Reichlin T, Irfan A, . How safe is the outpatient management of patients with acute chest pain and mildly increased cardiac troponin concentrations? Clin Chem. May 2012;58(5):916–24. doi:10.1373/clinchem.2011.178053. No defined ADP.22410086
200 Miller J, Cook B, Singh-Kucukarslan G, . RACE-IT - Rapid Acute Coronary Syndrome Exclusion using the Beckman Coulter Access high-sensitivity cardiac troponin I: A stepped-wedge cluster randomized trial. Contemp Clin Trials Commun. Jun 2021;22:100773. doi:10.1016/j.conctc.2021.100773. Protocol and no trial outcome paper found.34013092
201 Miller-Hodges E, Anand A, Shah ASV, . High-Sensitivity Cardiac Troponin and the Risk Stratification of Patients With Renal Impairment Presenting With Suspected Acute Coronary Syndrome. Circulation. Jan 30 2018;137(5):425–435. doi:10.1161/circulationaha.117.030320. No defined ADP.28978551
202 Möckel M, Searle J, Hamm C, . Early discharge using single cardiac troponin and copeptin testing in patients with suspected acute coronary syndrome (ACS): a randomized, controlled clinical process study. Eur Heart J. Feb 7 2015;36(6):369–76. doi:10.1093/eurheartj/ehu178. Not prospective.24786301
203 Mohsen M, Shawky A. The diagnostic utility of High-Sensitivity Cardiac Troponin T in acute coronary syndrome. The Egyptian Heart Journal. 2016;68(1):1–9. No defined ADP.
204 Mokhtari A, Borna C, Gilje P, . A 1-h Combination Algorithm Allows Fast Rule-Out and Rule-In of Major Adverse Cardiac Events. J Am Coll Cardiol. Apr 5 2016;67(13):1531–1540. doi:10.1016/j.jacc.2016.01.059. ADP not prospective.27150684
205 Mokhtari A, Khoshnood A, Lundager Forberg J, . Effectiveness and Safety of the European Society of Cardiology 0-/1-h Troponin Rule-Out Protocol: The Design of the ESC-TROP Multicenter Implementation Study. Cardiology. 2020;145(11):685–692. doi:10.1159/000509390. Study design, no outcomes.32818945
206 Mokhtari A, Lindahl B, Schiopu A, . A 0-Hour/1-Hour Protocol for Safe, Early Discharge of Chest Pain Patients. Acad Emerg Med. Aug 2017;24(8):983–992. doi:10.1111/acem.13224. ADP not prospective.28500753
207 Mokhtari A, Lindahl B, Smith JG, Holzmann MJ, Khoshnood A, Ekelund U. Diagnostic Accuracy of High-Sensitivity Cardiac Troponin T at Presentation Combined With History and ECG for Ruling Out Major Adverse Cardiac Events. Ann Emerg Med. Dec 2016;68(6):649–658.e3. doi:10.1016/j.annemergmed.2016.06.008. ADP not prospective.27471140
208 Morawiec B, Przywara-Chowaniec B, Muzyk P, . Combined Use of High-Sensitive Cardiac Troponin, Copeptin, and the Modified HEART Score for Rapid Evaluation of Chest Pain Patients. Dis Markers. 2018;2018:9136971. doi:10.1155/2018/9136971. Standard care is based on esc but paper does not report those results and instead reports non prospective ADP.30538785
209 Mueller C, Giannitsis E, Christ M, . Multicenter Evaluation of a 0-Hour/1-Hour Algorithm in the Diagnosis of Myocardial Infarction With High-Sensitivity Cardiac Troponin T. Ann Emerg Med. Jul 2016;68(1):76–87.e4. doi:10.1016/j.annemergmed.2015.11.013. Not prospective.26794254
210 Mueller M, Biener M, Vafaie M, . Absolute and relative kinetic changes of high-sensitivity cardiac troponin T in acute coronary syndrome and in patients with increased troponin in the absence of acute coronary syndrome. Clin Chem. Jan 2012;58(1):209–18. doi:10.1373/clinchem.2011.171827. No defined ADP.22134520
211 Mueller T, Egger M, Peer E, Jani E, Dieplinger B. Evaluation of sex-specific cut-off values of high-sensitivity cardiac troponin I and T assays in an emergency department setting–results from the Linz Troponin (LITROP) study. Clinica Chimica Acta. 2018;487:66–74. No defined ADP.
212 Mueller-Hennessen M, Lindahl B, Giannitsis E, . Diagnostic and prognostic implications using age- and gender-specific cut-offs for high-sensitivity cardiac troponin T - Sub-analysis from the TRAPID-AMI study. Int J Cardiol. Apr 15 2016;209:26–33. doi:10.1016/j.ijcard.2016.01.213. No defined ADP.26878470
213 Mueller-Hennessen M, Lindahl B, Giannitsis E, . Combined testing of copeptin and high-sensitivity cardiac troponin T at baseline in comparison to other algorithms for rule-out of acute myocardial infarction. European Heart Journal. 2017;38(suppl_1). Abstract, no PDF.
214 Mueller-Hennessen M, Lindahl B, Giannitsis E, . Combined testing of copeptin and high-sensitivity cardiac troponin T at presentation in comparison to other algorithms for rapid rule-out of acute myocardial infarction. Int J Cardiol. Feb 1 2019;276:261–267. doi:10.1016/j.ijcard.2018.10.084. Not Prospective.30404726
215 Mueller-Hennessen M, Mueller C, Giannitsis E, . Serial Sampling of High-Sensitivity Cardiac Troponin T May Not Be Required for Prediction of Acute Myocardial Infarction Diagnosis in Chest Pain Patients with Highly Abnormal Concentrations at Presentation. Clin Chem. Feb 2017;63(2):542–551. doi:10.1373/clinchem.2016.258392. Not prospective.27932414
216 Mumma BE, Casey SD, Dang RK, . Diagnostic Reclassification by a High-Sensitivity Cardiac Troponin Assay. Ann Emerg Med. Nov 2020;76(5):566–579. doi:10.1016/j.annemergmed.2020.06.047. No defined ADP.32807538
217 Mungai E, Hamilton BK, Burns D. Comparison of High-Sensitivity Troponin T Assay to Conventional Troponin T Assay for Rule Out of Acute Coronary Syndrome in the Emergency Department. Adv Emerg Nurs J. Oct/Dec 2020;42(4):304–314. doi:10.1097/tme.0000000000000324. No defined ADP.33105185
218 Musey PI, Jr., Bellolio F, Upadhye S, . Guidelines for reasonable and appropriate care in the emergency department (GRACE): Recurrent, low-risk chest pain in the emergency department. Acad Emerg Med. Jul 2021;28(7):718–744. doi:10.1111/acem.14296. Not primary study.34228849
219 Nejatian A, Omstedt Å, Höijer J, . Outcomes in Patients With Chest Pain Discharged After Evaluation Using a High-Sensitivity Troponin T Assay. J Am Coll Cardiol. May 30 2017;69(21):2622–2630. doi:10.1016/j.jacc.2017.03.586. No defined ADP.28545635
220 Nestelberger T, Boeddinghaus J, Greenslade J, . Two-Hour Algorithm for Rapid Triage of Suspected Acute Myocardial Infarction Using a High-Sensitivity Cardiac Troponin I Assay. Clin Chem. Nov 2019;65(11):1437–1447. doi:10.1373/clinchem.2019.305193. Not prospective.31570634
221 Nestelberger T, Boeddinghaus J, Wussler D, . Predicting Major Adverse Events in Patients With Acute Myocardial Infarction. J Am Coll Cardiol. Aug 20 2019;74(7):842–854. doi:10.1016/j.jacc.2019.06.025. Not prospective.31416527
222 Nestelberger T, Cullen L, Lindahl B, . Diagnosis of acute myocardial infarction in the presence of left bundle branch block. Heart. Oct 2019;105(20):1559–1567. doi:10.1136/heartjnl-2018-314673. Not prospective.31142594
223 Nestelberger T, Lopez-Ayala P, Boeddinghaus J, . External Validation and Extension of a Clinical Score for the Discrimination of Type 2 Myocardial Infarction. J Clin Med. Mar 18 2021;10(6)doi:10.3390/jcm10061264. Not prospective.
224 Nestelberger T, Wildi K, Boeddinghaus J, . Characterization of the observe zone of the ESC 2015 high-sensitivity cardiac troponin 0h/1h-algorithm for the early diagnosis of acute myocardial infarction. Int J Cardiol. Mar 15 2016;207:238–45. doi:10.1016/j.ijcard.2016.01.112. Not prospective.26808985
225 Neumann JT, Sörensen NA, Ojeda F, . Early diagnosis of acute myocardial infarction using high-sensitivity troponin I. PLoS One. 2017;12(3):e0174288. doi:10.1371/journal.pone.0174288. Standard of care is esc but research team applied rules of esc and manipulated to determine a better ADP.28333976
226 Neumann JT, Sörensen NA, Ojeda F, . Immediate Rule-Out of Acute Myocardial Infarction Using Electrocardiogram and Baseline High-Sensitivity Troponin I. Clin Chem. Jan 2017;63(1):394–402. doi:10.1373/clinchem.2016.262659. Standard of care is esc but research team applied rules of esc and manipulated to determine a better ADP.27903616
227 Neumann JT, Sörensen NA, Schwemer T, . Diagnosis of Myocardial Infarction Using a High-Sensitivity Troponin I 1-Hour Algorithm. JAMA Cardiol. Jul 1 2016;1(4):397–404. doi:10.1001/jamacardio.2016.0695. Not prospective.27438315
228 Neumann JT, Twerenbold R, Ojeda F, . Application of High-Sensitivity Troponin in Suspected Myocardial Infarction. N Engl J Med. Jun 27 2019;380(26):2529–2540. doi:10.1056/NEJMoa1803377. No defined ADP.31242362
229 Ng M, Tan HJG, Gao F, . Comparative prospective study of the performance of chest pain scores and clinical assessment in an emergency department cohort in Singapore. J Am Coll Emerg Physicians Open. Oct 2020;1(5):723–729. doi:10.1002/emp2.12242. Not prospective.33145512
230 Nilsson T, Johannesson E, Lundager Forberg J, Mokhtari A, Ekelund U. Diagnostic accuracy of the HEART Pathway and EDACS-ADP when combined with a 0-hour/1-hour hs-cTnT protocol for assessment of acute chest pain patients. Emerg Med J. Nov 2021;38(11):808–813. doi:10.1136/emermed-2020-210833. Not prospective.33837120
231 Nowak R, Mueller C, Giannitsis E, . High sensitivity cardiac troponin T in patients not having an acute coronary syndrome: results from the TRAPID-AMI study. Biomarkers. Dec 2017;22(8):709–714. doi:10.1080/1354750x.2017.1334154. Describes final non-ACS diagnoses of patients without ACS.28532247
232 Nowak RM, Christenson RH, Jacobsen G, . Performance of Novel High-Sensitivity Cardiac Troponin I Assays for 0/1-Hour and 0/2- to 3-Hour Evaluations for Acute Myocardial Infarction: Results From the HIGH-US Study. Ann Emerg Med. Jul 2020;76(1):1–13. doi:10.1016/j.annemergmed.2019.12.008. Not prospective.32046869
233 Nowak RM, Jacobsen G, Limkakeng A, Jr., . Outpatient versus observation/inpatient management of emergency department patients rapidly ruled-out for acute myocardial infarction: Findings from the HIGH-US study. Am Heart J. Jan 2021;231:6–17. doi:10.1016/j.ahj.2020.10.067. Not prospective.33127532
234 Ola O, Akula A, De Michieli L, . Clinical Impact of High-Sensitivity Cardiac Troponin T Implementation in the Community. J Am Coll Cardiol. Jun 29 2021;77(25):3160–3170. doi:10.1016/j.jacc.2021.04.050. Abstract, no PDF.34167641
235 Olsson P, Khoshnood A, Mokhtari A, Ekelund U. Glucose and high-sensitivity troponin T predict a low risk of major adverse cardiac events in emergency department chest pain patients. Scand Cardiovasc J. Dec 2021;55(6):354–361. doi:10.1080/14017431.2021.1987512. Not prospective.34617492
236 Pang PS, Fermann GJ, Hunter BR, . TACIT (High Sensitivity Troponin T Rules Out Acute Cardiac Insufficiency Trial) An Observational Study to Identify Acute Heart Failure Patients at Low Risk for Rehospitalization or Mortality. Circulation: Heart Failure. 2019;12(7):e005931. Not non-STEMI ACS.31288565
237 Paoloni R, Kumar P, Janu M. Pilot study of high-sensitivity troponin T testing to facilitate safe early disposition decisions in patients presenting to the emergency department with chest pain. Intern Med J. Mar 2010;40(3):188–92. doi:10.1111/j.1445-5994.2009.01962.x. Not non-STEMI ACS.19323696
238 Papendick C, Blyth A, Seshadri A, . A randomized trial of a 1-hour troponin T protocol in suspected acute coronary syndromes: Design of the Rapid Assessment of Possible ACS In the emergency Department with high sensitivity Troponin T (RAPID-TnT) study. Am Heart J. Aug 2017;190:25–33. doi:10.1016/j.ahj.2017.05.004. Not published/peer reviewed.28760210
239 Parsonage WA, Greenslade JH, Hammett CJ, . Validation of an accelerated high-sensitivity troponin T assay protocol in an Australian cohort with chest pain. Med J Aust. Feb 17 2014;200(3):161–5. doi:10.5694/mja13.10466. Not non-STEMI ACS.24528432
240 Parsonage WA, Mueller C, Greenslade JH, . Validation of NICE diagnostic guidance for rule out of myocardial infarction using high-sensitivity troponin tests. Heart. Aug 15 2016;102(16):1279–86. doi:10.1136/heartjnl-2016-309270. Not non-STEMI ACS.27288278
241 Pavlovsky T, Obadia M, Ragot S, Douay B, Casalino E, Ghazali DA. Predictors of Risk Stratification and Value of Point-of-Care of High-Sensitivity Cardiac Troponin-I in EMS Management of Non-ST-Segment Elevation Myocardial Infarction: A Retrospective Study. Prehosp Disaster Med. Jun 2022;37(3):365–372. doi:10.1017/s1049023x22000681. Not prospective.35477838
242 Peacock WF, Baumann BM, Bruton D, . Efficacy of High-Sensitivity Troponin T in Identifying Very-Low-Risk Patients With Possible Acute Coronary Syndrome. JAMA Cardiol. Feb 1 2018;3(2):104–111. doi:10.1001/jamacardio.2017.4625. Not prospective.29238804
243 Peacock WF, Christenson R, Diercks DB, . Myocardial Infarction Can Be Safely Excluded by High-sensitivity Troponin I Testing 3 Hours After Emergency Department Presentation. Acad Emerg Med. Aug 2020;27(8):671–680. doi:10.1111/acem.13922. No defined ADP.32220124
244 Peck D, Knott J, Lefkovits J. Clinical impact of a high-sensitivity troponin assay introduction on patients presenting to the emergency department. Emerg Med Australas. Jun 2016;28(3):273–8. doi:10.1111/1742-6723.12566. No defined ADP.26989877
245 Pedersen CK, Stengard C, Boetker MT, Soendergaard HM, Dodt KK, Terkelsen CJ. Copeptin and troponin for rule-out of AMI reduces length of stay (the AROMI study) 2018; https://academic.oup.com/ehjacc/article/7/1_suppl/4/5922359 by New York University user on 21 July 2022. Abstract of AROMI study.
246 Pettersson A, Ljung L, Johansson C, . Experiences of a One-hour Algorithm in Chest Pain Patients With a Nonelevated Troponin T at Presentation. Crit Pathw Cardiol. Mar 2018;17(1):6–12. doi:10.1097/hpc.0000000000000138. Not prospective.29432370
247 Pickering JW, Flaws D, Smith SW, . A Risk Assessment Score and Initial High-sensitivity Troponin Combine to Identify Low Risk of Acute Myocardial Infarction in the Emergency Department. Acad Emerg Med. Apr 2018;25(4):434–443. doi:10.1111/acem.13343. Not prospective.29131477
248 Pickering JW, Greenslade JH, Cullen L, . Assessment of the European Society of Cardiology 0-Hour/1-Hour Algorithm to Rule-Out and Rule-In Acute Myocardial Infarction. Circulation. Nov 15 2016;134(20):1532–1541. doi:10.1161/circulationaha.116.022677. Not prospective.27754881
249 Pickering JW, Greenslade JH, Cullen L, . Validation of presentation and 3 h high-sensitivity troponin to rule-in and rule-out acute myocardial infarction. Heart. Aug 15 2016;102(16):1270–8. doi:10.1136/heartjnl-2015-308505. Not prospective.26955848
250 Pickering JW, Than MP, Cullen L, . Rapid Rule-out of Acute Myocardial Infarction With a Single High-Sensitivity Cardiac Troponin T Measurement Below the Limit of Detection: A Collaborative Meta-analysis. Ann Intern Med. May 16 2017;166(10):715–724. doi:10.7326/m16-2562. Systematic Review.28418520
251 Pickering JW, Young JM, George P, . The utility of presentation and 4-hour high sensitivity troponin I to rule-out acute myocardial infarction in the emergency department. Clin Biochem. Dec 2015;48(18):1219–24. doi:10.1016/j.clinbiochem.2015.07.033. Not prospective.26232285
252 Poldervaart JM, Reitsma JB, Backus BE, . Effect of Using the HEART Score in Patients With Chest Pain in the Emergency Department: A Stepped-Wedge, Cluster Randomized Trial. Ann Intern Med. May 16 2017;166(10):689–697. doi:10.7326/m16-1600. Not high-sensitivity Tn.28437795
253 Pongas D, Dupouy P, Daoud B, . Acute chest pain and cardiac computed tomography. Sang Thrombose Vaisseaux. 2016;28(3):119–131. Neither primary study nor SR.
254 Potocki M, Reichlin T, Thalmann S, . Diagnostic and prognostic impact of copeptin and high-sensitivity cardiac troponin T in patients with pre-existing coronary artery disease and suspected acute myocardial infarction. Heart. 2012;98(7):558–565. Not prospective.22337952
255 Puelacher C, Gugala M, Adamson PD, . Incidence and outcomes of unstable angina compared with non-ST-elevation myocardial infarction. Heart. Sep 2019;105(18):1423–1431. doi:10.1136/heartjnl-2018-314305. No defined ADP.31018955
256 Rainer TH, Ahuja AT, Graham CA, Yan BP, Wong JK, Chan CP. Improving early risk stratification in patients presenting to emergency department with suspected acute coronary syndrome. Hong Kong Med J. Feb 2018;24 Suppl 2(1):24–29. Not prospective.
257 Rainer TH, Leung YK, Lee A, . Add-on tests for improving risk-stratification in emergency department patients with chest pain who are at low to moderate risk of 30-day major adverse cardiac events. Int J Cardiol. Oct 1 2016;220:299–306. doi:10.1016/j.ijcard.2016.05.057. Not prospective.27390945
258 Ramezani F, Ahmadi S, Faridaalee G, Baratloo A, Yousefifard M. Value of Manchester Acute Coronary Syndromes Decision Rule in the Detection of Acute Coronary Syndrome; a Systematic Review and Meta-Analysis. Emerg (Tehran). 2018;6(1):e61. Systematic Review.30788388
259 Ras M, Reitsma JB, Hoes AW, Six AJ, Poldervaart JM. Value of Repeated Troponin Measurements to Improve the Safety of the HEART Score for Chest Pain Patients at the Emergency Department. Crit Pathw Cardiol. Jun 2020;19(2):62–68. doi:10.1097/hpc.0000000000000213. Not high-sensitivity Tn.32053520
260 Rasmussen MB, Stengaard C, Sørensen JT, . Predictive value of routine point-of-care cardiac troponin T measurement for prehospital diagnosis and risk-stratification in patients with suspected acute myocardial infarction. Eur Heart J Acute Cardiovasc Care. Jun 2019;8(4):299–308. doi:10.1177/2048872617745893. Not high-sensitivity Tn.29199427
261 Ratmann PD, Boeddinghaus J, Nestelberger T, . External Validation of the No Objective Testing Rules in Acute Chest Pain. J Am Heart Assoc. May 18 2021;10(10):e020031. doi:10.1161/jaha.120.020031. Not prospective.33977760
262 Reichlin T, Cullen L, Parsonage WA, . Two-hour algorithm for triage toward rule-out and rule-in of acute myocardial infarction using high-sensitivity cardiac troponin T. Am J Med. Apr 2015;128(4):369–79.e4. doi:10.1016/j.amjmed.2014.10.032. Not prospective.25446294
263 Reichlin T, Schindler C, Drexler B, . One-hour rule-out and rule-in of acute myocardial infarction using high-sensitivity cardiac troponin T. Arch Intern Med. Sep 10 2012;172(16):1211–8. doi:10.1001/archinternmed.2012.3698. Not prospective.22892889
264 Reichlin T, Twerenbold R, Maushart C, . Risk stratification in patients with unstable angina using absolute serial changes of 3 high-sensitive troponin assays. Am Heart J. Mar 2013;165(3):371–8.e3. doi:10.1016/j.ahj.2012.11.010. No defined ADP.23453106
265 Reichlin T, Twerenbold R, Wildi K, . Prospective validation of a 1-hour algorithm to rule-out and rule-in acute myocardial infarction using a high-sensitivity cardiac troponin T assay. Cmaj. May 19 2015;187(8):E243–e252. doi:10.1503/cmaj.141349. Not prospective.25869867
266 Restan IZ, Sanchez AY, Steiro OT, . Adding stress biomarkers to high-sensitivity cardiac troponin for rapid non-ST-elevation myocardial infarction rule-out protocols. Eur Heart J Acute Cardiovasc Care. Mar 16 2022;11(3):201–212. doi:10.1093/ehjacc/zuab124. Not prospective.35024819
267 Reynard C, Ismail H, Hadden N. BET 1: Can the Manchester Acute Coronary Syndromes and Troponin-only Manchester Acute Coronary Syndromes decision aids rule out acute coronary syndromes in the emergency department? Emerg Med J. Dec 2017;34(12):852–854. doi:10.1136/emermed-2017-207286.1. Systematic Review.29170295
268 Richards G, Sen G, Halliday A, . Reducing chest pain admissions using a 1 hour high-sensitivity troponin-t pathway. Heart. 2017;103(Suppl 5):A50–A51. Not published/peer reviewed.
269 Riedlinger D, Möckel M, Müller C, . High-sensitivity cardiac troponin T for diagnosis of NSTEMI in the elderly emergency department patient: a clinical cohort study. Biomarkers. Sep 2018;23(6):551–557. doi:10.1080/1354750x.2018.1460763. No defined ADP.29619842
270 Roongsritong C, Taha ME, Pisipati S, . SVEAT Score, a Potential New and Improved Tool for Acute Chest Pain Risk Stratification. Am J Cardiol. Jul 15 2020;127:36–40. doi:10.1016/j.amjcard.2020.04.009. No defined ADP.32418720
271 Roos A, Holzmann MJ. Use of historical high-sensitivity cardiac troponin T levels to rule out myocardial infarction. Open Heart. May 2021;8(1)doi:10.1136/openhrt-2021-001682. Not prospective.
272 Röttger E, de Vries-Spithoven S, Reitsma JB, . Safety of a 1-hour Rule-out High-sensitive Troponin T Protocol in Patients With Chest Pain at the Emergency Department. Crit Pathw Cardiol. Dec 2017;16(4):129–134. doi:10.1097/hpc.0000000000000135. No defined ADP.29135620
273 Ruangsomboon O, Mekavuthikul P, Chakorn T, . The feasibility of the 1-h high-sensitivity cardiac troponin T algorithm to rule-in and rule-out acute myocardial infarction in Thai emergency patients: an observational study. Int J Emerg Med. Oct 22 2018;11(1):43. doi:10.1186/s12245-018-0204-9. No defined ADP.31179940
274 Ruangsomboon O, Thirawattanasoot N, Chakorn T, . The utility of the 1-hour high-sensitivity cardiac troponin T algorithm compared with and combined with five early rule-out scores in high-acuity chest pain emergency patients. Int J Cardiol. Jan 1 2021;322:23–28. doi:10.1016/j.ijcard.2020.08.099. Not prospective.32882291
275 Rubini Gimenez M, Badertscher P, Twerenbold R, . Impact of the US Food and Drug Administration-Approved Sex-Specific Cutoff Values for High-Sensitivity Cardiac Troponin T to Diagnose Myocardial Infarction. Circulation. Apr 24 2018;137(17):1867–1869. doi:10.1161/circulationaha.117.031940. No defined ADP.29685935
276 Rubini Giménez M, Hoeller R, Reichlin T, . Rapid rule out of acute myocardial infarction using undetectable levels of high-sensitivity cardiac troponin. Int J Cardiol. Oct 9 2013;168(4):3896–901. doi:10.1016/j.ijcard.2013.06.049. No defined ADP.23876467
277 Rubini Giménez M, Twerenbold R, Boeddinghaus J, . Clinical Effect of Sex-Specific Cutoff Values of High-Sensitivity Cardiac Troponin T in Suspected Myocardial Infarction. JAMA Cardiol. Nov 1 2016;1(8):912–920. doi:10.1001/jamacardio.2016.2882. No defined ADP.27653005
278 Rubini Gimenez M, Twerenbold R, Reichlin T, . Direct comparison of high-sensitivity-cardiac troponin I vs. T for the early diagnosis of acute myocardial infarction. Eur Heart J. Sep 7 2014;35(34):2303–11. doi:10.1093/eurheartj/ehu188. No defined ADP.24842285
279 Rubini Giménez M, Wildi K, Wussler D, . Early kinetics of cardiac troponin in suspected acute myocardial infarction. Rev Esp Cardiol (Engl Ed). Jun 2021;74(6):502–509. doi:10.1016/j.rec.2020.04.008. No defined ADP.32451223
280 Sajeed SM, De Dios MP, Ong DWJ, Punyadasa AC. Performance of the modified HEART score in an Asian population. Int J Emerg Med. Aug 19 2020;13(1):43. doi:10.1186/s12245-020-00300-1. Not prospective.32814557
281 Sajeev JK, New G, Roberts L, . High sensitivity troponin: Does the 50% delta change alter clinical outcomes in chest pain presentations to the emergency room? Int J Cardiol. Apr 1 2015;184:170–174. doi:10.1016/j.ijcard.2015.01.074. No defined ADP.25705009
282 Sanchis J, Abellán L, García-Blas S, . Usefulness of delta troponin for diagnosis and prognosis assessment of non-ST-segment elevation acute chest pain. Eur Heart J Acute Cardiovasc Care. Sep 2016;5(5):399–406. doi:10.1177/2048872615593534. No defined ADP.
283 Sanchis J, García-Blas S, Carratalá A, . Clinical Evaluation Versus Undetectable High-Sensitivity Troponin for Assessment of Patients With Acute Chest Pain. Am J Cardiol. Dec 1 2016;118(11):1631–1635. doi:10.1016/j.amjcard.2016.08.040. No defined ADP.27665208
284 Sanchis J, García-Blas S, Mainar L, . High-sensitivity versus conventional troponin for management and prognosis assessment of patients with acute chest pain. Heart. Oct 2014;100(20):1591–6. doi:10.1136/heartjnl-2013-305440. No defined ADP.24947318
285 Sanchis J, Valero E, García Blas S, . Undetectable high-sensitivity troponin in combination with clinical assessment for risk stratification of patients with chest pain and normal troponin at hospital arrival. Eur Heart J Acute Cardiovasc Care. Sep 2020;9(6):567–575. doi:10.1177/2048872620907539. No outcomes within 6 weeks reported.32067483
286 Sandoval Y, Lewis BR, Mehta RA, . Rapid Exclusion of Acute Myocardial Injury and Infarction With a Single High-Sensitivity Cardiac Troponin T in the Emergency Department: A Multicenter United States Evaluation. Circulation. Jun 7 2022;145(23):1708–1719. doi:10.1161/circulationaha.122.059235. No defined ADP.35535607
287 Sandoval Y, Smith SW, Love SA, Sexter A, Schulz K, Apple FS. Single High-Sensitivity Cardiac Troponin I to Rule Out Acute Myocardial Infarction. Am J Med. Sep 2017;130(9):1076–1083.e1. doi:10.1016/j.amjmed.2017.02.032. No defined ADP.28344141
288 Sandoval Y, Smith SW, Schulz K, Sexter A, Apple FS. Comparison of 0/3-Hour Rapid Rule-Out Strategies Using High-Sensitivity Cardiac Troponin I in a US Emergency Department. Circ Cardiovasc Qual Outcomes. Jul 2020;13(7):e006565. doi:10.1161/circoutcomes.120.006565. No defined ADP.32552062
289 Sandoval Y, Smith SW, Shah AS, . Rapid Rule-Out of Acute Myocardial Injury Using a Single High-Sensitivity Cardiac Troponin I Measurement. Clin Chem. Jan 2017;63(1):369–376. doi:10.1373/clinchem.2016.264523. No defined ADP.27811203
290 Sandoval Y, Smith SW, Thordsen SE, . Diagnostic Performance of High Sensitivity Compared with Contemporary Cardiac Troponin I for the Diagnosis of Acute Myocardial Infarction. Clin Chem. Oct 2017;63(10):1594–1604. doi:10.1373/clinchem.2017.272930. No defined ADP.28701316
291 Santaló M, Martin A, Velilla J, . Using high-sensitivity troponin T: the importance of the proper gold standard. Am J Med. Aug 2013;126(8):709–17. doi:10.1016/j.amjmed.2013.03.003. No defined ADP.23764266
292 Santi L, Farina G, Gramenzi A, . The HEART score with high-sensitive troponin T at presentation: ruling out patients with chest pain in the emergency room. Intern Emerg Med. Apr 2017;12(3):357–364. doi:10.1007/s11739-016-1461-3. Not prospective.27178708
293 Scharnhorst V, Krasznai K, van’t Veer M, Michels R. Rapid detection of myocardial infarction with a sensitive troponin test. Am J Clin Pathol. Mar 2011;135(3):424–8. doi:10.1309/ajcpa4g8aqoyekld. No defined ADP.21350097
294 Schønemann-Lund M, Schoos MM, Iversen K, . Retrospective Evaluation of Two Fast-track Strategies to Rule Out Acute Coronary Syndrome in a Real-life Chest Pain Population. J Emerg Med. Dec 2015;49(6):833–42. doi:10.1016/j.jemermed.2015.06.026. Not ED or pre-ED presentation.26281816
295 Sedighi SM, Nguyen M, Khalil A, Fülöp T. The impact of cardiac troponin in elderly patients in the absence of acute coronary syndrome: A systematic review. Int J Cardiol Heart Vasc. Dec 2020;31:100629. doi:10.1016/j.ijcha.2020.100629. No defined ADP.32964099
296 Sepehrvand N, Zheng Y, Armstrong PW, Welsh RC, Ezekowitz JA. Identifying Low-risk Patients for Early Discharge From Emergency Department Without Using Subjective Descriptions of Chest Pain: Insights From Providing Rapid Out of Hospital Acute Cardiovascular Treatment (PROACT) 3 and 4 Trials. Acad Emerg Med. Jun 2017;24(6):691–700. doi:10.1111/acem.13183. Not high-sensitivity Tn.28261896
297 Sethi A, Bajaj A, Malhotra G, Arora RR, Khosla S. Diagnostic accuracy of sensitive or high-sensitive troponin on presentation for myocardial infarction: a meta-analysis and systematic review. Vasc Health Risk Manag. 2014;10:435–50. doi:10.2147/vhrm.S63416. No defined ADP.25092986
298 Shah AS, Anand A, Sandoval Y, . High-sensitivity cardiac troponin I at presentation in patients with suspected acute coronary syndrome: a cohort study. Lancet. Dec 19 2015;386(10012):2481–8. doi:10.1016/s0140-6736(15)00391-8. No defined ADP.26454362
299 Shah AS, Griffiths M, Lee KK, . High sensitivity cardiac troponin and the under-diagnosis of myocardial infarction in women: prospective cohort study. Bmj. Jan 21 2015;350:g7873. doi:10.1136/bmj.g7873. No defined ADP.25609052
300 Shah ASV, Anand A, Strachan FE, . High-sensitivity troponin in the evaluation of patients with suspected acute coronary syndrome: a stepped-wedge, cluster-randomised controlled trial. Lancet. Sep 15 2018;392(10151):919–928. doi:10.1016/s0140-6736(18)31923-8. No defined ADP.30170853
301 Shiozaki M, Inoue K, Suwa S, . Clinical Evaluation of a New High-Sensitivity Cardiac Troponin I Assay for Diagnosis and Risk Assessment of Patients with Suspected Acute Myocardial Infarction. Cardiology. 2021;146(2):172–178. doi:10.1159/000512185. No defined ADP.33461202
302 Shiozaki M, Inoue K, Suwa S, . Implementing the European Society of Cardiology 0-h/1-h algorithm in patients presenting very early after chest pain. Int J Cardiol. Dec 1 2020;320:1–6. doi:10.1016/j.ijcard.2020.07.037. Not prospective.32730826
303 Shiozaki M, Inoue K, Suwa S, . Utility of the 0-hour/1-hour high-sensitivity cardiac troponin T algorithm in Asian patients with suspected non-ST elevation myocardial infarction. Int J Cardiol. Dec 15 2017;249:32–35. doi:10.1016/j.ijcard.2017.09.009. Not prospective.28986063
304 Shortt C, Ma J, Clayton N, . Rule-In and Rule-Out of Myocardial Infarction Using Cardiac Troponin and Glycemic Biomarkers in Patients with Symptoms Suggestive of Acute Coronary Syndrome. Clin Chem. Jan 2017;63(1):403–414. doi:10.1373/clinchem.2016.261545. Combination with other lab (only).28062631
305 Shortt C, Xie F, Whitlock R, . Economic Considerations of Early Rule-In/Rule-Out Algorithms for The Diagnosis of Myocardial Infarction in The Emergency Department Using Cardiac Troponin and Glycemic Biomarkers. Clin Chem. Feb 2017;63(2):593–602. doi:10.1373/clinchem.2016.261776. Combination with other lab (only).27811206
306 Simpson P, Tirimacco R, Cowley P, . A comparison of cardiac troponin T delta change methods and the importance of the clinical context in the assessment of acute coronary syndrome. Annals of Clinical Biochemistry. 2019;56(6):701–707. No defined ADP.31569964
307 Smulders MW, Bekkers S, van Cauteren YJM, . Risk stratification and role for additional diagnostic testing in patients with acute chest pain and normal high-sensitivity cardiac troponin levels. PLoS One. 2018;13(9):e0203506. doi:10.1371/journal.pone.0203506. No defined ADP.30192899
308 Snavely AC, Hendley N, Stopyra JP, . Sex and race differences in safety and effectiveness of the HEART pathway accelerated diagnostic protocol for acute chest pain. Am Heart J. Feb 2021;232:125–136. doi:10.1016/j.ahj.2020.11.005. Not high-sensitivity Tn.33160945
309 Sörensen NA, Goßling A, Neumann JT, . Diagnostic Validation of a High-Sensitivity Cardiac Troponin I Assay. Clin Chem. Sep 1 2021;67(9):1230–1239. doi:10.1093/clinchem/hvab070. Not prospective.34254126
310 Sörensen NA, Ludwig S, Makarova N, . Prognostic Value of a Novel and Established High-Sensitivity Troponin I Assay in Patients Presenting with Suspected Myocardial Infarction. Biomolecules. Sep 9 2019;9(9)doi:10.3390/biom9090469. No defined ADP.
311 Sörensen NA, Neumann JT, Ojeda F, . Diagnostic Evaluation of a High-Sensitivity Troponin I Point-of-Care Assay. Clin Chem. Dec 2019;65(12):1592–1601. doi:10.1373/clinchem.2019.307405. Not prospective.31699700
312 Sörensen NA, Neumann JT, Ojeda F, . Challenging the 99th percentile: A lower troponin cutoff leads to low mortality of chest pain patients. Int J Cardiol. Apr 1 2017;232:289–293. doi:10.1016/j.ijcard.2016.12.167. Not prospective.28087181
313 Stähli BE, Yonekawa K, Altwegg LA, . Clinical criteria replenish high-sensitive troponin and inflammatory markers in the stratification of patients with suspected acute coronary syndrome. PLoS One. 2014;9(6):e98626. doi:10.1371/journal.pone.0098626. Not prospective.24892556
314 Steiro OT, Tjora HL, Langørgen J, . Clinical risk scores identify more patients at risk for cardiovascular events within 30 days as compared to standard ACS risk criteria: the WESTCOR study. Eur Heart J Acute Cardiovasc Care. May 11 2021;10(3):287–301. doi:10.1093/ehjacc/zuaa016. Not prospective.33620429
315 Stopyra JP, Riley RF, Hiestand BC, . The HEART Pathway Randomized Controlled Trial One-year Outcomes. Acad Emerg Med. Jan 2019;26(1):41–50. doi:10.1111/acem.13504. Not high-sensitivity Tn.29920834
316 Strebel I, Twerenbold R, Boeddinghaus J, . Diagnostic value of the cardiac electrical biomarker, a novel ECG marker indicating myocardial injury, in patients with symptoms suggestive of non-ST-elevation myocardial infarction. Ann Noninvasive Electrocardiol. Jul 2018;23(4):e12538. doi:10.1111/anec.12538. No defined ADP.29476571
317 Suh D, Keller DI, Hof D, von Eckardstein A, Gawinecka J. Rule-out of non-ST elevation myocardial infarction by five point of care cardiac troponin assays according to the 0 h/3 h algorithm of the European Society of Cardiology. Clin Chem Lab Med. Mar 28 2018;56(4):649–657. doi:10.1515/cclm-2017-0486. No defined ADP.29257750
318 Tada M, Azuma H, Yamada N, . A comprehensive validation of very early rule-out strategies for non-ST-segment elevation myocardial infarction in emergency departments: protocol for a multicentre prospective cohort study. BMJ Open. Sep 3 2019;9(9):e026985. doi:10.1136/bmjopen-2018-026985. Not published/peer reviewed.
319 Tan JWC, Tan HJG, Sahlen AO, . Performance of cardiac troponins within the HEART score in predicting major adverse cardiac events at the emergency department. Am J Emerg Med. Aug 2020;38(8):1560–1567. doi:10.1016/j.ajem.2019.158420. Not prospective.31493982
320 Tan WCJ, Inoue K, AbdelWareth L, . The Asia-Pacific Society of Cardiology (APSC) Expert Committee Consensus Recommendations for Assessment of Suspected Acute Coronary Syndrome Using High-Sensitivity Cardiac Troponin T in the Emergency Department. Circ J. Jan 24 2020;84(2):136–143. doi:10.1253/circj.CJ-19-0874. Neither primary study nor SR.31852863
321 Thelin J, Borna C, Erlinge D, Öhlin B. The combination of high sensitivity troponin T and copeptin facilitates early rule-out of ACS: a prospective observational study. BMC cardiovascular disorders. 2013;13(1):1–8. Not ED or pre-ED presentation.23294904
322 Thelin J, Melander O, Öhlin B. Early rule-out of acute coronary syndrome using undetectable levels of high sensitivity troponin T. Eur Heart J Acute Cardiovasc Care. Oct 2015;4(5):403–9. doi:10.1177/2048872614554107. Not ED or pre-ED presentation.25281765
323 Tjora HL, Steiro OT, Langørgen J, . Aiming toWards Evidence baSed inTerpretation of Cardiac biOmarkers in patients pResenting with chest pain-the WESTCOR study: study design. Scand Cardiovasc J. Oct 2019;53(5):280–285. doi:10.1080/14017431.2019.1634280. No defined ADP.31216908
324 Tjora HL, Steiro OT, Langørgen J, . Diagnostic Performance of Novel Troponin Algorithms for the Rule-Out of Non-ST-Elevation Acute Coronary Syndrome. Clin Chem. Feb 1 2022;68(2):291–302. doi:10.1093/clinchem/hvab225. Not prospective.34897415
325 Toh LC, Khoo C, Goh CH, . Impact of a rapid access chest pain clinic in Singapore to improve evaluation of new-onset chest pain. Postgrad Med J. Jan 31 2022;doi:10.1136/postgradmedj-2021-141427. Not ED or pre-ED presentation.
326 Torralba F, Navarro A, la Hoz JC, . HEART, TIMI, and GRACE Scores for Prediction of 30-Day Major Adverse Cardiovascular Events in the Era of High-Sensitivity Troponin. Arq Bras Cardiol. Mar 13 2020;114(5):795–802. Os Escores HEART, TIMI e GRACE para Predição de Eventos Cardiovasculares Adversos Maiores no Período de 30 Dias na Era de Troponina I de Alta Sensibilidade. doi:10.36660/abc.20190206. Not English.32187284
327 Trambas C, Pickering JW, Than M, . Impact of High-Sensitivity Troponin I Testing with Sex-Specific Cutoffs on the Diagnosis of Acute Myocardial Infarction. Clin Chem. Jun 2016;62(6):831–8. doi:10.1373/clinchem.2015.252569. No defined ADP.27117468
328 Truong QA, Bayley J, Hoffmann U, . Multi-marker strategy of natriuretic peptide with either conventional or high-sensitivity troponin-T for acute coronary syndrome diagnosis in emergency department patients with chest pain: from the "Rule Out Myocardial Infarction using Computer Assisted Tomography" (ROMICAT) trial. Am Heart J. Jun 2012;163(6):972–979.e1. doi:10.1016/j.ahj.2012.03.010. No defined ADP.22709749
329 Twerenbold R, Badertscher P, Boeddinghaus J, . 0/1-Hour Triage Algorithm for Myocardial Infarction in Patients With Renal Dysfunction. Circulation. Jan 30 2018;137(5):436–451. doi:10.1161/circulationaha.117.028901. Not prospective.29101287
330 Twerenbold R, Boeddinghaus J, Nestelberger T, . Clinical Use of High-Sensitivity Cardiac Troponin in Patients With Suspected Myocardial Infarction. J Am Coll Cardiol. Aug 22 2017;70(8):996–1012. doi:10.1016/j.jacc.2017.07.718. Neither primary study nor SR.28818210
331 Twerenbold R, Boeddinghaus J, Nestelberger T, . How to best use high-sensitivity cardiac troponin in patients with suspected myocardial infarction. Clin Biochem. Mar 2018;53:143–155. doi:10.1016/j.clinbiochem.2017.12.006. Neither primary study nor SR.29253510
332 Twerenbold R, Jaeger C, Rubini Gimenez M, . Impact of high-sensitivity cardiac troponin on use of coronary angiography, cardiac stress testing, and time to discharge in suspected acute myocardial infarction. Eur Heart J. Nov 21 2016;37(44):3324–3332. doi:10.1093/eurheartj/ehw232. No defined ADP.27357358
333 Twerenbold R, Neumann JT, Sörensen NA, . Prospective Validation of the 0/1-h Algorithm for Early Diagnosis of Myocardial Infarction. J Am Coll Cardiol. Aug 7 2018;72(6):620–632. doi:10.1016/j.jacc.2018.05.040. Not prospective.30071991
334 van den Berg P, Collinson P, Morris N, Body R. Diagnostic accuracy of a high-sensitivity troponin I assay and external validation of 0/3 h rule out strategies. Eur Heart J Acute Cardiovasc Care. Feb 8 2022;11(2):127–136. doi:10.1093/ehjacc/zuab102. Not prospective.35136994
335 van der Linden N, Wildi K, Twerenbold R, . Combining High-Sensitivity Cardiac Troponin I and Cardiac Troponin T in the Early Diagnosis of Acute Myocardial Infarction. Circulation. Sep 4 2018;138(10):989–999. doi:10.1161/circulationaha.117.032003. Not prospective.29691270
336 van Dongen DN, Fokkert MJ, Tolsma RT, . Accuracy of pre-hospital HEART score risk classification using point of care versus high sensitive troponin in suspected NSTE-ACS. Am J Emerg Med. Aug 2020;38(8):1616–1620. doi:10.1016/j.ajem.2019.158448. Not prospective.31699426
337 van Dongen DN, Tolsma RT, Fokkert MJ, . Pre-hospital risk assessment in suspected non-ST-elevation acute coronary syndrome: A prospective observational study. Eur Heart J Acute Cardiovasc Care. Mar 2020;9(1_suppl):5–12. doi:10.1177/2048872618813846. Not high-sensitivity Tn.
338 Van Hise CB, Greenslade JH, Parsonage W, Than M, Young J, Cullen L. External validation of heart-type fatty acid binding protein, high-sensitivity cardiac troponin, and electrocardiography as rule-out for acute myocardial infarction. Clin Biochem. Feb 2018;52:161–163. doi:10.1016/j.clinbiochem.2017.10.001. Not prospective.29054440
339 Vigen R, Kutscher P, Fernandez F, . Evaluation of a Novel Rule-Out Myocardial Infarction Protocol Incorporating High-Sensitivity Troponin T in a US Hospital. Circulation. Oct 30 2018;138(18):2061–2063. doi:10.1161/circulationaha.118.033861. Not prospective.30372140
340 Visser A, Wolthuis A, Breedveld R, ter Avest E. HEART score and clinical gestalt have similar diagnostic accuracy for diagnosing ACS in an unselected population of patients with chest pain presenting in the ED. Emerg Med J. Aug 2015;32(8):595–600. doi:10.1136/emermed-2014-203798. No defined ADP.25217099
341 Westwood M, Ramaekers B, Grimm S, . High-sensitivity troponin assays for early rule-out of acute myocardial infarction in people with acute chest pain: a systematic review and economic evaluation. Health Technol Assess. May 2021;25(33):1–276. doi:10.3310/hta25330. Systematic Review.
342 Westwood M, van Asselt T, Ramaekers B, . High-sensitivity troponin assays for the early rule-out or diagnosis of acute myocardial infarction in people with acute chest pain: a systematic review and cost-effectiveness analysis. Health Technol Assess. Jun 2015;19(44):1–234. doi:10.3310/hta19440. Systematic Review.
343 Westwood ME, Armstrong N, Worthy G, . Optimizing the Use of High-Sensitivity Troponin Assays for the Early Rule-out of Myocardial Infarction in Patients Presenting with Chest Pain: A Systematic Review. Clin Chem. Jan 8 2021;67(1):237–244. doi:10.1093/clinchem/hvaa280. Systematic Review.33418577
344 Wibring K, Lingman M, Herlitz J, Amin S, Bång A. Prehospital stratification in acute chest pain patient into high risk and low risk by emergency medical service: a prospective cohort study. BMJ Open. Apr 15 2021;11(4):e044938. doi:10.1136/bmjopen-2020-044938. Not ED or pre-ED presentation.
345 Widera C, Pencina MJ, Bobadilla M, . Incremental prognostic value of biomarkers beyond the GRACE (Global Registry of Acute Coronary Events) score and high-sensitivity cardiac troponin T in non-ST-elevation acute coronary syndrome. Clin Chem. Oct 2013;59(10):1497–505. doi:10.1373/clinchem.2013.206185. Not prospective.23818444
346 Wildi K, Boeddinghaus J, Nestelberger T, . External validation of the clinical chemistry score. Clin Biochem. May 2021;91:16–25. doi:10.1016/j.clinbiochem.2021.02.006. Not prospective.33636187
347 Wildi K, Boeddinghaus J, Nestelberger T, . Comparison of fourteen rule-out strategies for acute myocardial infarction. Int J Cardiol. May 15 2019;283:41–47. doi:10.1016/j.ijcard.2018.11.140. Retrospective.30545622
348 Wildi K, Cullen L, Twerenbold R, . Direct Comparison of 2 Rule-Out Strategies for Acute Myocardial Infarction: 2-h Accelerated Diagnostic Protocol vs 2-h Algorithm. Clin Chem. Jul 2017;63(7):1227–1236. doi:10.1373/clinchem.2016.268359. It is unclear how hs-TnT was used.28515106
349 Wildi K, Lopez-Ayala P, Koechlin L, . Validation of the Novel European Society of Cardiology 0/2-hour Algorithm Using Hs-cTnT in the Early Diagnosis of Myocardial Infarction. Am J Cardiol. Sep 1 2021;154:128–130. doi:10.1016/j.amjcard.2021.06.003. Unclear ADP. Only hs-TnT was used to classify patients.34272043
350 Wildi K, Nelles B, Twerenbold R, . Safety and efficacy of the 0 h/3 h protocol for rapid rule out of myocardial infarction. Am Heart J. Nov 2016;181:16–25. doi:10.1016/j.ahj.2016.07.013. Not prospective.27823689
351 Wildi K, Nestelberger T, Wussler D, . Impact of Food and Drug Administration Regulatory Approach on the 0/2-Hour Algorithm for Rapid Triage of Suspected Myocardial Infarction. Circ Cardiovasc Qual Outcomes. Jan 2019;12(1):e005188. doi:10.1161/circoutcomes.118.005188. No defined ADP.30630358
352 Wildi K, Twerenbold R, Jaeger C, . Clinical impact of the 2010-2012 low-end shift of high-sensitivity cardiac troponin T. Eur Heart J Acute Cardiovasc Care. Oct 2016;5(6):399–408. doi:10.1177/2048872616642952. No defined ADP.
353 Wong CP, Lui CT, Sung JG, Lam H, Fung HT, Yam PW. Prognosticating Clinical Prediction Scores Without Clinical Gestalt for Patients With Chest Pain in the Emergency Department. J Emerg Med. Feb 2018;54(2):176–185. doi:10.1016/j.jemermed.2017.10.006. Not prospective.29191490
354 Yang SM, Chan CH, Chan TN. HEART pathway and Emergency Department Assessment of Chest Pain Score–Accelerated Diagnostic Protocol application in a local emergency department of Hong Kong: an external prospective validation study. Hong Kong Journal of Emergency Medicine. 2020;27(1):30–38. Not high-sensitivity Tn.
355 Yean KS, Abd. Wahab MB, Zakaria MIB. A study on modified accelerated diagnostic protocol to safely discharge low-risk chest pain patients in emergency department. Hong Kong Journal of Emergency Medicine. 2020;27(3):134–145. Exclusions based on post-ED ETT.
356 Young JM, Pickering JW, George PM, . Heart Fatty Acid Binding Protein and cardiac troponin: development of an optimal rule-out strategy for acute myocardial infarction. BMC Emerg Med. Aug 31 2016;16(1):34. doi:10.1186/s12873-016-0089-y. Not prospective.27577952
357 Zhao Y, Izadnegahdar M, Lee MK, . High-Sensitivity Cardiac Troponin-Optimizing the Diagnosis of Acute Myocardial Infarction/Injury in Women (CODE-MI): Rationale and design for a multicenter, stepped-wedge, cluster-randomized trial. Am Heart J. Nov 2020;229:18–28. doi:10.1016/j.ahj.2020.06.013. No outcomes within 6 weeks reported.32916606
358 Zhao Y, Sivaswamy A, Lee MK, . A feasibility study for CODE-MI: High-sensitivity cardiac troponin–Optimizing the diagnosis of acute myocardial infarction/injury in women. American Heart Journal. 2021;234:60–70. No outcomes within 6 weeks reported.33460579
359 Zi Y, Ying-Xiong H, Zi-Yu Z, . Point-of-care sensitive cardiac troponin I in the rapid triage of chest pain patients in emergency department. Journal of the American College of Cardiology. 2014;64(16S):C131–C131. Not published/peer reviewed.