# APPENDIX A SEARCH STRATEGIES

## MEDLINE

1 | ((((“Chest Pain”[Mesh] OR “Myocardial Ischemia”[Mesh] OR “Acute Coronary Syndrome”[Mesh] OR “Myocardial Infarction”[Mesh] OR (acute coronary syndrome*[tiab]) OR (preinfarc*[tiab] AND Angina*[tiab]) OR (pre-infarc*[tiab] AND Angina*[tiab]) OR “Unstable angina*”[tiab] OR ((heart*[tiab] OR myocardi*[tiab] OR cardiac[tiab] OR coronary[tiab]) AND (preinfarc*[tiab] OR infarc*[tiab] OR attack*[tiab] OR arrest*[tiab] OR occlusion*[tiab] OR ischemia*[tiab] OR ischaemia[tiab]) OR occlusi*[tiab]) OR MI[tiab] OR ACS[tiab] OR STEMI[tiab] OR NSTE-ACS[tiab] OR NSTEACS[tiab] OR nonSTEMI[tiab] OR NSTEMI[tiab] OR AMI[tiab] OR UAP[tiab] OR OMI[tiab] OR ((acute[tiab] OR ischem*[tiab] OR ischaem*[tiab]) AND (coronar*[tiab] OR cardiac*[tiab] OR heart[tiab])) OR ((heart[tiab] OR myocard*[tiab]) AND infarct*[tiab])))
2 | ((“troponin T”[Mesh] OR “troponin I”[Mesh] OR troponin[Mesh] OR “trop I”[tiab] OR “trop t”[tiab] OR “troponin I”[tiab] OR “troponin T”[tiab] OR accu-tni[tiab] OR accutni[tiab] OR ctni-hs[tiab] OR ctniultra[tiab] OR ctni[tiab] OR ctnihs[tiab] OR ctnt-hs[tiab] OR ctnt[tiab] OR cTnT[tiab] OR ctnths[tiab] OR hs-ctni[tiab] OR hs-cTnT[tiab] OR hs-tni[tiab] OR hs-TnT[tiab] OR hsctni[tiab] OR hscTnT[tiab] OR Hstni[tiab] OR hsTnT[tiab] OR tni[tiab] OR tnt-hs[tiab] OR tnt[tiab] OR tnths[tiab] OR tropI[tiab] OR troponin*[tiab] OR tropT[tiab] OR “Accelerated diagnostic protocol*” OR “HEART Pathway” OR “EDACS-ADP” OR “EDACS” OR ADP)))
3 | ((“Emergency Service, Hospital”[Mesh] OR emergency room* OR emergency department* OR ED OR ER OR “Triage”[Mesh] OR “Emergencies”[Mesh] OR “Emergency Responders”[Mesh] OR “Emergency Treatment”[Mesh] OR “Emergency Medicine”[Mesh] OR “Emergency Medical Technicians”[Mesh] OR “Emergency Medical Services”[Mesh] OR “Ambulances”[Mesh] OR “Hospital Rapid Response Team”[Mesh] OR triage OR emergenc* OR ambulance* OR EMT OR EMS OR “Cardiology Service, Hospital”[Mesh])))
5 | #1 AND #2 AND #3
6 | ((((“2008/01/01”[Date - Entry] : “3000”[Date - Entry])) OR ((“2008/01/01”[Date - Publication] : “3000”[Date - Publication]))) OR ((“2008/01/01”[Date - Create] : “3000”[Date - Create])))
7 | AND/5-6

## EMBASE

1 | Heart muscle ischemia/exp OR heart muscle ischemia
2 | Myocardial ischemia
3 | Acute coronary syndrome
4 | Heart infarction
5 | Myocardial infarction
6 | Unstable angina pectoris
7 | Unstable angina
8 | (heart* OR myocardi* OR cardiac OR coronary) AND ((preinfarc* OR infarc* OR attachk* OR arrest*or) AND occlusion* OR ischemia* OR ischaemia* OR occlusi*)
9 | mi OR acs OR stemi OR ‘nste acs’ OR nsteacs. OR nonstemi OR nstemi OR ami OR uap OR omi
10 | #1 OR #2 OR #3 OR #4 OR #5 OR #6 OR #7 OR #8 OR #9
11 | troponin i
12 | troponin t
13 | trop i OR trop t OR troponin i OR troponin t OR accu tni OR accutni OR ctni hs OR ctni ultra OR ctni OR ctnihs OR ctnt hs OR ctnt OR ctnths OR hs ctni OR hs tni OR hs tnt OR hsctni OR hsctnt OR hstni OR hstnt OR tni OR tnt hs OR tnt OR tnths OR tropi OR troponin* OR tropt OR accelerated diagnostic protocol* OR heart pathway OR edacs-adp OR edacs OR adp
14 | #11 OR #12 OR #13
15 | emergency ward
16 | (Emergency AND room* OR emergency) AND department* OR ed OR er OR triage OR emergenc* OR emt OR ems
17 | #15 OR #16
18 | #10 AND #14 AND #17
19 | #10 AND #14 AND #17 AND ([article/lim OR [article in press]/lim) AND [humans]/lim AND [2008-2022-04-15]/py

## COCHRANE

1 | MeSh descriptor: [Chest Pain] explode all trees
2 | MeSh descriptor: [Myocardial Ischemia] explode all trees
3 | MeSh descriptor: [Acute Coronary Syndrome] explode all trees
4 | MeSh descriptor: [Myocardial Infarction] explode all trees
5 | ((hear* OR myocardi* OR cardiac OR coronary) AND (preinfarc* OR infarc* OR attack* OR arrest* OR ischemia* OR ischaemia* OR occlusi*))
6 | #1 OR #2 OR #3 OR #4 OR #5
7 | MeSh descriptor: [Troponin I] explode all trees
8 | MeSh descriptor: [Troponin T] explode all trees
9 | *trop I OR trop T OR troponin I OR troponin T OR accu-tni OR accutni OR ctni-hs OR ctni-ultra OR ctnihs OR ctnt-hs OR ctnt OR cTnT OR ctnths OR hs-ctni OR hs-cTnT OR hs-tni OR hs-TnT OR hsctni OR hscTnT OR Hstni OR hsTnT OR tni OR tnt-hs OR tnt OR tnths OR tropl OR troponin* OR tropT OR Accelerated diagnostic protocol* OR HEART Pathway OR EDACS-ADP OR EDACS OR ADP
10 | #7 OR #8 OR #9
11 | MeSh descriptor: [Emergency Medicall Services] explode all trees
12 | Triage OR emergenc* OR ambulance* OR EMT OR EMS
13 | #11 OR #12
14 | #6 AND #10 AND #13