# ABBREVIATIONS TABLE

Abbreviation: Definition
ACC/AHA: American College of Cardiology/American Heart Association
ACS: Acute coronary syndrome
ADP: Accelerated diagnostic protocols
BMI: Body mass index
CABG: Coronary artery bypass graft
CI: Confidence interval
CoE: Certainty of evidence
CP: Chest pain
cTn: Cardiac troponins
CVD: Cardiovascular disease
ECG: Electrocardiogram
ED: Emergency Department
EDACS: Emergency Department Assessment of Chest Pain Score
ESC: European Society of Cardiology
ESP: Evidence Synthesis Program
FDA: Food and Drug Administration
FHx: Family history
GRACE: Global Registry of Acute Coronary Events
GRADE: Grading of Recommendations Assessment, Development and Evaluation
HEART: History, Electrocardiogram, Age, Risk Factors, Troponin
hs-cTn: High-sensitivity cardiac troponins
IQR: Interquartile range
KQ: Key Questions
MACE: Major adverse cardiovascular event
MeSH: Medical Subject Heading
MI: Myocardial infarction
Mo: Month(s)
N: Sample size
NA: Not applicable
NR: Not reported
NRCS: Nonrandomized comparative study
NSTEMI: Non-ST-elevation myocardial infarction
OR: Odds ratio
PAD: Peripheral arterial disease
PCI: Percutaneous coronary intervention
PMID: PubMed identifier
RCT: Randomized controlled trial
RD: Risk difference
RF: Risk factor
SD: Standard deviation
STEMI: ST-elevation myocardial infarction
TEP: Technical Expert Panel
TIA: Transient ischemic attack
TIMI: Thrombolysis In Myocardial Infarction (study)
US: United States
VA: Veterans Affairs
wk: Week(s)
yo: Years old