# REFERENCES

1 Brignone E. Misconduct-related discharge from active duty military service: An examination of precipitating factors and post-deployment health outcomes. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2018;78(10-B(E)):No-Specified.
2 Metraux S, Clegg LX, Daigh JD, Culhane DP, Kane V. Risk factors for becoming homeless among a cohort of veterans who served in the era of the iraq and afghanistan conflicts. American Journal of Public Health. 2013;103(S2):S255–S261.24148066
3 Brignone E, Gundlapalli AV, Blais RK, Differential risk for homelessness among us male and female veterans with a positive screen for military sexual trauma. JAMA Psychiatry. 2016;73(6):582–589.27096847
4 Byrne T, Fargo JD, Montgomery AE, Roberts CB, Culhane DP, Kane V. Screening for homelessness in the veterans health administration: Monitoring housing stability through repeat screening. Public health reports (Washington, DC: 1974). 2015;130(6):684–692.
5 Cusack M, Montgomery AE. Examining the bidirectional association between veteran homelessness and incarceration within the context of permanent supportive housing. Special Issue: Homelessness Among Veterans, Other Adults, and Youth. 2017;14(2):250–256.
6 Fargo JD, Brignone E, Metraux S, Homelessness following disability-related discharges from active duty military service in afghanistan and iraq. Disability and Health Journal. 2017;10(4):592–599.28336255
7 Jutkowitz E, DeVone F, Halladay C, Hooshyar D, Tsai J, Rudolph JL. Incidence of homelessness among veterans newly diagnosed with alzheimer's disease and related dementias. Rhode Island medical journal (2013). 2021;104(4):20–25.
8 Montgomery AE, Rahman FAKM, Cusack M, Varley A, Byrne T. Correlates of transitions into housing instability among veterans accessing veterans health administration health care. Medical care. 2020;58(12):1105–1110.32925462
9 Mulcahy E, Szymkowiak D, Montgomery AE. Psychosocial risk factors for transitions into housing instability among women veterans. Journal of the American Board of Family Medicine: JABFM. 2021;34(2):387–391.33833007
10 Rosenheck R, Fontana A. A model of homelessness among male veterans of the vietnam war generation. The American Journal of Psychiatry. 1994;151(3):421–427.8109652
11 Tsai J, Hoff RA, Harpaz-Rotem I. One-year incidence and predictors of homelessness among 300,000 u.S. Veterans seen in specialty mental health care. Special Issue: Homelessness Among Veterans, Other Adults, and Youth. 2017;14(2):203–207.
12 Ghose T, Fiellin DA, Gordon AJ, Hazardous drinking and its association with homelessness among veterans in care. Drug and Alcohol Dependence. 2013;132(1–2):202–206.23474200
13 Elbogen EB, Sullivan CP, Wolfe J, Wagner HR, Beckham JC. Homelessness and money mismanagement in iraq and afghanistan veterans. American Journal of Public Health. 2013;103(S2):S248–S254.24148067
14 Gundlapalli AV, Fargo JD, Metraux S, Military misconduct and homelessness among us veterans separated from active duty, 2001–2012. JAMA: Journal of the American Medical Association. 2015;314(8):832–834.26305655
15 Naifeh JA, Capaldi VF, Chu C, Prospective associations of military discharge characterization with post-active duty suicide attempts and homelessness: Results from the study to assess risk and resilience in servicemembers-longitudinal study (starrs-ls). Military medicine. 2022.
16 Gundlapalli AV, Redd A, Carter ME, Palmer M, Peterson R, Samore MH. Exploring patterns in resource utilization prior to the formal identification of homelessness in recently returned veterans. Studies in health technology and informatics. 2014;202:265–268.25000067
17 Rivera-Rivera N, Villarreal AA. Homeless veterans in the caribbean: Profile and housing failure. Revista Puertorriquena de Psicologia. 2021;32(1):64–73.35765409
18 Edwards ER, Dichiara A, Gromatsky M, Tsai J, Goodman M, Pietrzak R. Understanding risk in younger veterans: Risk and protective factors associated with suicide attempt, homelessness, and arrest in a nationally representative veteran sample. Military Psychology. 2022;34(2):175–186.
19 Nichter B, Tsai J, Pietrzak RH. Prevalence, correlates, and mental health burden associated with homelessness in u.S. Military veterans. Psychological medicine. 2022:1–11.
20 Spinola S, Hoff RA, Tsai J. A psychosocial mediational model of homelessness among u.S. Male and female veterans who served in iraq and afghanistan. Health & social care in the community. 2021;29(2):453–463.32662176
21 Tsai J, Hooshyar D. Prevalence of eviction, home foreclosure, and homelessness among low-income us veterans: The national veteran homeless and other poverty experiences study. Public health. 2022;213:181–188.36444823
22 Tsai J, Link B, Rosenheck RA, Pietrzak RH. Homelessness among a nationally representative sample of us veterans: Prevalence, service utilization, and correlates. Social Psychiatry and Psychiatric Epidemiology: The International Journal for Research in Social and Genetic Epidemiology and Mental Health Services. 2016;51(6):907–916.
23 Twamley EW, Hays CC, Van Patten R, Neurocognition, psychiatric symptoms, and lifetime homelessness among veterans with a history of traumatic brain injury. Psychiatry Research. 2019;271:167–170.30481694
24 Washington DL, Yano EM, McGuire J, Hines V, Lee M, Gelberg L. Risk factors for homelessness among women veterans. Journal of Health Care for the Poor and Underserved. 2010;21(1):81–91.
25 Copeland LA, Miller AL, Welsh DE, McCarthy JF, Zeber JE, Kilbourne AM. Clinical and demographic factors associated with homelessness and incarceration among va patients with bipolar disorder. American Journal of Public Health. 2009;99(5):871–877.19299667
26 Brown GR, Jones KT. Mental health and medical health disparities in 5135 transgender veterans receiving healthcare in the veterans health administration: A case-control study. LGBT Health. 2016;3(2):122–131.26674598
27 Carter SP, Montgomery AE, Henderson ER, Housing instability characteristics among transgender veterans cared for in the veterans health administration, 2013–2016. American Journal of Public Health. 2019;109(10):1413–1418.31415197
28 Fletcher OV, Chen JA, van Draanen J, Prevalence of social and economic stressors among transgender veterans with alcohol and other drug use disorders. SSM - population health. 2022;19:101153.35813187
29 Byrne T, Montgomery AE, Fargo JD. Predictive modeling of housing instability and homelessness in the veterans health administration. Health services research. 2019;54(1):75–85.30240000
30 Iheanacho T, Stefanovics E, Rosenheck R. Opioid use disorder and homelessness in the veterans health administration: The challenge of multimorbidity. Journal of opioid management. 2018;14(3):171–182.30044482
31 Harris T, Kintzle S, Wenzel S, Castro CA. Expanding the understanding of risk behavior associated with homelessness among veterans. Military Medicine. 2017;182(9):e1900–e1907.
32 Stefanovics EA, Rosenheck RA. Prevalence and multi-morbid correlates of homelessness among veterans with hiv infection nationally in the veterans health administration. Psychology, Health & Medicine. 2019;24(9):1123–1136.
33 Lin D, Kim H, Wada K, Unemployment, homelessness, and other societal outcomes in patients with schizophrenia: A real-world retrospective cohort study of the united states veterans health administration database: Societal burden of schizophrenia among us veterans. BMC Psychiatry. 2022;22.34996394
34 US Department of Housing and Urban Development. The 2022 annual homelessness assessment report (ahar) to congress. 2022.
35 O’Flaherty B. Wrong person and wrong place: For homelessness, the conjunction is what matters. Journal of Housing Economics. 2004;13(1):1–15.
36 McLeroy KR, Bibeau D, Steckler A, Glanz K. An ecological perspective on health promotion programs. Health Educ Q. 1988;15(4):351–377.3068205
37 Shelton KH, Taylor PJ, Bonner A, van den Bree M. Risk factors for homelessness: Evidence from a population-based study. Psychiatr Serv. 2009;60(4):465–472.19339321
38 Tsai J, Mares AS, Rosenheck RA. Do homeless veterans have the same needs and outcomes as non-veterans? Military Medicine. 2012;177(1):27–31.22338975
39 Fargo J, Metraux S, Byrne T, Prevalence and risk of homelessness among us veterans. Preventing chronic disease. 2012;9:E45.22280960
40 Fazel S, Geddes JR, Kushel M. The health of homeless people in high-income countries: Descriptive epidemiology, health consequences, and clinical and policy recommendations. Lancet. 2014;384(9953):1529–1540.25390578
41 Tsai J, Doran KM, Rosenheck RA. When health insurance is not a factor: National comparison of homeless and nonhomeless us veterans who use veterans affairs emergency departments. American Journal of Public Health. 2013;103(S2):S225–S231.24148061
42 O'Toole TP, Johnson EE, Redihan S, Borgia M, Rose J. Needing primary care but not getting it: The role of trust, stigma and organizational obstacles reported by homeless veterans. Journal of health care for the poor and underserved. 2015;26(3):1019–1031.26320930
43 Whiting P, Savović J, Higgins JP, Robis: A new tool to assess risk of bias in systematic reviews was developed. Journal of clinical epidemiology. 2016;69:225–234.26092286
44 Hayden JA, Cote P, Bombardier C. Evaluation of the quality of prognosis studies in systematic reviews. Annals of Internal Medicine. 2006;144(6):427.16549855
45 Berkman ND, Lohr KN, Ansari M, Grading the strength of a body of evidence when assessing health care interventions for the effective health care program of the agency for healthcare research and quality: An update methods guide for effectiveness and comparative effectiveness reviews. In. Rockville MD: Agency for Healthcare Research and Quality; 2013.
46 Liu M, Luong L, Lachaud J, Edalati H, Reeves A, Hwang SW. Adverse childhood experiences and related outcomes among adults experiencing homelessness: A systematic review and meta-analysis. The Lancet Public health. 2021;6(11):e836–e847.34599894
47 Nilsson SF, Nordentoft M, Hjorthoj C. Individual-level predictors for becoming homeless and exiting homelessness: A systematic review and meta-analysis. Journal of urban health: bulletin of the New York Academy of Medicine. 2019;96(5):741–750.31388823
48 Ackerman A. The impact of combat on veteran well-being. Dissertation Abstracts International Section A: Humanities and Social Sciences. 2018;79(12-A(E)):No-Specified.
49 Adler AB, LeardMann CA, Yun S, Jacobson IG, Forbes D. Problematic anger and economic difficulties: Findings from the millennium cohort study. Journal of Affective Disorders. 2022;297:679–685.34710505
50 Bachhuber MA, Roberts CB, Metraux S, Montgomery AE. Screening for homelessness among individuals initiating medication-assisted treatment for opioid use disorder in the veterans health administration. Journal of opioid management. 2015;11(6):459–462.26728642
51 Brown GR, Jones KT. Racial health disparities in a cohort of 5,135 transgender veterans. Journal of Racial and Ethnic Health Disparities. 2014;1(4):257–266.
52 Byrne T, Cashy J, Metraux S, Association between registered sex offender status and risk of housing instability and homelessness among veterans. Journal of interpersonal violence. 2022;37(7–8):NP5818–NP5829.32960141
53 Dichter ME, Wagner C, Borrero S, Broyles L, Montgomery AE. Intimate partner violence, unhealthy alcohol use, and housing instability among women veterans in the veterans health administration. Special Issue: Homelessness Among Veterans, Other Adults, and Youth. 2017;14(2):246–249.
54 Dunne EM, Burrell LE II, Diggins AD, Whitehead NE, Latimer WW. Increased risk for substance use and health-related problems among homeless veterans. The American Journal on Addictions. 2015;24(7):676–680.26359444
55 Edens EL, Kasprow W, Tsai J, Rosenheck RA. Association of substance use and va service-connected disability benefits with risk of homelessness among veterans. The American Journal on Addictions. 2011;20(5):412–419.21838839
56 Elbogen EB, Johnson SC, Wagner HR, Newton VM, Beckham JC. Financial well-being and postdeployment adjustment among iraq and afghanistan war veterans. Military Medicine. 2012;177(6):669–675.22730842
57 Gamache G, Rosenheck R, Tessler R. Military discharge status of homeless veterans with mental illness. Military Medicine. 2000;165(11):803–815.11143423
58 Ghose T, Gordon AJ, Metraux S, Justice AC. Mental illness and homelessness among veterans. Psychiatric Services. 2011;62(12):1514–1515.
59 Ghose T, Gordon AJ, Metraux S, The association between hiv status and homelessness among veterans in care. Journal of Community Psychology. 2015;43(2):189–198.
60 Haque L, Rosenheck R. Mental health and addiction service use among united states veterans with liver disease nationally in the veterans health administration. Journal of Public Mental Health. 2021;20(3):191–200.
61 Hefner K, Rosenheck R. Multimorbidity among veterans diagnosed with ptsd in the veterans health administration nationally. Psychiatric Quarterly. 2019;90(2):275–291.30847694
62 Ho P, Rosenheck R. Substance use disorder among current cancer patients: Rates and correlates nationally in the department of veterans affairs. Psychosomatics. 2018;59(3):267–276.29452704
63 Lim S, Kasprow WJ, Rosenheck RA. Psychiatric illness and substance abuse among homeless asian-american veterans. Psychiatric Services. 2006;57(5):704–707.16675767
64 MacLean RR, Sofuoglu M, Rosenheck R. Tobacco and alcohol use disorders: Evaluating multimorbidity. Addictive Behaviors. 2018;78:59–66.29127785
65 Manhapra A, Stefanovics E, Rosenheck R. The association of opioid use disorder and homelessness nationally in the veterans health administration. Drug and Alcohol Dependence. 2021;223.
66 Mares AS, Rosenheck RA. Perceived relationship between military service and homelessness among homeless veterans with mental illness. Journal of Nervous and Mental Disease. 2004;192(10):715–719.15457118
67 Montgomery AE, Cutuli JJ, Evans-Chase M, Treglia D, Culhane DP. Relationship among adverse childhood experiences, history of active military service, and adult outcomes: Homelessness, mental health, and physical health. American journal of public health. 2013;103 Suppl 2:S262–268.24148064
68 Montgomery AE, Dichter ME, Thomasson AM, Fu X, Roberts CB. Demographic characteristics associated with homelessness and risk among female and male veterans accessing vha outpatient care. Women's Health Issues. 2015;25(1):42–48.25498763
69 Montgomery AE, Dichter ME, Thomasson AM, Roberts CB, Byrne T. Disparities in housing status among veterans with general medical, cognitive, and behavioral health conditions. Psychiatric Services. 2015;66(3):317–320.25727122
70 Rosenheck R, Gallup P, Leda CA. Vietnam era and vietnam combat veterans among the homeless. American Journal of Public Health. 1991;81(5):643–646.2014870
71 Rosenheck R, Stefanovics E, Rhee TG. Association of the military transition to an all-volunteer force and subsequent zero-tolerance drug policy with characteristics of male veterans in the vietnam, post-vietnam and subsequent post-post vietnam cohorts. The Psychiatric quarterly. 2021;92(3):1129–1145.33587258
72 Tsai J, Pietrzak RH, Szymkowiak D. The problem of veteran homelessness: An update for the new decade. American journal of preventive medicine. 2021;60(6):774–780.33583678
73 Tsai J, Szymkowiak D, Pietrzak RH. Delayed homelessness after military discharge: Examination of a sleeper effect. American journal of preventive medicine. 2020;59(1):109–117.32386790
74 Yaekel-Black Elk JK. American indian vietnam combat veterans: How out-of-home placement and having a veteran primary care giver are associated with features and symptoms of trauma. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2009;69(12-B):7832.
75 Yoon G, Petrakis IL, Rosenheck RA. Correlates of major depressive disorder with and without comorbid alcohol use disorder nationally in the veterans health administration. The American Journal on Addictions. 2015;24(5):419–426.25950244
76 National Center for Homeless Education. The mckinney-vento definition of homeless. https://nche.ed.gov/mckinney-vento-definition/. Accessed June, 2023.
77 Veterans Health Administration. Va homeless programs. 2021; https://www.va.gov/HOMELESS/faqs.asp#accordion-definition. Accessed May, 2023.
78 Felitti VJ, Anda RF, Nordenberg D, Relationship of childhood abuse and household dysfunction to many of the leading causes of death in adults. The adverse childhood experiences (ace) study. Am J Prev Med. 1998;14(4):245–258.9635069
79 Mersky JP, Choi C, Plummer Lee C, Janczewski CE. Disparities in adverse childhood experiences by race/ethnicity, gender, and economic status: Intersectional analysis of a nationally representative sample. Child Abuse Negl. 2021;117:105066.33845239
80 American Psychiatric Association D-TF. Diagnostic and statistical manual of mental disorders, fifth edition, text revision (dsm-5-tr). Washington, DC: American Psychiatric Publishing, Inc.; 2022.
81 Byrne T, Munley EA, Fargo JD, Montgomery AE, Culhane DP. New perspectives on community-level determinants of homelessness. Journal of Urban Affairs. 2013;35(5):607–625.
82 Byrne T, Montgomery AE, Fargo JD. Unsheltered homelessness among veterans: Correlates and profiles. Community mental health journal. 2016;52(2):148–157.26289119
83 Kertesz SG, DeRussy AJ, Riggs KR, Characteristics associated with unsheltered status among veterans. American journal of preventive medicine. 2021;61(3):357–368.34419233
84 O'Connell MJ, Kasprow W, Rosenheck RA. Rates and risk factors for homelessness after successful housing in a sample of formerly homeless veterans. Psychiatric Services. 2008;59(3):268–275.18308907
85 Gabrielian S, Burns AV, Nanda N, Hellemann G, Kane V, Young AS. Factors associated with premature exits from supported housing. Psychiatric services (Washington, DC). 2016;67(1):86–93.
86 Tsai J, ed Homelessness among us veterans: Critical perspectives. Oxford University Press; 2019.
87 Balshem H, Christensen V, Tuepker A, Kansagara D. A critical review of the literature regarding homelessness among veterans. 2011.
88 Tsai J, Szymkowiak D, Jutkowitz E. Developing an operational definition of housing instability and homelessness in veterans health administration's medical records. PloS one. 2022;17(12):e0279973.36584201
89 Ciccarone D. The rise of illicit fentanyls, stimulants and the fourth wave of the opioid overdose crisis. Curr Opin Psychiatry. 2021;34(4):344–350.33965972
90 Becker WC, Fiellin DA. When epidemics collide: Coronavirus disease 2019 (covid-19) and the opioid crisis. Ann Intern Med. 2020;173(1):59–60.32240291
91 Koh KA, Montgomery AE, O'Brien RW, Predicting homelessness among u.S. Army soldiers no longer on active duty. Am J Prev Med. 2022;63(1):13–23.35725125
92 Padgett DK, Tiderington E, Smith BT, Derejko KS, Henwood BF. Complex recovery: Understanding the lives of formerly homeless adults with complex needs. J Soc Distress Homeless. 2016;25(2):60–70.28439191