# DISCUSSION

The aim of this systematic review was to synthesize evidence on factors impacting the risk of homelessness among Veterans to inform ongoing VA efforts to reduce and prevent Veteran homelessness and to identify areas for future research. Despite searching for studies of both community and individual-level factors associated with homelessness among Veterans, we only identified studies of individual-level factors. Using a best-evidence approach, we focused on studies that evaluated potential risk and protective factors before homelessness occurred to establish cause and effect. As such, the strongest evidence for many factors was from studies that followed participants over time, identifying and measuring factors that differentiated those who eventually become homelessness from those who remained stably housed. We categorized factors as occurring before, during, or after miliary service, recognizing that defining a specific timeframe for some factors, including the presence of mental health and substance use disorders, is methodologically challenging. We also synthesized evidence on demographic factors, many of which were not bound to a specific timeframe, such as race and gender.

Overall, the following individual-level factors were consistently associated with an increased risk of experiencing homelessness in studies providing longitudinal evidence: ACEs (studied in general populations and Veterans), discharge status aside from honorable, lower service-connected disability rating or no service-connected disability rating, history of military sexual trauma, and presence of a mental health and/or substance use disorder. Having a history of incarceration and non-military-related trauma in adulthood were also factors associated with an increased risk of experiencing homelessness, although these factors were only evaluated in a single study. Additionally, enlisted status (compared to drafted or commissioned status) and lifetime trauma history were associated with homelessness in cross-sectional studies (considered risk correlates and not necessarily true risk factors, given study designs). In contrast, honorable discharge status, having a higher military pay grade, and having a higher service-connected disability rating were consistently associated with a lower risk of experiencing homelessness in studies providing longitudinal evidence. Completing more years of service was also identified as a potential protective factor in cross-sectional studies. In terms of demographics, Veterans who were male, Black, and/or unmarried were more likely to experience homelessness, while those living in a rural area appeared to have a lower risk of homelessness. Additionally, having a lower education level or identifying as transgender were factors associated with a greater risk of experiencing homelessness in cross-sectional studies.

Among individual-level factors with longitudinal evidence (best evidence), the strongest associations (based on the magnitude of the reported effect size) were observed for higher military pay grade (lower homelessness risk), not being married (greater risk), discharge status aside from honorable (greater risk), any mental health diagnosis (greater risk), and ACEs (greater risk).

Findings on combat exposure were mixed and the overall association between combat exposure and homelessness risk is unclear. Findings were also inconsistent for other factors related to miliary service including service era and military branch. Associations between chronic medical conditions and/or medical co-morbidities and homelessness have been less frequently studied compared to mental health and substance-related conditions. Available evidence does not suggest a pattern of increased or decreased homelessness risk based on chronic medical conditions and/or medical co-morbidities and so the nature of these associations, if any, remains unclear.

VHA currently supports several initiatives to reduce and prevent homelessness among Veterans. Findings from this review may help further inform outreach efforts or service provision for Veterans with identified individual-level risks for experiencing homelessness. However, this evidence base has several limitations, as discussed in more detail below, and important research gaps exist.

Community factors, such as housing access and affordability, may account for why some Veterans experience homelessness while others with similar individual-level vulnerabilities remain stably housed. Structural models of homelessness focus on macro-level trends related to housing affordability and access, safety net spending, labor market conditions, and eviction rates.^81^ Researchers who study housing and homelessness have argued that personal experiences and circumstances that may make an individual more likely to experience homelessness should not be evaluated outside of the context of structural factors at the community level that create conditions for homelessness.^35^

A socio-ecological view of homelessness underscores that the relative importance of a given individual-level factor, such as having a mental health disorder, to the risk of experiencing homelessness greatly depends on factors external to the individual, such as the presence or absence of affordable housing in that individual’s community. For example, 2 individuals with similar demographic profiles and similar exposures in terms of childhood experiences, military service, and post-service circumstances could have different levels of risk for experiencing homelessness depending on their unique family and social networks, presence of a local safety net and access to housing resources, and the degree of housing scarcity in their specific geographic locations. To date, little research has been conducted on the effects of structural factors on Veteran homelessness risk. Consequently, our understanding of the mechanisms that lead to homelessness among Veterans is incomplete. A potential consequence of this important gap in the evidence is that predictive models of homelessness risk as well as programs and policies designed to reduce and prevent Veteran homelessness may overly emphasize the importance of individual factors, even if community-level factors are predominantly driving homelessness rates in some locations.

Finally, while we used a general definition of homelessness to determine study eligibility—and many included studies describe the relationship of a certain factor with “homelessness”—it is important to consider variation in the meanings and experiences of homelessness across individuals. For instance, Veterans experiencing homelessness may be unstably housed but have regular access to shelter, or they may frequently be unsheltered. Another example is that some Veterans experiencing homelessness may remain housed after accessing permanent supportive housing or other stable housing in their community, while others may have great difficulty maintaining housing even if it is available.

We identified, but did not formally include among our results, several studies that discuss factors that may confer greater risk of unsheltered (versus sheltered) homelessness or of returning to homelessness after being housed. Factors associated with unsheltered homelessness are broadly consistent with those that may make a Veteran more vulnerable to homelessness overall, including being male, older, or unmarried, and having a substance use or other mental health disorder.^82,83^ Other factors associated with unsheltered homelessness include lower levels of VHA eligibility and greater use of VHA inpatient services with infrequent use of VHA outpatient services;^82^ having a criminal justice history, financial hardship, or limited social support;^83^ or living in a community with poor shelter access or higher rents.^83^ Several studies^5,84,85^ also reported that many of these factors were common among Veterans who returned to homelessness after enrollment in a housing support program. These studies were generally cross-sectional, but their findings highlight the confluence of individual and community factors that may increase (and sustain) Veterans’ risk of homelessness.

## LIMITATIONS

This evidence base has several important limitations. First, most studies relied on retrospective analysis of medical record data to measure individual risks. While information on certain risks may be straightforward to ascertain (such as demographic characteristics and service era), the availability and timing of data related to some risk factors may be limited. For example, data regarding military sexual trauma depend on Veterans being asked a screening question at the point of care and were reported as missing for 23% of participants in 1 study.^3^ Variability in screening practices resulting in missing data may skew the observed effect for a given risk factor. Moreover, studies based on VHA medical record data only capture information related to Veterans receiving VHA services. Because access points to VA housing resources are often integrated with other services related to diagnosing and treating mental health and substance use disorders, these conditions may be overrepresented in samples of Veterans using VA services. Findings may or may not be generalizable to Veterans not receiving health care or receiving care outside of VHA settings.

Second, although cohort studies attempted to verify potential risk factors that occurred before homelessness, the timing of some factors may be inherently difficult to determine. For example, in cohort studies, mental health diagnoses were recorded after military service (while in VHA care) and prior to experiencing homelessness. However, mental health symptoms may have occurred prior to or during service and/or been exacerbated by experiences during service. The same limitation applies to other factors with the potential to span service timeframes, such as substance use.

Third, most studies used analytic methods that give the association between individual risk factors and homelessness (ie, while holding others constant). This approach limits insights into the relationships between factors and the importance of 1 factor relative to others. Analyses of ACEs as a risk factor for later homelessness, for example, may tend to oversimplify an association that is mediated by other factors such as poverty and race/ethnicity.^79^

Fourth, methods used to measure and define homelessness varied across studies and all have potential limitations. For example, PIT counts like those used by HUD taken on a single night may overestimate long-term chronic homelessness and underestimate the prevalence of transient or episodic homelessness.^86,87^ Moreover, definitions used in research may not necessarily align with how individuals self-report homelessness (which could be more nuanced) or how homelessness is assessed in a health care setting and captured in medical record data. Unstable housing, a term that refers to the potential to become homeless, is sometimes used interchangeably with the term homeless, further complicating efforts to identify individuals experiencing homelessness using medical record data.^88^ Whether individual-level factors associated with homelessness vary according to what definitions are used is unclear.

Finally, most studies included in this review were published before the start of the COVID-19 pandemic and prior to changes in the illicit drug supply leading to increased use of potent synthetic opioids and stimulants among those with substance use disorders.^89^ The COVID-19 pandemic and the ongoing crisis of substance use and substance-related deaths have had profound impacts on US society generally, and may have increased the vulnerability of Veterans already at-risk for experiencing homelessness in ways that have yet to be described.^90^

Limitations of our review methods include our use of sequential review (rather than dual independent review) for data abstraction and risk of bias assessment.

## FUTURE RESEARCH

The following are considerations for future research on factors impacting the risk of homelessness among Veteran populations:

- Conduct analyses of structural factors that may be impacting Veteran homelessness, ideally in ways that integrate community-level data with individual-level data to provide a comprehensive assessment of risk and protective factors. An example of this type of study is one that integrated individual-level data with county-level data to predict homelessness among active-duty Army soldiers.^91^
- Employ methods frequently used in social science settings, like latent class analysis, to improve understanding of how risk factors for homelessness co-occur and together increase homelessness risk. Examining mediation relationship could also be informative. For instance, despite having PTSD or another mental health diagnosis that could increase vulnerability to homelessness, having a service-connected disability for that diagnosis (which confers financial compensation) may reduce an individual’s actual risk of homelessness substantially. Similarly, higher risk associated with dishonorable/other than honorable discharge might be a proxy for lack of access to VA benefits/services.
- Consider further use of qualitative methods to describe complex interplays between structural and individual-level factors impacting homeless, as have been used in studies of homelessness among the general population.^92^

## CONCLUSION

The aim of this systematic review was to synthesize evidence on factors associated with Veteran homelessness. The strongest associations were observed for higher military pay grade (lower homelessness risk), not being married (greater risk), discharge status aside from honorable (greater risk), any mental health diagnosis (greater risk), and ACEs (greater risk). Available evidence has important gaps and limitations. To date, little research has been conducted on the effects of structural factors, such as those that reduce housing security or make stable housing difficult to obtain, on Veteran homelessness risk. Consequently, our understanding of the mechanisms the lead to homelessness among Veterans is incomplete. Future research should aim to integrate community and individual factors to provide a more comprehensive understanding of the pathways to Veteran homelessness, which if incorporated into a predictive model of homelessness, would likely result in a more accurate assessment of a Veteran’s vulnerability to homelessness.