# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 1) summarizes the results of the study selection process (a full list of excluded studies is available in Appendix B in Supplemental Materials).

Figure 1 Literature Flowchart

Abbreviations. CCRCT=Cochrane Central Register of Controlled Trials; CDSR=Cochrane Database of Systematic Reviews; SR=systematic review.

## LITERATURE OVERVIEW

We identified 103 potentially relevant articles after deduplication and title and abstract screening. We included 62 studies (in 64 publications), 2 systematic reviews on childhood and adolescent risk factors for homelessness in the general population,^46,47^ and 15 longitudinal cohorts^1–4,6–16^ (Table 1) and 43 cross-sectional studies (in 45 publications)^18–33,39,48–75^ in Veteran populations (see Appendix C in Supplemental Materials for full study details). Most longitudinal studies were retrospective cohorts utilizing large samples (sample size range 620 to 4,633,069) pulled from VHA databases. Most of these studies included a general Veteran population utilizing VHA services, but several studies were specific to Veterans serving in Operation Enduring Freedom (OEF), Operation Iraqi Freedom (OIF), and Operation New Dawn (OND), and 1 study^10^ from 1994 focused on male Vietnam Veterans.

Studies evaluated individual-level factors associated with homelessness. We did not identify any studies of structural factors examined at the community level. Most exposures occurred during service (eg, combat exposure, military sexual trauma) or post-service (eg, mental health, substance use). Many studies also examined disparities in experiencing homelessness based on demographic factors that spanned timeframes (eg, gender and race/ethnicity).

Definitions of homelessness varied across studies, reflecting the lack of a universally accepted definition or method of measuring homelessness. HUD’s definition of homeless describes a person who lacks a fixed, regular, and adequate nighttime residence.^34^ The VA uses the McKinney-Vento definition of homelessness which includes those living in temporary shelters.^76,77^ In included studies, homelessness was most often measured by International Classification of Diseases (ICD)-9/10 codes (8/15 longitudinal studies), use of VA homelessness services, and/or a positive response to the VA Homelessness Screening Clinical Reminder (HCSR). The VA HCSR asks 2 questions: “In the past 2 months, have you been living in stable housing that you own, rent, or stay in as part of a household?” and “Are you worried or concerned that in the next 2 months you may NOT have stable housing that you own, rent, or stay in as part of a household?” Most studies relied on a positive response to the first question regarding stable housing, but several studies looked at the combined response to the 2 screening questions, which represents both homelessness and housing insecurity.

Factors that were examined in more than 1 cross-sectional study but not included in longitudinal studies were transgender identity,^26–28^ education level,^18–24^ Asian race,^29,63^ geographic location,^21,29,33,52^ obesity,^29,69^ dementia,^32,55^ unemployment,^23–25^ years of military service,^18,19,22^ enlistment (not commissioned or drafted),^19,22^ deployment frequency,^18,19^ inpatient substance abuse treatment,^29,30^ tobacco use,^19,24,31,32^ lifetime trauma history,^19,33^ and use of inpatient, outpatient, or emergency department care.^24,29,30,52^ The remaining cross-sectional studies either examined factors that were included in longitudinal studies or examined a factor unique to that study (see Supplemental Materials for full study details).

Although most studies used statistical adjustment methods to control for demographic characteristics and health conditions (ie, age, race, mental health disorders), most did not adjust for a comprehensive set of potential confounding variables and remain at risk of bias. Another common methodological limitation of cohort studies was the exclusion of potential study participants because of missing data. Strength of evidence ratings were mostly low or insufficient due to study limitations, inconsistent findings, and/or identifying only a single cohort study for a given factor. However, several factors were rated as having moderate strength of evidence including alcohol use disorder, drug use disorder (including opioid use disorder), posttraumatic stress disorder (PTSD), depression, schizophrenia or psychoses, misconduct or dishonorable discharge status, experience of military sexual trauma, non-married marital status, having a lower income or financial status, and living in a non-rural geographic area (see Supplemental Materials for full risk of bias and strength of evidence assessments).

Table 1 Characteristics of Included Longitudinal Studies

Study | Sample Size; Follow-up | Specific Population(s) Examined | Population Characteristics | Homelessness Classification | Exposures/Factors Assessed
Brignone 2016^3^ | N=601,892; 60 mos. | OEF/OIF Veterans separated between 2001 and 2011 | 39.2 yrs.; 87.6% male; 50.2% White | ICD-9 code, or non-ICD VHA clinic or specialty code related to receipt of homeless services | Gender; Military sexual trauma; Education; Marital status; Race; Hispanic ethnicity; Military rank; Branch of service
Brignone 2018^1^ | N=19,794; 12 mos. | Misconduct-discharged Veterans deployed to post-9/11 conflicts in Iraq and Afghanistan | 26.8 yrs.; 91.9% male; 59.3% White | ICD-9 code, or non-ICD VHA clinic or specialty code related to receipt of homeless services | Gender; Marital status; No HS diploma; Race; Combat exposure; Disability rating; Military branch; Military sexual trauma; Pay grade; MH clinic usage; PTSD diagnosis; Substance use clinic usage
Byrne 2015^4^ | N=17,720; 6–12 mos. | Veterans responding to the HSCR at VHA healthcare facilities | NR | Positive screen on HSCR | Age; Gender; Hispanic/Latino ethnicity; Race; Disability rating; OEF/OIF service era
Elbogen 2013^13^ | N=1,090; 12 mos. | Iraq and Afghanistan War era Veterans | 34.4 yrs. (median); 84.5% male; 72.8% White | Study survey question | Mental health diagnoses; History of incarceration; Income (annual and money mismanagement)
Fargo 2017^6^ | N=449,329; 60 mos. | OEF/OIF Veterans discharged as of Dec. 2011 | 38.4 yrs.; 89.7% male; 38.4% White | ICD-9 codes and receipt of VHA homeless services | Disability rating; Discharge status; Mental health or substance use disorder
Ghose 2013^12^ | N=28,383; 12 mos. | HIV-infected and uninfected patients seen in VA infectious disease and general medical clinics | 50.2 yrs.; 94.9% male; NR | Study survey question | Gender; Race; HIV status; Mental health diagnoses; Income; Hazardous alcohol use; Alcohol dependence; Weekly illicit substance use
Gundlapalli 2014^16^ | N=31,260; 24 mos. | OEF/OIF/OND Veterans | NR | ICD-9 code or receipt of VA homeless services | Alcohol/Substance use VA encounter
Gundlapalli 2015^14^ | N=448,290; 60 mos. | Veterans deployed in Afghanistan or Iraq | NR (62.3% 18–29 yrs.); 87.8% male; 39.8% White | ICD-9 code or participation in VA homelessness services | Discharge status
Jutkowitz 2021^7^ | N=383,478; NR | Veterans with a diagnosis of Alzheimer’s disease or related diagnoses | 78.5 yrs.; 97.5% male; 77.2% White | ICD-9 and ICD-10 codes | Age; Gender; Marital status; Race; Combat exposure; Disability rating; Medical conditions; Mental health diagnoses; Rural living area; Alcohol use disorder; Substance use disorder
Metraux 2013^2^ | N=310,685; 60 mos. | Veterans discharged between 2005–2006 | NR; 84.8% male; NR | ICD-9 code or receipt of VA homeless services | Age; Discharge status; Military branch; Pay grade; Mental health diagnoses; Substance use
Montgomery 2020^8^ | N=4,633,069; 48 mos. | Veterans responding to the HSCR at VHA health care facilities | NR; 92.8% male; 76.9% White | Positive screen on HSCR | Age; Gender; Hispanic ethnicity; Marital status; Race; Combat exposure; Disability rating; Military sexual trauma; OEF/OIF/OND service era; Chronic medical condition; Mental health diagnoses; Suicide or self-harm; Rural living area; Alcohol use disorder; Drug use disorder; Opioid use disorder
Mulcahy 2021^9^ | N=194,330; NR | Female Veterans responding to HSCR 3 or more times with initial housing stability | 49.6 yrs.; 100% female; 61.1 White (non-Hispanic) | Positive screen on HSCR | Marital status; Combat exposure; Disability rating; Discharge status; Military sexual trauma; OEF/OIF/OND service era; Chronic medical condition; Mental health diagnoses; Suicide or self-harm; Alcohol use disorder; Drug use disorder
Naifeh 2022^15^ | N=6,837; NR | Veterans responding to 2 Army STARRS surveys | NR; 82.6% male; 67.3% White (non-Hispanic) | STARRS survey question modified from HSCR | Discharge status
Rosenheck 1994^10^ | N=1,523; NR | Male Vietnam War era Veterans | NR | Study survey question | Marital status; Minority/ethnic racial group; Combat exposure; Participation in atrocities; Mental health diagnoses; Adult non-military trauma; Substance abuse; ACEs
Tsai 2017^11^ | N=306,351; 12 mos. | Veterans referred to specialty mental health clinics | NR (27% 56–65 yrs.); 93.7% male; 60.3% White | ICD-9 code, participation in VA homelessness services, or specialty bed selection codes for homeless Veterans | Age; Marital status; Race; Major depression/dysthymia; Income; Alcohol use disorder; Drug use disorder

Abbreviations. ACEs=adverse childhood experiences; Dec.=December; HIV=human immunodeficiency virus; HS=high school; HSCR=homelessness screening clinical reminder; HUD-VASH=Housing and Urban Affairs Veterans Affairs Supportive Housing; ICD=International Classification of Diseases; MH=mental health; mos.=months; NR=not reported; OEF=Operation Enduring Freedom; OIF=Operation Iraqi Freedom; OND=Operation New Dawn; PTSD=posttraumatic stress disorder; SC=service connected; STARRS=Study to Assess Risk and Resilience in Servicemembers; TBI=traumatic brain injury; VA=Veterans Affairs; VHA=Veterans Health Affairs; yrs.=years.

## PRE-SERVICE FACTORS ASSOCIATED WITH HOMELESSNESS

### Childhood and Adolescent Factors Studied in the General Population

Adverse childhood experiences (ACEs), which are more common among economically disadvantaged and racial/ethnic minority populations, are associated with a range of negative health and social outcomes^78^ and are frequently reported among adults experiencing homelessness (Table 2).^46,47,79^ One meta-analysis^46^ found that nearly 90% of adults experiencing homelessness reported 1 or more ACEs and more than 50% reported 4 or more ACEs. Another meta-analysis^47^ reported that adults who experienced childhood sexual, physical, or emotional abuse, family or parental problems, or foster care were more likely to experience homelessness than adults who did not experience those events in childhood.

Table 2 Adverse Childhood Experiences Associated with Homelessness

Review | Timeframe for Eligible Studies | # Included Studies^a^ | ACE (# studies^b^) | Findings
Liu 2021^46^ | Through Nov. 2020^c^ | 29 (Cross-sectional) | 1 or more ACEs^d^ (20) | Prevalence=89.8%, 95% CI [83.7, 93.7]
Liu 2021^46^ | Through Nov. 2020^c^ | 29 (Cross-sectional) | 4 or more ACEs^d^(15) | Prevalence=53.9%, 95% CI [45.0, 61.7]
Nilsson 2019^47^ | Through Jan. 2018^c^ | 134 (Cross-sectional) | Sexual abuse (10) | OR=1.9, 95% CI [1.3, 2.8)]
Nilsson 2019^47^ | Through Jan. 2018^c^ | 134 (Cross-sectional) | Physical abuse (11) | OR=2.9, 95% CI [1.8, 4.4]
Nilsson 2019^47^ | Through Jan. 2018^c^ | 134 (Cross-sectional) | Emotional abuse (3) | OR=2.4, 95% CI [1.6, 3.5]
Nilsson 2019^47^ | Through Jan. 2018^c^ | 134 (Cross-sectional) | Family/parental problems (17) | OR=2.3, 95% CI [1.7, 3.0]
Nilsson 2019^47^ | Through Jan. 2018^c^ | 134 (Cross-sectional) | Foster care/change of carer (13) | OR=3.7, 95% CI [1.9, 7.3]

Notes.

a Total number of included studies in the review.

b Number of studies included in meta-analysis for each exposure.

c No limit on start date of search for eligible studies.

d Includes physical abuse; sexual abuse; emotional, verbal, or psychological abuse; neglect; exposure to domestic violence; household mental illness; household criminal justice involvement; parental separation or divorce; separation from family; parental death.

### Childhood and Adolescent Factors Studied in Veterans

A single longitudinal study^10^ from 1994 examined the impact of childhood and adolescent experiences on the risk of future homelessness among male Vietnam Veterans. Surveys from the National Vietnam Veterans Study showed an increased risk for experiencing homelessness among male Vietnam Veterans who experienced childhood poverty (RR=1.9, 95% CI [1.3, 2.7]), childhood physical or sexual abuse (RR=3.1, 95% CI [2.0, 4.6]), parental mental illness (RR=1.3, 95% CI [0.9, 1.9], not significant), other childhood trauma (RR=2.3, 95% CI [1.4, 2.6]), childhood psychiatric treatment (RR=6.5, 95% CI [1.9, 22.5]), or foster care (RR=5.3, 95% CI [2.0, 14.2]). Similarly, several cross-sectional studies^18–20^ reported increased odds of experiencing homelessness among Veterans who experienced ACEs. Lifetime trauma experience was also associated with an increased odds of experiencing homelessness among Veterans in 2 cross-sectional studies.^19,33^

The longitudinal study^10^ of male Vietnam Veterans also found an increased risk for experiencing homelessness among those with a history of a conduct disorder in childhood or adolescence (RR=2.7, 95% CI [1.8, 4.0]). In this study, conduct disorder was defined by behaviors occurring before the age of 15 such as “being in trouble with the law or school officials, playing hooky, being suspended or expelled from school, or doing poorly academically,” a definition that is notably distinct from the current definition for conduct disorder according to the Diagnostic and Statistical Manual of Mental Disorders (DSM)-5.^80^ Therefore, findings from this study on the risk of homelessness associated with childhood or adolescent conduct disorder may have narrow applicability and may not be generalizable to individuals diagnosed using contemporary criteria.

## DURING SERVICE RISK FACTORS FOR HOMELESSNESS IN VETERANS

### Combat Exposure

Whether combat exposure increased the risk of experiencing homelessness varied across 5 studies, making the overall impact of combat exposure on the risk of homelessness unclear (Table 3).^1,7–10^ One retrospective cohort study^1^ based on VHA administrative data found that post-9/11 Veterans who had been discharged from the miliary due to misconduct had an increased odds of experiencing homelessness if they had been exposed to combat. Likewise, male Vietnam Veterans with high combat exposure (measured on a scale of combat exposure ranging from 0 to 14) were at an increased risk of experiencing homelessness compared to those with no combat exposure in a study^10^ from 1994. However, 2 recent retrospective cohort studies based on responses to VHA’s universal screening question related to housing instability had conflicting findings.^8,9^ In the largest study of more than 4 million Veterans, combat exposure was associated with a lower adjusted odds of homelessness, while another retrospective cohort study specific to female Veterans found no difference in the adjusted odds of experiencing homelessness based on a history of combat. In addition, a recent retrospective cohort study of Veterans diagnosed with Alzheimer’s disease and related dementias found that Veterans with a history of combat had a lower risk of homelessness based on ICD-9/10 codes.^7^

Table 3 Combat Exposure and Homelessness in Veterans

Study; Sample size | Population | Comparison | Estimate
Brignone 2018^1^; N=18,784 | Misconduct-discharged Veterans deployed to post-9/11 conflicts in Iraq and Afghanistan | Combat exposure vs no combat exposure | aOR=1.33, 95% CI [1.24, 1.44]
Jutkowitz 2021^7^; N=383,478 | Veterans with a diagnosis of Alzheimer’s disease and related dementias | Combat exposure vs no combat exposure | aHR=0.69, 95% CI [0.62, 0.78]
Montgomery 2020^8^; N=4,633,069 | Veterans responding the HSCR 2 or more times | Combat exposure vs no combat exposure | aOR=0.87, 95% CI [0.84, 0.89]
Mulcahy 2021^9^; N=194,069 | Female Veterans responding to HSCR 3 or more times with initial housing stability | Combat exposure vs no combat exposure | aOR=0.98, 95% CI [0.80, 1.19]
Rosenheck 1994^10^; N=1,523 | Male Vietnam war era Veterans | High level of combat exposure vs no combat exposure | RR=2.1, 95% CI [1.5, 3.0]

Notes. Boldface indicates statistically significant finding.

Abbreviations. aOR=adjusted odds ratio; aPR=adjusted prevalence ratio; CI=confidence interval; HSCR=homelessness screening clinical reminder; HUD-VASH=Housing and Urban Development-VA Supported Housing; RR=risk ratio; VHA=Veterans Health Administration.

### VA Service-connected Disability Rating

Veterans with a higher VA service-connected disability rating (which confers financial compensation) had a lower odds of experiencing homelessness compared to those with a lower rating or no service connected-disability rating across 6 studies (Table 4). Findings were statistically significant except in a comparison of female Veterans with a 10–40% service-connected disability rating compared to those without a service-connected disability, in which the risk of experiencing homelessness was similar.^9^

Table 4 VA Disability Rating and Homelessness in Veterans

Study; Sample size | Population | Comparator | Estimate
Brignone 2018^1^; N=19,794 | Misconduct-discharged Veterans deployed to post-9/11 conflicts in Iraq and Afghanistan | NSC | SC 0–49%: aOR=0.88, 95 % CI [0.8, 0.97]; SC 50–100%: aOR=0.51, 95% CI [0.46, 0.56]
Byrne 2015^4^; N=17,720 | Veterans responding to the HSCR at VHA healthcare facilities | SC≥50% | NSC: aOR=1.79, 95% CI [1.49, 2.15]; NSC with VA pension ^a^ : aOR=3.09, 95% CI [2.36, 4.05]; SC<50%: aOR=1.44, 95% CI [1.17, 1.77]
Fargo 2017^6^; N=449,329 | OEF/OIF Veterans discharged as of Dec. 2011 | NSC | 1^st^ VHA encounter to 1 yr.:; SC<50%: aHR=0.62, 95% CI [0.56, 0.68]; SC≥50%: aHR=0.5, 95% CI [0.44, 0.57]; 1–5 yrs. after 1^st^ encounter:; SC<50%: aHR=0.72, 95% CI [0.68, 0.77]; SC≥50%: aHR=0.71, 95% CI [0.67, 0.76]
Jutkowitz 2021^7^; N=383,478 | Veterans with a diagnosis of Alzheimer’s disease or related diagnoses | Other than Priority Group 1^b^ | SC≥50% (Priority Group 1): aHR=0.54, 95% CI [0.49, 0.60]
Montgomery 2020^8^; N=4,633,069 | Veterans responding to HSCR at VHA health care facilities | NSC with VA pension | NSC: aOR=0.68, 95% CI [0.66, 0.71]; SC<50%: aOR=0.46, 95% CI [0.44, 0.48]; SC≥50%: aOR=0.56, 95% CI [0.52, 0.61]
Mulcahy 2021^9^; N=194,330 | Female Veterans responding to HSCR 3 or more times with initial housing stability | NSC | SCD 10–40%: aOR=1.11,95% CI [0.97, 1.27]; SCD 50–100%: aOR=0.74, 95% CI [0.67, 0.85]

Notes. Boldface indicates statistically significant finding.

a Non-service connected: VA pension is a needs-based benefit program for wartime Veterans who are age 65 or older or have a permanent and total non-service-connected disability, and who have limited income and net worth.

b Priority Group 1: Service-connected disability rated as 50% or more disabling; service-connected disability that makes you unable to work; or receipt of the Medal of Honor.

Abbreviations. aHR=adjusted hazard ratio; aOR=adjusted odds ratio; HSCR=homelessness screening clinical reminder; HUD-VASH=Housing and Urban Development-VA Supported Housing; NSC=not service connected; OEF/OIF=Operation Enduring Freedom/Operation Iraqi Freedom; SC=service connected; VHA=Veterans Health Administration; yr.=year.

### Discharge Status

Five cohort studies^2,6,9,14,15^ found that, in most cases, any discharge status aside from honorable was associated with an increased odds of experiencing homelessness (Table 5). The magnitude of effect was greatest among Veterans with dishonorable, other than honorable, or misconduct discharge status and more pronounced in males compared to females, based on 1 study^2^ that stratified results by gender. Additionally, 2 cohort studies^6,14^ found that, compared to routine discharge, disability discharge was associated with a similar or lower risk or odds of experiencing homelessness at the time of their first VHA encounter but a higher risk within 5 years.

Table 5 Discharge Status and Homelessness in Veterans

Study; Sample size | Population | Comparator | Estimate
Fargo 2017^6^; N=449,329 | OEF/OIF Veterans discharged as of Dec. 2011 | Routine discharge | 1^st^ encounter to 1 yr.:; Disability discharge: aHR=0.86, 95% CI [0.70, 1.06]; 1–5 yrs. after 1^st^ encounter:; Disability discharge: aHR=1.41, 95% CI [1.11, 1.79]
Gundlapalli 2015^14^; N=448,329 | Veterans deployed in Afghanistan or Iraq | Routine discharge | 1^st^ VHA encounter:; Disability discharge: aOR=0.6, 95% CI [0.4, 0.8]; Misconduct discharge: aOR=4.7, 95% CI [4.1, 5.5]; Within 1 yr. of 1^st^ encounter:; Disability discharge: aOR=1.3, 95% CI [1.1, 1.4]; Misconduct discharge: aOR=6.9, 95% CI [6.4, 7.5]; Within 5 yrs. of 1^st^ encounter:; Disability discharge: aOR=1.6, 95% CI [1.4, 1.7]; Misconduct discharge: aOR=6.3, 95% CI [5.7, 6.9]
Metraux 2013^2^; N=310,685 | Veterans discharged between 2005–2006 | Honorable discharge | OEF/OIF Veterans:; Dishonorable/bad conduct: aHR=1.79, 95% CI [0.25, 12.7]^a^; Other than honorable: aHR=2.37, 95% CI [1.93, 2.92] male; aHR=0.76, 95% CI [0.11,5.42] female; Not OEF/OIF Veterans:; Dishonorable/bad conduct: aHR=8.18, 95% CI [4.07, 16.45] male; aHR=3.4, 95% CI [0.47, 24.41] female; Other than honorable: aHR=5.39, 95% CI [4.23, 6.86] male; aHR=2.91, 95% CI [1.43, 5.95] female
Mulcahy 2021^9^; N=194,330 | Female Veterans responding to HSCR 3 or more times with initial housing stability | Non-honorable discharge | Honorable discharge: aOR=0.63, 95% CI [0.49, 0.82]
Naifeh 2022^15^; N=6,837 | Veterans responding to 2 Army STARRS surveys | Honorable discharge | General (under honorable conditions): aHR=1.4, 95% CI [0.8, 2.3]; Other than honorable/bad conduct/ dishonorable: aHR= 4.4, 95% CI [2.3, 8.3)]

Notes. Boldface indicates statistically significant finding.

a Males only, data for females not reported.

Abbreviations. aHR=adjusted hazard ratio; aOR=adjusted odds ratio; Army STARRS=Army Study to Assess Risk and Resilience in Servicemembers; HSCR=homelessness screening clinical reminder; OEF/OIF=Operation Enduring Freedom/Operation Iraqi Freedom; VHA=Veterans Health Administration; yr.=year.

### Military Sexual Trauma

Veterans who reported military sexual trauma had an increased odds of experiencing homelessness across 4 cohort studies^1,3,8,9^ (Table 6). This finding was consistent across studies of different Veteran populations (eg, OEF/OIF Veterans, misconduct-discharged Veterans, female Veterans only), and in 1 study^1^ was consistent over 5 years (although the magnitude of effect decreased with time).

Table 6 Military Sexual Trauma and Homelessness in Veterans

Study; Sample size | Population | Estimate
Brignone 2016^3^; N=601,892 | OEF/OIF Veterans separated between 2001 and 2011 | Within 30 days of 1^st^ VHA encounter:; aOR=1.62, 95% CI [1.36, 1.93]; Within 1 yr. of 1^st^ encounter:; aOR=1.49, 95% CI [1.33, 1.66]; Within 5 yrs. of 1^st^ encounter:; aOR=1.39, 95% CI [1.24, 1.55]
Brignone 2018^1^; N=19,794 | Misconduct-discharged Veterans deployed to post-9/11 conflicts in Iraq and Afghanistan | aOR=1.65, 95% CI [1.4, 1.95]
Montgomery 2020^8^; N=4,633,069 | Veterans responding to the HSCR at VHA healthcare facilities | aOR=1.63, 95% CI [1.58, 1.68]
Mulcahy 2021^9^; N=194,330 | Female Veterans responding to HSCR 3 or more times with initial housing stability | aOR=1.57, 95% CI [1.42, 1.75]

Notes. Boldface indicates statistically significant finding.

Abbreviations. aOR=adjusted odds ratio; HSCR=homelessness screening clinical reminder; OEF/OIF=Operation Enduring Freedom/Operation Iraqi Freedom; VHA=Veterans Health Administration; yr.=year.

### Other Service-related Factors

Other aspects of military service have been studied as possible risk factors for homelessness. Two cross-sectional studies^19,22^ found a correlation between experiencing homelessness and enlisted status (compared to being drafted and/or commissioned). In contrast, higher military pay grade was associated with a decreased odds of experiencing homelessness in 3 cohort studies,^1–3^ and higher number of years of military service was correlated with decreased homelessness in 3 cross-sectional studies.^18,19,22^ Among 3 cohort studies^4,8,9^ comparing OEF/OIF Veterans to non-OEF/OIF Veterans, no differences in homelessness were reported. Similarly, deployment frequency was not associated with experiencing homelessness in 2 cross-sectional studies.^19,22^ Findings regarding the association of service branch and homelessness risk were inconsistent. In a longitudinal study^1^ of post-9/11 Veterans discharged for misconduct, the odds of experiencing homelessness were lower among Navy and Air Force Veterans compared to Army Veterans, but similar between Army and Marine Veterans. However, in 2 other longitudinal studies^2,3^, the odds of experiencing homelessness were generally lower among Marines and Air Force Veterans compared to Army Veterans, but higher among Navy compared to Army Veterans.

## POST-SERVICE RISK FACTORS FOR HOMELESSNESS IN VETERANS

### General Medical Conditions

The impact of medical conditions on homelessness risk, if any, is unclear (Table 7). Two longitudinal studies^8,9^ examining the odds of homelessness with the presence of any chronic medical condition had inconsistent findings. A single cohort study^12^ reported no difference in homelessness among Veterans with and without (human immunodeficiency virus) HIV. Two cohort studies^2,7^ reported no difference in homelessness among Veterans with traumatic brain injury (TBI), with the exception of a single subgroup of non-OEF/OIF male Veterans, for which an increased risk of experiencing homelessness was observed. In a cohort study^7^ of Veterans with Alzheimer’s disease and related dementias, renal disease was associated with lower odds of experiencing homelessness while liver disease, lung disease, and hypertension were associated with higher odds. Findings from cross-sectional studies^24,29,30,32,52,55,69^ were mixed on the association between homelessness and obesity, dementia, and inpatient, emergency room, or outpatient medical visits.

Table 7 Medical Conditions and Homelessness in Veterans

Study; Sample size | Population^a^ | Comparison | Estimate
Ghose 2013^12^; N=28,383 | HIV-infected and uninfected patients seen in VHA infectious disease and general medical clinics | HIV+ vs HIV− | aOR=0.97, 95% CI [0.72, 1.32]
Jutkowitz 2021^7^; N=383,478 | Veterans with a diagnosis of Alzheimer’s disease and related dementias | Presence vs absence of specific disease | Rheumatic disease: aHR=0.99, 95% CI [.073, 1.34]; Renal disease: aHR=0.78, 95% CI [0.67, 0.90]; Liver disease: aHR=1.24, 95% CI [1.06, 1.45]; Diabetes: aHR=1.08, 95% CI [0.98, 1.18]; Hypertension: aHR=1.22, 95% CI [1.12, 1.33]; CHF: aHR=0.95, 95% CI [0.82, 1.11]; Lung disease: aHR=1.12, 95% CI [1.02, 1.24]; TBI: aHR=0.98, 95% CI [0.86, 1.13]; Valvular disease: aHR=0.91,95% CI [0.74, 1.11]; Stroke: aHR=0.95, 95% CI [0.85, 1.05]
Metraux 2013^2^; N=310,685 | Veterans discharged between 2005–2006 | TBI vs no TBI | OEF/OIF Veterans:; aHR=1.2, 95% CI [0.98, 1.46] male; aHR=1.23, 95% CI [0.54, 2.79] female; Not OEF/OIF Veterans:; aHR=1.59, 95% CI [1.18, 2.15] male; aHR=1.64, 95% CI [0.85, 3.2] female
Montgomery 2020^8^; N=4,633,069 | Veterans responding to HSCR at VHA healthcare facilities | Any vs no chronic medical condition | aOR=0.88, 95% CI 0.81, 0.90]
Mulcahy 2021^9^; N=194,069 | Female Veterans responding to HSCR 3 or more times with initial housing stability | Any vs no chronic medical condition | aOR=1.03, 95% CI [0.91, 1.16]

Notes. Bolding of data indicates a statistically significant finding.

a Presence of medical conditions determined from VA records.

Abbreviations. aHR=adjusted hazard ratio; aOR=adjusted odds ratio; CHF=congestive heart failure; HIV=human immunodeficiency virus; HSCR=homelessness screening clinical reminder; HUD-VASH=Housing and Urban Development-VA Supported Housing; TBI=traumatic brain injury; VHA=Veterans Health Administration.

### Mental Health

Most longitudinal studies found that posttraumatic stress disorder (PTSD), depression, and psychoses or psychotic disorders were associated with an increased odds of experiencing homelessness (Table 8). Among 7 studies^1,2,7–10,12^ examining Veterans with PTSD, 6 reported an increased odds of experiencing homelessness among Veterans with PTSD compared to those without. Similarly, 5 studies^7–9,11,12^ examining Veterans with depression and 4 out of 5 studies^2,7–9,12^ examining Veterans with schizophrenia or other psychotic disorders reported increased odds of experiencing homelessness among Veterans with these disorders. Additionally, the presence of any mental health diagnosis was associated with an increased odds of homelessness among 3 studies^3,6,13^ and among misconduct-discharged Veterans,^1^ higher mental health clinic usage (assumed to be a surrogate marker of having a mental health diagnosis) was associated with an increased odds of experiencing homelessness.

Findings were less consistent for other mental health conditions and having a history of a suicide attempt or self-inflicted harm. A single study^2^ reported mixed effects on the risk of homelessness among Veterans with adjustment disorders, anxiety disorders, mood disorders, and personality disorders, and associations varied by gender and service era. A large study^8^ (N = 4,633,069) based on VHA administrative data found an increased odds of experiencing homelessness among Veterans with a history of a suicide attempt or self-inflicted harm. However, another large cohort study^9^ based on the same data source but limited to female Veterans found no difference in homelessness risk according to a history of a suicide attempt or self-inflicted harm.

Table 8 Mental Health and Homelessness in Veterans

Mental Health Factor^a^ | Study; Sample Size | Estimate^b^
Adjustment disorders | Metraux 2013^2^; N=310,685 | OEF/OIF Veterans:; aHR=1.53, 95% CI [1.37, 1.71] male; aHR=1.28, 95% CI [0.96, 1.71] female; Not OEF/OIF Veterans:; aHR=1.45, 95% CI [1.23, 1.72] male; aHR=1.6, 95% CI [1.27, 2.05] female
Anxiety disorders | Metraux 2013^2^; N=310,685 | OEF/OIF Veterans:; aHR=1.03, 95% CI [0.9, 1.18] male; aHR=0.92, 95% CI [0.65, 1.31] female; Not OEF/OIF Veterans:; aHR=1.38, 95% CI [1.15, 1.67] male; aHR=1.02, 95% CI [0.77, 1.36] female
Depression | Ghose 2013^12^; N=28,383 | aOR=1.55, 95% CI [1.01, 2.36]
Depression | Jutkowitz 2021^7^; N=1,523 | aHR=1.41,95% CI [1.30, 1.53]
Depression | Montgomery 2020^8^; N=194,330 | aOR=1.36, 95% CI [1.33, 1.39]
Depression | Mulcahy 2021^9^; N=383,478 | aOR=1.74, 95% CI [1.52, 1.99]
Depression | Tsai 2017^11^; N=306,351 | aOR=1.21, 95% CI [1.16, 1.26]
Mental health clinic usage | Brignone 2018^1^; N=19,794 | aOR=1.85, 95% CI [1.69, 2.02]
Mental health diagnoses (any) | Brignone 2016^3^; N=601,892 | Within 30 days of 1^st^ VHA encounter: aOR=3.91, 95% CI [3.67, 4.16]; Within 1 yr. of 1^st^ encounter: aOR=5.31,95% CI [5.08, 5.54]; Within 5 yrs. of 1^st^ encounter: aOR=8.15, 95% CI [7.64, 8.70]
Mental health diagnoses (any) | Elbogen 2013^13^; N=1,090 | aOR=2.59, 95% CI [1.26, 5.33]
Mental health diagnoses (any) | Fargo 2017^6^; N=449,329 | 1^st^ VHA encounter to 1 yr.:; aHR=3.66, 95% CI [3.36, 3.99]; Within 1–5 yrs. of 1^st^ encounter:; aHR=4.78, 95% CI [4.23, 5.15]
Mood disorders (any) | Metraux 2013^2^; N=310,685 | OEF/OIF Veterans:; aHR=1.41,95% CI [1.25, 1.59] male; aHR=1.31,95% CI [0.96, 1.77] female; Not OEF/OIF Veterans:; aHR=1.62, 95% CI [1.37, 1.92] male; aHR=1.79, 95% CI [1.4, 2.29] female
Personality disorders (any) | Metraux 2013^2^; N=310,685 | OEF/OIF Veterans:; aHR=1.46, 95% CI [1.24, 1.72] male; aHR=1.49, 95% CI [1.0, 2.22] female; Not OEF/OIF Veterans:; aHR=1.39, 95% CI [1.12, 1.73] male; aHR=1.05, 95% CI [0.74, 1.49] female
Psychiatric disorders (any) | Rosenheck 1994^10^; N=1,523 | RR=3.7, 95% CI [2.6, 5.4]
Psychotic disorders or psychoses | Ghose 2013^12^; N=28,383 | Schizophrenia: aOR=1.27, 95% CI [0.6, 1.75]
Psychotic disorders or psychoses | Jutkowitz 2021^7^; N=1,523 | Psychoses: aHR=1.63, 95% CI [1.49, 1.77]
Psychotic disorders or psychoses | Metraux 2013^2^; N=310,685 | Psychotic disorders:; OEF/OIF Veterans:; aHR=1.57, 95% CI [1.22, 2.04] male; aHR=4.22, 95% CI [2.16, 8.23] female; Not OEF/OIF Veterans:; aHR=2.66, 95% CI [2.04, 3.47] male; aHR=3.18, 95% CI [1.87, 5.39] female
Psychotic disorders or psychoses | Montgomery 2020^8^; N=194,330 | Schizophrenia: aOR=1.02, 95% CI [0.99, 1.06]; Other psychoses: aOR=1.32, 95% CI [1.28, 1.35]
Psychotic disorders or psychoses | Mulcahy 2021^9^; N=383,478 | Psychoses: aOR=1.37, 95% CI [1.06, 1.78]
PTSD | Brignone 2018^1^; N=19,794 | aOR=1.25, 95% CI [1.14, 1.36]
PTSD | Ghose 2013^12^; N=28,383 | aOR=1.03, 95% CI [0.59, 1.72]
PTSD | Jutkowitz 2021^7^; N=1,523 | aHR=1.26, 95% CI [1.13, 1.40]
PTSD | Metraux 2013^2^; N=310,685 | OEF/OIF Veterans:; aHR=1.24, 95% CI [1.09, 1.41] male; aHR=1.57, 95% CI [1.09, 2.26] female; Not OEF/OIF Veterans:; aHR=0.78, 95% CI [0.54, 1.13] male; aHR=0.86, 95% CI [0.55, 1.34] female
PTSD | Montgomery 2020^8^; N=194,330 | aOR=1.11, 95% CI [1.08, 1.14]
PTSD | Mulcahy 2021^9^; N=383,478 | aOR=1.49, 95% CI [1.27, 1.75]
PTSD | Rosenheck 1994^10^; N=1,523 | RR=5.0, 95% CI [3.5, 7.2]
Suicide or self-harm | Montgomery 2020^8^; N=194,330 | aOR=1.21, 95% CI [1.16, 1.27]
Suicide or self-harm | Mulcahy 2021^9^; N=383,478 | aOR=0.93, 95% CI [0.64, 1.33]

Notes. Bolding of data indicates a statistically significant finding.

a Mental health disorders most commonly determined from VA medical records.

b Comparison is the presence versus the absence of the mental health factor.

Abbreviations. aHR=adjusted hazard ratio; aOR=adjusted odds ratio; aPR=adjusted prevalence ratio; OEF/OIF=Operation Enduring Freedom/Operation Iraqi Freedom; OND=Operation New Dawn; PTSD=posttraumatic stress disorder; RR=risk ratio; VHA=Veterans Health Administration; yr.=year.

### Substance Use

Substance use was generally associated with an increased odds of experiencing homelessness across studies (Table 9). Five cohort studies^7–9,11,12^ found that alcohol use disorder or alcohol dependence was associated with an increased odds of experiencing homelessness among Veterans. Likewise, 5 cohort studies^8,9,11,12^ reported an increased odds of experiencing homelessness with drug use disorder, weekly illicit substance use, or opioid use disorder (measures that likely overlap but were defined differently in each study). Similarly, 3 studies^2,7,10^ reported an increased risk of experiencing homelessness with substance use generally or substance use disorder. Higher substance use clinic usage (assumed to be a surrogate marker of having a substance use disorder diagnosis) was also associated with an increased odds of experiencing homelessness.^1,8,16^ Among cross-sectional studies, inpatient substance abuse clinic treatment^29,30^ was associated with homelessness. Tobacco use or dependence^19,24,31,32^ was generally associated with an increased odds of experiencing homelessness, although in 1 study^24^ the effect was no longer significant in an adjusted model.

Table 9 Substance Use and Homelessness in Veterans

Substance Use Factor^a^ | Study | Estimate^b^
Alcohol use disorder | Ghose 2013^12^; N=28,383 | Alcohol dependence: aOR=1.72, 95% CI (1.06, 2.81)
Alcohol use disorder | Jutkowitz 2021^7^; N=1,523 | aHR=1.87, 95% CI (1.67, 2.10)
Alcohol use disorder | Montgomery 2020^8^; N=194,330 | aOR=1.26, 95% CI (1.22, 1.30)
Alcohol use disorder | Mulcahy 2021^9^; N=383,478 | aOR=1.49, 95% CI (1.13, 1.98)
Alcohol use disorder | Tsai 2017^11^; N=306,351 | aOR=1.48, 95% CI (1.40, 1.56)
Drug use disorder | Ghose 2013^12^; N=28,383 | Weekly illicit substance use: aOR=1.54, 95% CI (1.08, 2.19)
Drug use disorder | Montgomery 2020^8^; N=194,330 | aOR=1.50, 95% CI (1.45, 1.55)
Drug use disorder | Mulcahy 2021^9^; N=383,478 | aOR=1.77, 95% CI (1.34, 2.35)
Drug use disorder | Tsai 2017^11^; N=306,351 | aOR=2.48, 95% CI (2.34, 2.62)
Opioid use disorder | Montgomery 2020^8^; N=194,330 | aOR=2.22, 95% CI (2.04, 2.41)
Substance use | Jutkowitz 2021^7^; N=1,523 | aHR=2.15, 95% CI (1.84, 2.53)
Substance use | Rosenheck1994^10^; N=1,523 | RR=3.4, 95% CI (2.3, 4.9)
Substance use | Metraux 2013^2^; N=310,685 | OEF/OIF Veterans:; aHR=2.59, 95% CI (2.33, 2.87) male; aHR=1.85, 95% CI (1.28, 2.67) female; Not OEF/OIF Veterans:; aHR=2.72, 95% CI (2.34, 3.16) male; aHR=2.03, 95% CI (1.47, 2.82) female
Substance use clinic usage | Gundlapalli 2014^16^; N=31,260 | Mean increase in encounters:; 61–90 days: 1.00 (p NS); 91–180 days: 1.86 (p<0.001); 180–365 days: 1.94 (p<0.001); 1–2 yrs.: 1.98 (p<0.001)
Substance use clinic usage | Brignone 2018^1^; N=19,794 | aOR=2.38, 95% CI (2.12, 2.67)

Notes. Bolding of data indicates a statistically significant finding.

a Substance use disorders most commonly determined from VA records.

b Comparison is the presence versus the absence of the substance use factor.

Abbreviations. aHR=adjusted hazard ratio; aOR=adjusted odds ratio; aPR=adjusted prevalence ratio; OEF/OIF=Operation Enduring Freedom/Operation Iraqi Freedom; OND=Operation New Dawn; RR=risk ratio; yrs.=years.

### Other Post-service Factors

Other post-service factors have been studied for their associations with homelessness, with findings limited to a single or few studies. One longitudinal study^13^ reported an increased odds of experiencing homelessness among Veterans with a history of incarceration. Likewise, experience of adult non-military trauma was associated with an increased odds of experiencing homelessness in a single study.^10^

## DEMOGRAPHIC CHARACTERISTICS AND HOMELESSNESS IN VETERANS

Demographic factors, some of which span service timeframes (eg, gender, race/ethnicity), have been evaluated for associations with homelessness risk. Younger Veterans may have higher odds of experiencing homelessness based on 3 studies.^4,7,8^ However, 1 study^2^ found that OEF/OIF Veterans in older age groups had a higher odds of experiencing homelessness than those aged 18 to 24 years, and another study^11^ found that Veterans aged 46–55 years had a higher odds of experiencing homelessness compared to other age groups. Among 6 studies of gender,^1,3,4,7,8,12,17^ most reported that females had a lower odds of experiencing homelessness than males. However, 1 study^1^ in post-9/11 Veterans discharged for misconduct reported an increased odds of experiencing homelessness among females compared to males. Three cross-sectional studies^26–28^ reported an association between transgender identity and homelessness among Veterans.

Among 9 longitudinal studies^1,3,4,7,8,10–12^ examining racial disparities in homelessness among Veterans, most reported increased homelessness among Black Veterans compared to White Veterans. Increased homelessness was reported among Veterans with Hispanic ethnicity in 2 studies^3,8^ but no difference in homelessness by ethnicity was reported in 1 other study.^4,5^ Among 2 cross-sectional studies,^29,63^ mixed findings were reported on the association between Asian race and homelessness in Veterans.

Among 7 studies examining marital status,^1,3,7–11^ all but 1^1^ reported a lower odds of experiencing homelessness among married Veterans compared to those who were not married, including those who were never married, separated, or divorced. Two longitudinal studies^1,3^ reported that Veterans with a higher level of education had a decreased odds of experiencing homelessness. Similarly, among 7 cross-sectional studies,^18–24^ a higher level of education was generally negatively associated with homelessness among Veterans. Lower financial status and unemployment were associated with an increased odds of experiencing homelessness across 3 longitudinal^11–13^ and 3 cross-sectional^23–25^ studies. Lastly, living in a rural area was associated with a lower odds of experiencing homelessness among Veterans in 2 longitudinal studies.^7,8^