# METHODS

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42023418367 (http://www.crd.york.ac.uk/PROSPERO/)).

## KEY QUESTIONS

The following key questions below were the focus of this review:

Key Question 1 | Among Veterans and other adults, what factors during childhood and adolescence are associated with homelessness during adulthood?
Key Question 2 | Among Veterans, what factors during in-service and post-service periods are associated with post-service homelessness?

## ELIGIBILITY CRITERIA

Study eligibility criteria are shown in the table below. Given that early-life experiences may impact later risk for experiencing homelessness regardless of military service, studies addressing Key Question 1 (KQ1) could include Veterans or adults in the general population. Studies in the general (ie, non-Veteran) population were included only when they were synthesized in 1 or more existing systematic reviews. Relevant reviews were required to meet predefined methodological criteria to be included (see below for further detail). Key Question 2 (KQ2) was limited to studies conducted among Veterans.

Population | KQ1: US Veterans (any service era) and other adults experiencing homelessness; KQ2: US Veterans (any service era) experiencing homelessness
Exposures | Factors examined for associations with homelessness, including at the population and individual levels. Studies focused on interventions for homelessness will be ineligible.
Outcomes | Homelessness (defined as meeting US Department of Housing and Urban Development criteria, use of any specialized VA homeless services, or documented ICD-9/10 clinical code suggesting homelessness)
Study Design | Comparative and noncomparative studies (eg, cohort studies, case-control studies, cross-sectional survey studies)

## DATA SOURCES AND SEARCHES

To identify articles relevant to the key questions, a research librarian searched Ovid MEDLINE, PsycInfo, and SocIndex, as well as AHRQ, the Cochrane Database of Systematic Reviews, and HSR&D through March 2023 using terms for homelessness and Veterans (see Appendix A in Supplemental Materials for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts. We limited the search to published and indexed articles involving human subjects available in the English language. We did not limit the search by date. Study selection was based on the eligibility criteria described above. Studies examining interventions for homelessness were excluded. Titles, abstracts, and full-text articles were independently reviewed by 2 investigators. All disagreements were resolved by consensus or discussion with a third reviewer.

## DATA ABSTRACTION AND ASSESSMENT

Effect information and population and exposure characteristics were abstracted from all included studies. The internal validity (risk of bias) was rated using the Cochrane Risk of Bias Tool for Systematic Reviews^43^ and the Quality in Prognosis Studies (QUIPS)^44^ tool for primary studies. All data abstraction and internal validity ratings were first completed by 1 reviewer and then checked by another; disagreements were resolved by consensus or discussion with a third reviewer.

We graded the strength of the evidence for each exposure examined in longitudinal studies based on the AHRQ Methods Guide for Comparative Effectiveness Reviews.^45^ This approach provides a rating of confidence in reported findings based on study methodology (design and risk of bias), consistency (whether effects are in the same direction and have a consistent magnitude), precision (eg, confidence intervals), and directness (whether assessed outcomes are clinically important to patients and providers). For this review, we applied the following general algorithm: high strength evidence consisted of multiple, large studies with low risk of bias, consistent and precise findings, and clinically relevant outcomes; moderate strength evidence consisted of multiple studies with low to unclear risk of bias, consistent and precise findings, and clinically relevant outcomes; low strength evidence consisted of a single study, or multiple small studies, with unclear to high risk of bias, inconsistent or imprecise findings, and/or outcomes with limited clinical relevance; and insufficient evidence consisted of a single study with an unclear or high risk of bias or no available studies.

## SYNTHESIS

We employed a best-evidence approach to guide the final synthesis. We prioritized studies that measured potential risk or protective factors before homelessness occurred (eg, substance misuse occurring prior to homelessness), or examined factors that clearly preceded homelessness (eg, military discharge status among Veterans experiencing homelessness). Practically, this approach meant that we prioritized longitudinal studies over cross-sectional studies, though we highlighted findings from cross-sectional studies when at least 2 studies examined a factor that was not included in cohort studies. We did not rate the internal validity of cross-sectional studies or consider them in strength of evidence assessments.

Findings were organized by timeframe (pre-service, during service, post-service, and across timeframes) and synthesized narratively. We classified military discharge status and disability ratings as “during service” factors because they reflect Veterans’ military service experiences. Although mental health, substance use, and general medical conditions may span timeframes and precede or be exacerbated by military service, data on these factors were measured after miliary service and we classified them as “post-service.”

For each potential individual-level factor, we considered whether that factor had a strong or moderate association with homelessness based on the magnitude of the reported risk ratio, odds ratio, and/or hazard ratio. Strong factors were those with ratios generally above 2.5 and moderate factors had risk estimates ranging from 1.5 to 2.5. We designated factors with estimates that were generally below 1.5 or had nonsignificant or mixed findings as uncertain. The inverse of ratios less than 1 was calculated to determine whether strong or moderate ratings were applicable. Some cross-sectional studies reported correlations or tested differences in continuous outcomes, and we prioritized studies reporting ratios to determine moderate or strong associations if available.