# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) Coordinating Center is responding to a request from the VA Offices of Enterprise Integration (OEI) and Planning and Performance Management (OPPM), which have established an Integrated Project Team (IPT) on Homelessness. The IPT has requested a review of known risk factors for homelessness experienced by US Veterans during the pre-service, in-service, and post-service periods. Findings from this review will inform cross-VA efforts to better understand and address homelessness among Veterans.

## BACKGROUND

According to the US Department of Housing and Urban Development’s (HUD) national Point-in-Time (PIT) counts, more than 33,000 US Veterans experienced homelessness on a single night in 2022.^34^ Circumstances leading to homelessness are often complex because they can involve both community-level factors, such as local housing policies and market conditions, and factors at the individual level, such as having a mental health or substance use disorder.^35^ A social-ecological framework for understanding homelessness underscores that individual-level factors alone do not predict homelessness; rather, these factors characterize individuals who may be more vulnerable to broader societal and economic forces that create conditions of homelessness.^35,36^ Veterans may have unique individual-level vulnerabilities to homelessness, including those stemming from a history of combat exposure or experiences of military sexual trauma.^37^ They may also have unique protective factors, such as access to health care (including mental health care) and case management supports.

Although estimates of homelessness among Veterans have been declining since 2009 (the first year these data were reported), homelessness remains more common among Veterans compared to non-Veterans.^38,39^ In general, individuals experiencing homelessness have higher rates of premature mortality compared to the housed population.^40^ Veterans experiencing homelessness are more likely than other Veterans to utilize VA emergency departments^41^ and may be less likely to receive preventive care.^42^ Improved understanding of the community and individual-level factors that increase Veterans’ risk of homelessness, as well as factors that may be protective, is needed for VA programs and policies to progress toward ending Veteran homelessness. The aim of this systematic review is to synthesize evidence on factors associated with homelessness among Veterans to inform ongoing VA efforts to reduce and prevent Veteran homelessness and identify areas for future research.