# APPENDIX D PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | None
2 | 2 | Yes | None
3 | 3 | Yes | None
4 | 4 | Yes | None
5 | 5 | No - The review is, one discovers, focused narrowly on studies that produce relative risk estimates of homelessness at the individual level. This is a major choice. No one who thinks about homelessness would discount community factors, family wealth, rental markets, eviction rates, etc. These are “risk factors” at some conceptual level but they seem to sit outside the bounds of the review. It’s possible to speculate that there is a reason, along the lines of “they aren’t consistently measured at the individual level”, but I don’t really know that for sure. Ultimately I wind up with the sense that somehow the review focuses on “only things measured among individuals that can be squarely assigned to them and not their families or their communities or their housing opportunity structure” even though all those things matter a lot (and perhaps a lot MORE than the risk factors in this report).; Therefore I can’t fully say I understand why the scope of this review is what it is, save that it appears narrow, and so it’s not “clearly described” | Thank you for this comment. We conducted a broad literature search with the intent of identifying studies of any factors associated with homelessness among Veterans, including population-level factors and individual-level factors. However, we found that the evidence base specific to Veterans is limited to studies of individual-level factors. We have substantially revised the Background and Discussion sections to make the aim of this review clearer and highlight identified gaps in the literature. We have also added detail to our presentation of the Key Questions and Eligibility Criteria.
6 | 5 | Very secondary concern. Sometimes I think if “scope” as the timespan of the literature that was searched, ie back to 1946 or 1972 or 2010. I may have missed an account of this matter, but perhaps it should be affirmed in a few places. | Thank you for this comment. Our search timeframe is listed in our methods section and was not limited by date. We revised text in the Methods section to make this detail more evident.
7 | 6 | Yes | None
8 | 7 | Yes | None
9 | 8 | Yes | None
Is there any indication of bias in our synthesis of the evidence?
10 | 1 | No | None
11 | 2 | No | None
12 | 3 | No | None
13 | 4 | No | None
14 | 5 | Yes - I will explain this in the detailed comments. Somehow this review narrows the question to “relative risk” and not “absolute risk” and it imposes a medicalizing framework on the problem of homelessness. Readers will be nudged to understand homelessness as a bit like diabetes, a disease or a trait that befalls certain individuals based on their bad experiences or medical diagnoses. There are a few passages that appear in the synthesis that suggest the authors understand this is something of a limitation, but they are modest and don’t really expose just how great the distortion really is. The fact that this document bears the title “Evidence Synthesis Review” strongly conveys a notion that this is a true synthesis of a large problem, and perhaps under another title the apparent bias would seem less concerning. | Thank you for this comment. We provide a synthesis of the available evidence on this topic, according to the scope as defined by our Key Questions and study eligibility criteria. In response to this comment and similar comments made by this reviewer, we revised the Background and Discussions sections to more clearly state that population and individual-level factors impact homelessness risk (rather than individual factors alone) and that the lack of evidence regarding population-level factors among Veterans is an important gap.
15 | 6 | No | None
16 | 7 | No | None
17 | 8 | No | None
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
18 | 1 | No | None
19 | 2 | No | None
20 | 3 | No | None
21 | 4 | No | None
22 | 5 | Yes - Many studies that attempt to look at community determinants of homelessness are absent. I have not attempted to review all such community determinant literature but cite several in the detailed comments. Obviously, if the “scope of work” assigned to the evidence synthesis team did NOT include community factors, then it’s unfair to say they “overlooked” community factors. | Thank you for this comment. As discussed above, we would have included studies of community or population-level risk factors for homelessness among Veterans if we had found any. The lack of such studies is an important evidence gap.
23 | 6 | Yes - Koh KA, Montgomery AE, O’Brien RW, et al. Predicting Homelessness Among U.S. Army Soldiers No Longer on Active Duty. Am J Prev Med. 2022 Jul;63(1):13-23. doi: 10.1016/j.amepre.2021.12.028. Epub 2022 Apr 14. PMID: 35725125; PMCID: PMC9219110.; Koh et al 2022 used predictive modeling (with longitudinal cohort data) to identify premilitary, military, and postmilitary characteristics that predict homelessness among Army soldiers. Strengths include survey measures of mental health disorders (rather than diagnoses from administrative records) assessed prior to homeless experience, and the inclusion of community-level variables after military service. Koh et al’s study found the most important predictors of homelessness were lifetime mental health disorders (e.g., depression, PTSD), lifetime trauma (i.e., loved one murdered), adverse childhood experiences (i.e., childhood homelessness), and criminal involvement. Because the findings differ a bit from the conclusions of the synthesis review, and the discussion mentions a need for predictive modeling studies, it seems worthwhile to include this study as part of the review. Alternatively, if the authors feel this study does not meet the scope of the review, it may be worthwhile to cite as an example of a predictive modeling study in the discussion. | Thank you for this comment. We now cite this study by Koh et al. in the Future Research section as an example of a study that integrates individual and community-level factors when discussing homelessness. The study did not meet our inclusion criteria for evidence synthesis because it lacks outcome data on the specific factors examined (i.e. a risk ratio, odds ratio, and/or hazard ratio for each measured factor).
24 | 7 | No | None
25 | 8 | No | None
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
26 | 1 | Yes, I think the review was good. I do think it is hard to capture and measure mental health and substance use problems preceding episodes of homelessness. So many studies capture mental and substance issues concurrently or are based on cross-sectional studies. I felt the report underplayed the potential effects of MH and SUDs, which I understand is due to lack of prospective studies. The consistent factors they found may have the most evidence, but may not be the strongest risk factors for veteran homelessness. It would be good to do some type of file-drawer calculation or have some discussion about how some risk factors are harder/easier to study than others so which factors are identified can be biased that way and they may not speak to the magnitude of these factors. | Thank you for this comment. While we did not expand on our discussion of mental health and substance use disorders as risk factors for homelessness specifically, we have substantially revised the Discussion and Limitation sections to highlight the challenges of measuring certain exposures.
27 | 2 | When reading the Executive Summary, my automatic thought was where is the information on impact of such things as housing availability, housing policies, poverty, financial literacy, legal (such as felonies) and military service in general on homelessness risk? Please see my below recommendation to potentially address the reason why such findings weren’t included. | Thank you for this comment. Please see our responses to comments from reviewer #5.
28 | 2 | Is there enough data to make this conclusion that no association between medical conditions and homelessness exist? | Thank you for this clarifying question. We did not conclude that no association between medical conditions and homelessness exists. Rather, we state that the relationship is unclear due to mixed findings among studies.
29 | 3 | Thank you for the opportunity to review this systematic review. Overall it is very well done. I found the tables particularly well laid out with valuable information. | Thank you.
30 | 3 | you do a very nice job talking about implications for future research, but do you have any policy or practice recommendations for the discussion section? | Thank you. Because the focus of this review was not on homelessness policy, but rather risk and protective factors, we refrain from making policy or practice recommendations. We defer to subject matter experts who are using this review to make such recommendations.
31 | 3 | page 15 paragraph 2 it talks about how homelessness was defined in the studies. It may be beneficial to say % of included studies that used this screening item/homeless service use/icd 10 codes to measure homelessness (i.e., x/62) | Thank you for this comment. We have added detail regarding how many of the longitudinal studies used ICD 9/10 codes to define homelessness.
32 | 3 | page 15 paragraph 3 lists several factors identified from cross-sectional studies. It may be helpful to list in descending order of how many studies addressed them or include the number of studies in parentheses that examined these factors or list in descending order of strength of association with homelessness | Thank you for this comment. We added citations to the list to make it clearer which and how many studies examined the specific factors. Most of the factors were supported by 2-3 studies.
33 | 3 | in limitations section it may be helpful to add a sentence or two that most of the cohort studies were retrospective and used VA administrative data to identify information and because of this some confounding variables were not collected or the timing isn’t as accurate | Thank you for this comment. We have added more detail to the Limitations section regarding the nature of the data obtained from medical records.
34 | 4 | Thorough review. This reviewer was expecting some discussion about how these risk factors could be considered to prevent homelessness, such as screening during discharge from the military, which could be considered. | Thank you for this comment. Because the focus of this review was not on homelessness policy, but rather risk and protective factors, we refrain from making policy or practice recommendations including relating to screening. We defer to subject matter experts who are using this review to make such recommendations.
35 | 5 | 1. Major: This review is narrow in ways that might reflect what was requested of the ESP, but also generates an unhelpfully constricted and potentially consequential misunderstanding of homelessness. To be specific, the document analyzes individual “risk factors” for a social condition. Of course, homelessness is not a disease, and not a static trait. Rather, it’s a state, the state of lacking a home, and it’s extremely dependent on community context. Homelessness can easily happen in the absence of “risk factors”, if (a) one is kicked out of one’s home and (b) no one else in your social network has extra rooms. Further, reliance on “relative risk factors” tends to opacify and hide just how little those risk factors matter when the absolute risk is tiny. Yes, losing a home is more common to befall a person with a few ACES and a drug problem, but the absolute risk is infinitesimal and ignorable if that person is well-off, White and in a community with low-cost rentals. For such a person, the “relative risk factor” of 1.5 or 2 amounts to little more than a statistical curiosity with little relevance for any future VA efforts at prevention. Targeting prevention based on such relative risk factors could be a grievous misallocation of resources, and yet the concept of “absolute risk” is absent from the review. Therefore, while it is possible to summarize papers that offered “relative risk factors” I really fear that this document risks reinforcing a misunderstanding that involves medicalizing homelessness, overlooking absolute risk, and may well invite research and even resource investments that “target” based on relative risk, resulting in a misallocation of both attention and resources. The text of the review reflects some awareness of this problem, but I think it should be confronted more squarely. | Thank you for this comment. We agree and have made revisions throughout the text to underscore that homelessness cannot be examined through the lens of individual-level factors alone and must be viewed in the context of community factors. As discussed in our response to other comments above, we conducted a broad literature search and would have included studies of population-level factors if we had found any. We now explicitly highlight this important evidence gap.
36 | 5 | a. Right now, the final paragraph of the Discussion, before the Limitations, introduces something of what I laid out above as a “limitation”. However, I don’t think this is a “limitation” in the traditional sense of a limitation in available data or in methods of collection. In essence, the research team’s mandate to carry out a certain type of review imposed a conceptual framework on the problem itself. The imposition of a “relative risk factor” framework made a review of this nature achievable within a certain budget and time, but it also invites serious misunderstandings, both in regard to absolute risk and in regard to the intersection of community and personal risk. Because this is really a design feature adopted by the perspective of the project itself, I recommend explaining the situation very bluntly, in the Introduction. In essence, if one is about to hand viewers a kind of distorted lens for an “evidence synthesis review”, it’s just preferable to tell readers right up front what they are getting, as bluntly as possible | Thank you for this comment. As discussed in our response to other comments above, we conducted a broad literature search and would have included studies of population-level factors impacting Veteran homelessness if we had found any. We view the lack of such evidence as an important limitation.; In response to this comment and similar comments made by this reviewer, we revised the Background and Discussions sections to more clearly state that population and individual-level factors impact homelessness risk (rather than individual factors alone) and that the lack of evidence regarding population-level factors among Veterans is an important gap.
37 | 5 | b. Additionally, it may be possible to mitigate the limitations of the review’s “risk factors” approach by offering a paragraph or even an inset box in the introduction. That paragraph or inset box. It could review the more traditional conceptual framework. The simplest version would say community factors are more strongly associated with a community’s total level of homelessness, and personal risk factors are more likely to govern “who” becomes homeless (this is enunciated by Shinn’s book1). A variation on this theme is to suggest that for any given person, their own homelessness is conceptually an interaction of “person” and “place”, which is introduced by O’Flaherty,2 and partially tested in one VA study3). There is some literature (some conceptual, some statistical) that approaches area level homelessness focused on factors like eviction filings4 rents5,6 and efforts to analyze multiple factors in tandem.7 This would be a kind of mitigation so that what follows isn’t taken the wrong way. | Thank for this comment and highlighting the citations. In response to this comment and similar comments made by this reviewer, we revised the Background and Discussions sections to more clearly state that population and individual-level factors impact homelessness risk (rather than individual factors alone) and that the lack of evidence regarding population-level factors among Veterans is an important gap. We now reference the article by O’Flaherty in the Background and Discussion sections.
38 | 5 | 2. Race is a powerful factor in determining absolute levels of homelessness nationally. Roughly 39-40% of the US Point-in-Time Count is African-American, even though they are 13% of the US population. It seems odd to only discuss this issue with no tables and as a short paragraph. | Thank you for this comment. We discuss race/ethnicity and other demographic factors in context of how included studies evaluated these factors as impacting homelessness risk.
39 | 5 | 3. Major: Risk of biased ascertainment or “cum hoc ergo propter hoc”; need to highlight VA service diagnosis-induced bias in estimates. Several sections appear to focus on correlation of exposure variables that are mostly or likely based on diagnoses assigned within VA health care (substance use on page 27, medical conditions on page 24, mental health conditions on page 25) and perhaps one based on a VA screener (military sexual trauma on page 23). These require clarification (at a minimum, a superscript in the tables, and a mention in the text when VA-record-derived diagnoses were used) because of this bias. Reliance on VA-assigned diagnoses introduces a bias in estimating the magnitude of association in ways that are not well explained in the “Limitations” (page 31, lines 9-14). In more traditional epidemiological studies, we might ascertain exposures by measuring (through survey or clinical examination) all members of a given population and then asking all members of that population, in the same way, whether they experienced homelessness (or better, observing them over time). Reliance on diagnostic codes from VA assures overdetection of certain diagnoses among persons who (a) have propensity to seek VA help for problems, and (b) have sought VA homeless assistance (which introduces a special increased likelihood of receiving addiction and mental health diagnoses).. In essence, if a homeless Veteran seeks VA help for their homelessness, they get an inflated opportunity to be designated as homeless and to be designated with various diagnoses, especially mental and addiction diagnoses (particularly if the VA they go to has a domiciliary, or RRTP). The differential application of medical and mental diagnoses to Veterans who seek VA help for homelessness likely biases the estimate of relative risk for homelessness upward. After all, non-homeless VA users aren’t going to be assessed nearly as intensively for addiction and mental health diagnoses, and they are unlikely to live in a VA building with VA doctors one hallway away, ready to diagnose at a moment’s notice. It is quite hard to know how great the distortion actually is. So, I urge that relative risk analyses wholly reliant on VA-assigned diagnoses be annotated as such with an asterisk or superscript in the row of the table where they are listed (this would certainly apply to Tables 7, 8, 9 and perhaps 6). We have no method in large retrospective VHA databases to control for this bias. But we can help readers see it. | Thank you for this comment. Regarding the tables, we added a footnote to say that diagnoses were most often based on VA medical record data.; We agree that data regarding Veterans accessing VA services may not be applicable to all Veterans. We previously discussed the applicability of available evidence as a limitation of the evidence base and have expanded on that text.; While we agree with you that there is potential for overdiagnosis of some conditions among Veterans accessing VA housing services, we did not identify objective data to support that assertion and prefer to avoid speculating.
40 | 5 | 4. If there was a early-bound on the time span restricting the literature search (2000? 1990?), I would suggest including mention of that boundary (orjust state that there was no such boundary, and that all literature going back to ____ was searched) on the Data Sources page (p. 11, line 49). I did note that there seemed to be very literature cited I this report before 2010. It made me wonder if perhaps no one ever did a Veterans study before 2010, or if there was a boundary on the search | Thank you for this comment. Our search timeframe is listed in our methods section and was not limited by date. We revised text in the Methods section to make this detail more evident.
41 | 5 | 5. “More research is needed on the ability of predictive models to identify Veterans at risk for homelessness and whether use of such models can help to cnnect at risk Veterans to services” (p 6, line 31-33). Is this actually credible? The basic “relative risk” vulnerabilities associated with one individual being more likely to be homeless than another have been fairly clear for 25-35 years. The awareness of these risk factors has – in a common sense way- led to some programs focused on health, others on employment, others on addiction, and others on financial assistance and housing. Is it likely that a new statistical formula would lead to better help? | Thank you for this comment. We revised the language suggesting the development of predictive models as a needed area for future research, noting that data on structural factors would need to be included in such models to make them useful. In the Future Research section, we highlight the model described in Koh 2022 as one that integrates individual and community-level factors.
42 | 5 | 6. Pag 11: The account of Eligibility Criteria (line 28-29) says for KQ1 “US Veterans and other adults experiencing homelessness”. I was puzzled if this means that studies of “other adults, absent veterans” were included, or not. The footnote (a) to that table (line 40) suggests that “systematic reviews” of non-Veterans were included. I’m unsure what was the definition of systematic review. It was evident to me that some papers that attempt to synthesize multiple other papers were excluded,2 but the reason is unclear. | For Key Question 1 regarding exposures that occurred in childhood and adolescence, we included systematic reviews in non-Veteran populations. The footnote explains the minimum methodological criteria that a systematic review would have to meet to be included in this synthesis (the review would have to include a systematic search of multiple databases and an assessment of risk of bias or quality of the included studies). Reviews that did not meet these minimal criteria, such as narrative reviews, were excluded. The citation referenced in this comment by O’Flagherty was not included for either Key Question because it is not a study of populations or individuals and does not include data on our outcomes of interest. However, the article by O’Flagherty provides a helpful perspective regarding the challenges of studying homelessness and we now cite it in both the Background and Discussion sections.
43 | 5 | 7. Page 15 (line 35) mentions “geographic location”. This is the first hint that community variables were considered. As a reader, it’s unclear how community variables were defined or how vigorously they were considered in this ESP. | Please see our responses to similar comments above.
44 | 5 | 8. Page 12: The synthesis section seems well-written and clear | None
45 | 5 | 9. For Table 1 (pages 16-18) is a bit confusing. The summary of longitudinal studies states, in the right hand column, “exposures assessed”. Can that 2-word phrase be explained a bit more precisely (ie are thse the ONLY exposures assessed? Or are the ones mentioned somehow “the onese of special interest”?). For example, in Table 1 the first line (Brignone, reference 3) states that they assessed “gender, military sexual trauma”. When I checked the Brignone paper, it appears that many other variables are included and would seem to count as “exposures”. (in fact, it did do so, but the table will leave most readers thinking it must not have done so). If the intention of the table is just to highlight a few exposures that the review authors felt were the “main ones of interest”, maybe just explain that in the table. | Table 1 is meant to include all exposures in the given studies. We missed a few exposures evaluated in Brignone 2016 as they were only reported in the supplement. Thank you for bringing that mistake to our attention. We have added all of the exposures in Brignone 2016 to the table and corresponding text.
46 | 5 | 10. For Table 2 (page 19) the expressions “Inception-Nov 2020” and “Inception-Jan.2-18” are listed under the heading “Search Timeframe”. I am not sure I understand what’s intended. Is it an effort to explain the “timeframe for eligible studies assessed in the cited source”? If that’s the case then it may be more explicit to say it that way. Also, what is “inception”? Is that a date? Finally the term “Jan.2-18” is not something I understand. | We have revised the wording in the table for clarity and corrected the typo of “2-18” which was intended to read “2018.”
47 | 5 | References:; 1. Shinn M, Khadduri J. In the Midst of Plenty: Homelessness and What to Do About It. Hoboken NJ: Wiley Blackwell; 2020.; 2. O’Flaherty B. Wrong person and wrong place: for homelessness, the conjunction is what matters. Journal of Housing Economics 2004; 13(1): 1-15. https://doi.org/10.1016/j.jhe.2003.12.001.; 3. Kertesz SG, deRussy AJ, Kim YI, Hoge AE, Austin EL, Gordon AJ, Gelberg L, Gabrielian SE, Riggs KR, Blosnich JR, Montgomery AE, Holmes SK, Varley AL, Pollio DE, Gundlapalli AV, Jones AL. Comparison of Patient Experience Between Primary Care Settings Tailored for Homeless Clientele and Mainstream Care Settings. Med Care 2021; 59: 495-503.10.1097/MLR.0000000000001548.; 4. Treglia D, Byrne T, Tamla Rai V. Quantifying the Impact of Evictions and Eviction Filings on Homelessness Rates in the United States. Housing Policy Debate 2023: 1-12.10.1080/10511482.2023.2186749.; 5. Hanratty M. Do Local Economic Conditions Affect Homelessness? Impact of Area Housing Market Factors, Unemployment, and Poverty on Community Homeless Rates. Housing Policy Debate 2017; 27(4): 640-55.10.1080/10511482.2017.1282885.; 6. Colburn G, Aldern CP. Homelessness is a housing problem : how structural factors explain U.S. patterns. Oakland, California: University of California Press; 2022.; 7. Byrne T, Munley EA, Fargo JD, Montgomery AE, Culhane DP. New Perspectives on Community-Level Determinants of Homelessness. Journal of Urban Affairs 2013; 35(5): 607-25.10.1111/j.1467-9906.2012.00643.x.; 17. | Thank you for these citations. None of these references met our inclusion criteria for evidence synthesis. However, we now reference the article by O’Flaherty et al. in the Background and Discussion sections and reference the article by Byrne et al. in the Discussion.
48 | 6 | I have no additional comments or suggestions. This is a well-written review that nicely synthesizes what is known about the drivers of homelessness among Veterans. | Thank you.
49 | 7 | Overall, this is a well-executed and thorough review of the literature on risk factors for homelessness among US Veterans. The methods, objectives, and scope were all clearly described. I especially appreciate the authors’ acknowledgment of the critical limitations of this review. Namely, variability in definitions and methods used to estimate homeless prevalence, as well as the lack of studies integrating examination of individual and structural factors. The complex interplay between individual and structural factors has been previously described in a qualitative study of formerly homeless adults with serious mental illness and co-occurring substance abuse (Padgett DK, Tiderington E, Smith BT, Derejko KS, Henwood BF. Complex Recovery: Understanding the Lives of Formerly Homeless Adults with Complex Needs. J Soc Distress Homeless. 2016;25(2):60-70. doi: 10.1080/10530789.2016.1173817. Epub 2016 Jul 26. PMID: 28439191; PMCID: PMC5400368.) However, this study was not specific to veteran populations. | Thank you. We agree that the interplay between individual and structural factors is important and have highlighted it as an area for future research in Veterans. We also suggest conducting further qualitative research on this topic and cite the study by Padgett et al. as an example of a helpful study conducted in a non-Veteran population.
50 | 7 | I had one question regarding the framing of the review and how the authors define “protective” factors. Were the factors detailed in these studies (e.g., completing more years of service) specifically identified in these studies as “protecting” the individual/population from becoming homeless or just found to be associated with NOT becoming homeless? I assume the latter. If so, I would suggest that the authors clarify this in the framing/wording of the review, or at the very least, provide a definition of “protective factors” at the beginning of the review. | Thank you for this comment. Yes, protective risk factors were those that were associated with not becoming homeless. We have revised text in the executive summary and discussion for clarity.
51 | 8 | Thank you for the opportunity to participate in this review, which was very thorough and thoughtfully completed. I have some comments to strengthen the review below.; -I would further explain in the first paragraph of the executive summary that homelessness also results from structural inequities to demonstrate the strong role of structural factors related to homelessness within the US. It seems important to acknowledge the structural factors contributing to homelessness (structural racism, poverty, unaffordable housing, lack of livable wages), so readers do not get the wrong impression that homelessness comes from solely individual factors or that individual level interventions only are needed. | Thank you. We agree and revised text in the Background and Discussion sections (and corresponding parts of the Executive Summary) to better frame homelessness as resulting from the conjunction of structural as well as individual factors. Please also see our responses to comments made by reviewer #5.
52 | 8 | For the bullet point in the executive summary about predictive models, it is not clear that the evidence synthesis supports the utility of predictive models at this point, or that this is a key take-away. Given that most studies look at individual factors, without incorporating greater ecological and structural factors, it is not clear if predictive models will be helpful or accurate in ending homelessness. | Thank you for this comment. We revised the language suggesting the development of predictive models as a needed area for future research, noting that data on structural factors would need to be included in such models to make them useful.
53 | 8 | -For the sentence on page 9, lines 42-44, “Developing accurate predictive models is challenging, however, because homelessness is multicausal and results from a complex interplay of individual-level risk factors and exposures across an individual’s lifespan,” would explain that homelessness also results from longstanding structural inequities and structural racism affecting housing, wealth, and access to services. Otherwise, there is concern this report could emphasize addressing homelessness individually, instead of addressing the issue structurally | Thank you for this comment. As above, we revised the text suggesting the development of predictive models as a recommended area for future research. Throughout the report, we now emphasize the importance of examining both individual and population-level factors.
54 | 8 | -On page 10, paragraph 2, would describe that the VA uses the definition of homelessness as established by the McKinney Vento Act, and cite the McKinney Vento Act. | Thank you for this comment. We have added a reference to the McKinney Vento Act and a citation in the Literature Overview section.
55 | 8 | -In the discussion of ACES, it seems important to give context that poverty is associated with a higher risk of ACES, and that ACES are more prevalent among low-income families. It also seems important to point out the racial/ethnic disparities in ACES exposures. Given the link between ACES and homelessness risk, the association with higher ACES scores among people who are more impoverished, and among minoritized people, should be acknowledged. (Page 19) | Thank you for this comment. We added this context to the initial discussion of ACEs. We also used the example of ACEs to highlight limitations of current analyses of individual-level factors and associations with homelessness. This text is in the Limitations section.
56 | 8 | -As the diagnosis of Conduct Disorder used for the Vietnam Veteran study cited is vastly different from today’s diagnosis and the reported symptoms of conduct disorder such as poor school attendance and academic failure are tied to social risk factors, this statement about conduct disorder being associated with homelessness could be misleading. You did a nice job of noting the diagnosis is different now, but I may add more caveats here about drawing any conclusion from this association with Conduct Disorder in this study (Page 19). | Thank you for this comment. We added a sentence to state that findings from this study are likely not generalizable to those diagnosed with Conduct Disorder using the contemporary definition.
57 | 8 | -You make strong points in the last paragraph on page 30 (line 45 onwards) about the lack of examining structural factors in the evidence. I recommend taking a key point from this paragraph and summarizing it as a bullet point in the executive summary key findings, particularly this point, “Indeed, it may be the case that many individual-level risk factors do not directly increase homelessness risk but instead make Veterans more susceptible to structural drivers of homeliness that undermine housing security or make stable housing difficult to obtain.” | Thank you for this comment. We agree and have added a bullet point regarding structural factors impacting homelessness to the Key Findings section.
58 | 8 | -For future research, I would consider advocating for research also examining local or regional housing policies, geographic factors, in addition to individual factors. | Thank you. We agree and have added this recommendation to the Future Research section.
59 | 8 | -I would also consider advocating for more qualitative research to understand these protective and risk factors. | Thank you. We agree that qualitative data could provide helpful insights into the risk and protective factors discussed in this review. We have added a recommendation to the Future Research section.

## REFERENCES

1 Brignone E, Gundlapalli AV, Blais RK, Differential risk for homelessness among us male and female veterans with a positive screen for military sexual trauma. JAMA Psychiatry. 2016;73(6):582–589.27096847
2 Brignone E. Misconduct-related discharge from active duty military service: An examination of precipitating factors and post-deployment health outcomes. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2018;78(10-B(E)):No-Specified.
3 Byrne T, Fargo JD, Montgomery AE, Roberts CB, Culhane DP, Kane V. Screening for homelessness in the veterans health administration: Monitoring housing stability through repeat screening. Public health reports (Washington, DC: 1974). 2015;130(6):684–692.
4 Elbogen EB, Sullivan CP, Wolfe J, Wagner HR, Beckham JC. Homelessness and money mismanagement in iraq and afghanistan veterans. American Journal of Public Health. 2013;103(S2):S248–S254.24148067
5 Fargo JD, Brignone E, Metraux S, Homelessness following disability-related discharges from active duty military service in afghanistan and iraq. Disability and Health Journal. 2017;10(4):592–599.28336255
6 Ghose T, Fiellin DA, Gordon AJ, Hazardous drinking and its association with homelessness among veterans in care. Drug and Alcohol Dependence. 2013;132(1–2):202–206.23474200
7 Gundlapalli AV, Redd A, Carter ME, Palmer M, Peterson R, Samore MH. Exploring patterns in resource utilization prior to the formal identification of homelessness in recently returned veterans. Studies in health technology and informatics. 2014;202:265–268.25000067
8 Jutkowitz E, DeVone F, Halladay C, Hooshyar D, Tsai J, Rudolph JL. Incidence of homelessness among veterans newly diagnosed with alzheimer's disease and related dementias. Rhode Island medical journal (2013). 2021;104(4):20–25.
9 Metraux S, Clegg LX, Daigh JD, Culhane DP, Kane V. Risk factors for becoming homeless among a cohort of veterans who served in the era of the iraq and afghanistan conflicts. American Journal of Public Health. 2013;103(S2):S255–S261.24148066
10 Montgomery AE, Rahman FAKM, Cusack M, Varley A, Byrne T. Correlates of transitions into housing instability among veterans accessing veterans health administration health care. Medical care. 2020;58(12):1105–1110.32925462
11 Mulcahy E, Szymkowiak D, Montgomery AE. Psychosocial risk factors for transitions into housing instability among women veterans. Journal of the American Board of Family Medicine: JABFM. 2021;34(2):387–391.33833007
12 Naifeh JA, Capaldi VF, Chu C, Prospective associations of military discharge characterization with post-active duty suicide attempts and homelessness: Results from the study to assess risk and resilience in servicemembers-longitudinal study (starrs-ls). Military medicine. 2022.
13 Rosenheck R, Fontana A. A model of homelessness among male veterans of the vietnam war generation. The American Journal of Psychiatry. 1994;151(3):421–427.8109652
14 Tsai J, Hoff RA, Harpaz-Rotem I. One-year incidence and predictors of homelessness among 300,000 u.S. Veterans seen in specialty mental health care. Special Issue: Homelessness Among Veterans, Other Adults, and Youth. 2017;14(2):203–207.
15 Brown GR, Jones KT. Mental health and medical health disparities in 5135 transgender veterans receiving healthcare in the veterans health administration: A case-control study. LGBT Health. 2016;3(2):122–131.26674598
16 Byrne T, Montgomery AE, Fargo JD. Predictive modeling of housing instability and homelessness in the veterans health administration. Health services research. 2019;54(1):75–85.30240000
17 Byrne T, Cashy J, Metraux S, Association between registered sex offender status and risk of housing instability and homelessness among veterans. Journal of interpersonal violence. 2022;37(7–8):NP5818–NP5829.32960141
18 Carter SP, Montgomery AE, Henderson ER, Housing instability characteristics among transgender veterans cared for in the veterans health administration, 2013–2016. American Journal of Public Health. 2019;109(10):1413–1418.31415197
19 Copeland LA, Miller AL, Welsh DE, McCarthy JF, Zeber JE, Kilbourne AM. Clinical and demographic factors associated with homelessness and incarceration among va patients with bipolar disorder. American Journal of Public Health. 2009;99(5):871–877.19299667
20 Edens EL, Kasprow W, Tsai J, Rosenheck RA. Association of substance use and va service-connected disability benefits with risk of homelessness among veterans. The American Journal on Addictions. 2011;20(5):412–419.21838839
21 Edwards ER, Dichiara A, Gromatsky M, Tsai J, Goodman M, Pietrzak R. Understanding risk in younger veterans: Risk and protective factors associated with suicide attempt, homelessness, and arrest in a nationally representative veteran sample. Military Psychology. 2022;34(2):175–186.
22 Fletcher OV, Chen JA, van Draanen J, Prevalence of social and economic stressors among transgender veterans with alcohol and other drug use disorders. SSM - population health. 2022;19:101153.35813187
23 Harris T, Kintzle S, Wenzel S, Castro CA. Expanding the understanding of risk behavior associated with homelessness among veterans. Military Medicine. 2017;182(9):e1900–e1907.
24 Iheanacho T, Stefanovics E, Rosenheck R. Opioid use disorder and homelessness in the veterans health administration: The challenge of multimorbidity. Journal of opioid management. 2018;14(3):171–182.30044482
25 Lim S, Kasprow WJ, Rosenheck RA. Psychiatric illness and substance abuse among homeless asian-american veterans. Psychiatric Services. 2006;57(5):704–707.16675767
26 Lin D, Kim H, Wada K, Unemployment, homelessness, and other societal outcomes in patients with schizophrenia: A real-world retrospective cohort study of the united states veterans health administration database: Societal burden of schizophrenia among us veterans. BMC Psychiatry. 2022;22.34996394
27 Montgomery AE, Dichter ME, Thomasson AM, Fu X, Roberts CB. Demographic characteristics associated with homelessness and risk among female and male veterans accessing vha outpatient care. Women's Health Issues. 2015;25(1):42–48.25498763
28 Montgomery AE, Dichter ME, Thomasson AM, Roberts CB, Byrne T. Disparities in housing status among veterans with general medical, cognitive, and behavioral health conditions. Psychiatric Services. 2015;66(3):317–320.25727122
29 Nichter B, Tsai J, Pietrzak RH. Prevalence, correlates, and mental health burden associated with homelessness in u.S. Military veterans. Psychological medicine. 2022:1–11.
30 Spinola S, Hoff RA, Tsai J. A psychosocial mediational model of homelessness among u.S. Male and female veterans who served in iraq and afghanistan. Health & social care in the community. 2021;29(2):453–463.32662176
31 Stefanovics EA, Rosenheck RA. Prevalence and multi-morbid correlates of homelessness among veterans with hiv infection nationally in the veterans health administration. Psychology, Health & Medicine. 2019;24(9):1123–1136.
32 Tsai J, Link B, Rosenheck RA, Pietrzak RH. Homelessness among a nationally representative sample of us veterans: Prevalence, service utilization, and correlates. Social Psychiatry and Psychiatric Epidemiology: The International Journal for Research in Social and Genetic Epidemiology and Mental Health Services. 2016;51(6):907–916.
33 Tsai J, Hooshyar D. Prevalence of eviction, home foreclosure, and homelessness among low-income us veterans: The national veteran homeless and other poverty experiences study. Public health. 2022;213:181–188.36444823
34 Twamley EW, Hays CC, Van Patten R, Neurocognition, psychiatric symptoms, and lifetime homelessness among veterans with a history of traumatic brain injury. Psychiatry Research. 2019;271:167–170.30481694
35 Washington DL, Yano EM, McGuire J, Hines V, Lee M, Gelberg L. Risk factors for homelessness among women veterans. Journal of Health Care for the Poor and Underserved. 2010;21(1):81–91.
36 Gundlapalli AV, Fargo JD, Metraux S, Military misconduct and homelessness among us veterans separated from active duty, 2001–2012. JAMA: Journal of the American Medical Association. 2015;314(8):832–834.26305655
37 Hefner K, Rosenheck R. Multimorbidity among veterans diagnosed with ptsd in the veterans health administration nationally. Psychiatric Quarterly. 2019;90(2):275–291.30847694
38 Adler AB, LeardMann CA, Yun S, Jacobson IG, Forbes D. Problematic anger and economic difficulties: Findings from the millennium cohort study. Journal of Affective Disorders. 2022;297:679–685.34710505
39 Mares AS, Rosenheck RA. Perceived relationship between military service and homelessness among homeless veterans with mental illness. Journal of Nervous and Mental Disease. 2004;192(10):715–719.15457118
40 Rosenheck R, Gallup P, Leda CA. Vietnam era and vietnam combat veterans among the homeless. American Journal of Public Health. 1991;81(5):643–646.2014870
41 Tsai J, Szymkowiak D, Pietrzak RH. Delayed homelessness after military discharge: Examination of a sleeper effect. American journal of preventive medicine. 2020;59(1):109–117.32386790
42 Ackerman A. The impact of combat on veteran well-being. Dissertation Abstracts International Section A: Humanities and Social Sciences. 2018;79(12-A(E)):No-Specified.
43 Bachhuber MA, Roberts CB, Metraux S, Montgomery AE. Screening for homelessness among individuals initiating medication-assisted treatment for opioid use disorder in the veterans health administration. Journal of opioid management. 2015;11(6):459–462.26728642
44 Brown GR, Jones KT. Racial health disparities in a cohort of 5,135 transgender veterans. Journal of Racial and Ethnic Health Disparities. 2014;1(4):257–266.
45 Dichter ME, Wagner C, Borrero S, Broyles L, Montgomery AE. Intimate partner violence, unhealthy alcohol use, and housing instability among women veterans in the veterans health administration. Special Issue: Homelessness Among Veterans, Other Adults, and Youth. 2017;14(2):246–249.
46 Dunne EM, Burrell LE II, Diggins AD, Whitehead NE, Latimer WW. Increased risk for substance use and health-related problems among homeless veterans. The American Journal on Addictions. 2015;24(7):676–680.26359444
47 Elbogen EB, Johnson SC, Wagner HR, Newton VM, Beckham JC. Financial well-being and postdeployment adjustment among iraq and afghanistan war veterans. Military Medicine. 2012;177(6):669–675.22730842
48 Fargo J, Metraux S, Byrne T, Prevalence and risk of homelessness among us veterans. Preventing chronic disease. 2012;9:E45.22280960
49 Gamache G, Rosenheck R, Tessler R. Military discharge status of homeless veterans with mental illness. Military Medicine. 2000;165(11):803–815.11143423
50 Ghose T, Gordon AJ, Metraux S, Justice AC. Mental illness and homelessness among veterans. Psychiatric Services. 2011;62(12):1514–1515.
51 Ghose T, Gordon AJ, Metraux S, The association between hiv status and homelessness among veterans in care. Journal of Community Psychology. 2015;43(2):189–198.
52 Haque L, Rosenheck R. Mental health and addiction service use among united states veterans with liver disease nationally in the veterans health administration. Journal of Public Mental Health. 2021;20(3):191–200.
53 Ho P, Rosenheck R. Substance use disorder among current cancer patients: Rates and correlates nationally in the department of veterans affairs. Psychosomatics. 2018;59(3):267–276.29452704
54 MacLean RR, Sofuoglu M, Rosenheck R. Tobacco and alcohol use disorders: Evaluating multimorbidity. Addictive Behaviors. 2018;78:59–66.29127785
55 Manhapra A, Stefanovics E, Rosenheck R. The association of opioid use disorder and homelessness nationally in the veterans health administration. Drug and Alcohol Dependence. 2021;223.
56 Montgomery AE, Cutuli JJ, Evans-Chase M, Treglia D, Culhane DP. Relationship among adverse childhood experiences, history of active military service, and adult outcomes: Homelessness, mental health, and physical health. American journal of public health. 2013;103 Suppl 2:S262–268.24148064
57 Rosenheck R, Stefanovics E, Rhee TG. Association of the military transition to an all-volunteer force and subsequent zero-tolerance drug policy with characteristics of male veterans in the vietnam, post-vietnam and subsequent post-post vietnam cohorts. The Psychiatric quarterly. 2021;92(3):1129–1145.33587258
58 Tsai J, Pietrzak RH, Szymkowiak D. The problem of veteran homelessness: An update for the new decade. American journal of preventive medicine. 2021;60(6):774–780.33583678
59 Yaekel-Black Elk JK. American indian vietnam combat veterans: How out-of-home placement and having a veteran primary care giver are associated with features and symptoms of trauma. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2009;69(12-B):7832.
60 Yoon G, Petrakis IL, Rosenheck RA. Correlates of major depressive disorder with and without comorbid alcohol use disorder nationally in the veterans health administration. The American Journal on Addictions. 2015;24(5):419–426.25950244
61 Liu M, Luong L, Lachaud J, Edalati H, Reeves A, Hwang SW. Adverse childhood experiences and related outcomes among adults experiencing homelessness: A systematic review and meta-analysis. The Lancet Public health. 2021;6(11):e836–e847.34599894
62 Nilsson SF, Nordentoft M, Hjorthoj C. Individual-level predictors for becoming homeless and exiting homelessness: A systematic review and meta-analysis. Journal of urban health: bulletin of the New York Academy of Medicine. 2019;96(5):741–750.31388823