# APPENDIX C EVIDENCE TABLES

## CHARACTERISTICS OF INCLUDED PRIMARY STUDIES

## OUTCOME DATA OF INCLUDED PRIMARY STUDIES

### Risk Factors Examined by a Single Cross-sectional Study

American Indian/Alaskan Native race – Byrne 2019^16^

Native Hawaiian/Pacific Islander race – Byrne 2019^16^

Neurological disorder – Byrne 2019^16^

Metastatic tumor – Byrne 2019^16^

Solid tumor without metastasis – Byrne 2019^16^

Weight loss – Byrne 2019^16^

Peripheral vascular disease – Iheanacho 2018^24^

Myocardial infarction – Iheanacho 2018^24^

Pain - Iheanacho 2018^24^

Seizures – Stefanovics 2019^31^

Pruritis – Stefanovics 2019^31^

Post-concussive syndrome – Twamley 2019^34^

Pregnant past 12 months – Washington 2010^35^

Hospitalization – Washington 2010^35^

Outpatient primary care visits – Byrne 2019^16^

Has a usual care provider – Washington 2010^35^

Unmet need for health care – Washington 2010^35^

Pathological gambling – Edens 2011^20^

PTSD multimorbidity – Hefner 2019^37^

Problematic anger – Adler 2022^38^

Bipolar disorder – current manic episode – Copeland 2009^19^

Bipolar disorder – current mixed state – Copeland 2009^19^

Bipolar disorder – current depression episode – Copeland 2009^19^

Binge drinking – Copeland 2009^19^

Inpatient mental health days – Byrne 2019^16^

Psychiatric inpatient visits – Iheanacho 2018^24^

Therapeutic alliance – Copeland 2009^19^

Any psychotropic medication - Iheanacho 2018^24^

Antidepressant – Iheanacho 2018^24^

Anticonvulsant or mood stabilizer – Iheanacho 2018^24^

Sedative hypnotic or analgesic – Iheanacho 2018^24^

Stimulant – Iheanacho 2018^24^

Opiates – Iheanacho 2018^24^

Antipsychotic – Iheanacho 2018^24^

Medication adherence – Copeland 2009^19^

Meredith Medication Beliefs Score – Copeland 2009^19^

Buprenorphine – Iheanacho 2018^24^

Methadone – Iheanacho 2018^24^

Buprenorphine or methadone – Iheanacho 2018^24^

Era of Service – Mares 2004^39^

Era of Service – Vietnam – Rosenheck 1991^40^

Era of Service – Post-Vietnam – Rosenheck 1991^40^

Era of Service – Vietnam or earlier – Tsai 2016^32^

Era of Service – Persian Gulf – Tsai 2020^41^

Exposure to hostile or friendly fire – Mares 2004^39^

Disabling illness or injury – Ackerman 2018^42^

Other tragic loss – Ackerman 2018^42^

Moral injury – Edwards 2022^21^

Deployed time – Ackerman 2018^42^

Ending period of military service – Washington 2010^35^

Age at discharge – Mares 2004^39^

Perceived effect of military experience – Edwards 2022^21^

Vocational service use – Iheanacho 2018^24^

Residential rehabilitation visits – Iheanacho 2018^24^

Community integration – Edwards 2022^21^

### Cross-sectional Studies Without Unique Risk Factors

Ackerman 2018^42^

Bachhuber 2015^43^

Brown 2014^44^

Dichter 2017^45^

Dunne 2015^46^

Elbogen 2012^47^

Fargo 2012^48^

Gamache 2000^49^

Ghose 2011^50^/Ghose 2015^51^

Haque 2021^52^

Hefner 2019^37^

Ho 2018^53^

MacLean 2018^54^

Manhapra 2021^55^

Montgomery 2013^56^

Rosenheck 1991^40^

Rosenheck 2021^57^

Tsai 2021^58^

Tsai 2020^41^

Yaekel-Black Elk 2009^59^

Yoon 2015^60^

## QUALITY ASSESSMENT

## STRENGTH OF EVIDENCE FOR INCLUDED STUDIES